# References

1 Aldrich Handbook of Fine Chemicals. Milwaukee (WI): Aldrich Chemical Company, Inc.; 1996. p. 849.
2 Broadbent TAS Broadbent HS 1. The chemistry and pharmacology of indole-3-carbinol (indole-3-methanol) and 3-(methoxymethyl)indole. [Part II]. [Part II]. Curr Med Chem. 1998;5(6):469–491. 9873111
3 Bradfield CA Bjeldanes LF Modification of carcinogen metabolism by indolylic autolysis products of Brassica oleraceae. Adv Exp Med Biol. 1991;289:153–163. http://dx.doi.org/10.1007/978-1-4899-2626-5_13 1897390
4 Wortelboer HM de Kruif CA van Iersel AAJ Falke HE Noordhoek J Blaauboer BJ Acid reaction products of indole-3-carbinol and their effects on cytochrome P450 and phase II enzymes in rat and monkey hepatocytes. Biochem Pharmacol. 1992;43(7):1439–1447. 10.1016/0006-2952(92)90200-3 1567468
5 Kwon C-S Grose KR Riby J Chen Y-H Bjeldanes LF In vivo production and enzyme-inducing activity of indolo[3,2-b]carbazole. J Agric Food Chem. 1994;42(11):2536–2540. 10.1021/jf00047a030
6 Jongen WMF Glucosinolates in Brassica: occurrence and significance as cancer-modulating agents. Proc Nutr Soc. 1996;55 1B:433–446. http://dx.doi.org/10.1079/PNS19960040 8832811
7 Holst B Williamson G A critical review of the bioavailability of glucosinolates and related compounds. Nat Prod Rep. 2004;21(3):425–447. 10.1039/b204039p 15162227
8 McDanell R McLean AEM Hanley AB Heaney RK Fenwick GR Chemical and biological properties of indole glucosinolates (glucobrassicins): a review. Food Chem Toxicol. 1988;26(1):59–70. http://dx.doi.org/10.1016/0278-6915(88)90042-7 3278958
9 Heaney RK Fenwick GR Natural toxins and protective factors in brassica species, including rapeseed. Nat Toxins. 1995;3(4):233–237, discussion 242. http://dx.doi.org/10.1002/nt.2620030412 7582622
10 Carlson DG Daxenbichler ME VanEtten CH Kwolek WF Williams PH Glucosinolates in crucifer vegetables: Broccoli, brussels sprouts, cauliflower, collards, kale, mustard greens, and kohlrabi. J Am Soc Hortic Sci. 1987;112(1):173–178.
11 Dashwood RH Uyetake L Fong AT Hendricks JD Bailey GS In vivo disposition of the natural anti-carcinogen indole-3-carbinol after po administration to rainbow trout. Food Chem Toxicol. 1989;27(6):385–392. http://dx.doi.org/10.1016/0278-6915(89)90144-0 2792968
12 Stresser DM Williams DE Griffin DA Bailey GS Mechanisms of tumor modulation by indole-3-carbinol. Disposition and excretion in male Fischer 344 rats. Drug Metab Dispos. 1995;23(9):965–975. 8565787
13 Anderton MJ Manson MM Verschoyle RD Gescher A Lamb JH Farmer PB Steward WP Williams ML Pharmacokinetics and tissue disposition of indole-3-carbinol and its acid condensation products after oral administration to mice. Clin Cancer Res. 2004;10(15):5233–5241. http://dx.doi.org/10.1158/1078-0432.CCR-04-0163 15297427
14 De Kruif CA Marsman JW Venekamp JC Falke HE Noordhoek J Blaauboer BJ Wortelboer HM Structure elucidation of acid reaction products of indole-3-carbinol: detection in vivo and enzyme induction in vitro. Chem Biol Interact. 1991;80(3):303–315. http://dx.doi.org/10.1016/0009-2797(91)90090-T 1954658
15 Chang Y-C Riby J Chang GHF Peng BC Firestone G Bjeldanes LF Cytostatic and antiestrogenic effects of 2-(indol-3-ylmethyl)-3,3′-diindolylmethane, a major in vivo product of dietary indole-3-carbinol. Biochem Pharmacol. 1999;58(5):825–834. http://dx.doi.org/10.1016/S0006-2952(99)00165-3 10449193
16 Riby JE Feng C Chang Y-C Schaldach CM Firestone GL Bjeldanes LF The major cyclic trimeric product of indole-3-carbinol is a strong agonist of the estrogen receptor signaling pathway. Biochemistry. 2000;39(5):910–918. http://dx.doi.org/10.1021/bi9919706 10653634
17 Gonzalez JM Yusta B Garcia C Carpio M Pulmonary and hepatic lesions in experimental 3-hydroxymethylindole intoxication. Vet Hum Toxicol. 1986;28(5):418–420. 3776083
18 LeBlanc GA Stuart JD Dunn SE Baldwin WS Effect of the plant compound indole-3-carbinol on hepatic cholesterol homoeostasis. Food Chem Toxicol. 1994;32(7):633–639. http://dx.doi.org/10.1016/0278-6915(94)90007-8 8045476
19 Shertzer HG Sainsbury M Intrinsic acute toxicity and hepatic enzyme inducing properties of the chemoprotectants indole-3-carbinol and 5,10-dihydroindeno[1,2-b]indole in mice. Food Chem Toxicol. 1991;29(4):237–242. http://dx.doi.org/10.1016/0278-6915(91)90020-8 2040485
20 Crowell JA Page JG Levine BS Tomlinson MJ Hebert CD Indole-3-carbinol, but not its major digestive product 3,3′-diindolylmethane, induces reversible hepatocyte hypertrophy and cytochromes P450. Toxicol Appl Pharmacol. 2006;211(2):115–123. http://dx.doi.org/10.1016/j.taap.2005.06.011 16043203
21 Leibelt DA Hedstrom OR Fischer KA Pereira CB Williams DE Evaluation of chronic dietary exposure to indole-3-carbinol and absorption-enhanced 3,3′-diindolylmethane in sprague-dawley rats. Toxicol Sci. 2003;74(1):10–21. http://dx.doi.org/10.1093/toxsci/kfg103 12730619
22 Johansson G Gillner M Högberg B Gustafsson JA The TCDD receptor in rat intestinal mucosa and its possible dietary ligands. Nutr Cancer. 1982;3(3):134–144. http://dx.doi.org/10.1080/01635588109513715 6291004
23 Bjeldanes LF Kim JY Grose KR Bartholomew JC Bradfield CA Aromatic hydrocarbon responsiveness-receptor agonists generated from indole-3-carbinol in vitro and in vivo: comparisons with 2,3,7,8-tetrachlorodibenzo-p-dioxin. Proc Natl Acad Sci USA. 1991;88(21):9543–9547. http://dx.doi.org/10.1073/pnas.88.21.9543 1658785
24 Jellinck PH Forkert PG Riddick DS Okey AB Michnovicz JJ Bradlow HL Ah receptor binding properties of indole carbinols and induction of hepatic estradiol hydroxylation. Biochem Pharmacol. 1993;45(5):1129–1136. http://dx.doi.org/10.1016/0006-2952(93)90258-X 8384853
25 Nishie K Daxenbichler ME Toxicology of glucosinolates, related compounds (nitriles, R-goitrin, isothiocyanates) and vitamin U found in Cruciferae. Food Cosmet Toxicol. 1980;18(2):159–172. http://dx.doi.org/10.1016/0015-6264(80)90070-X 7390339
26 Y.C. Wong GBradlow L, Sepkovic D, Mehl S, Mailman J, P. Osborne M. Dose-ranging study of Indole-3-Carbinol for breast cancer prevention. J Cell Biochem Suppl. 1997; 28-29:111-116.
27 Bell MC Crowley-Nowick P Bradlow HL Sepkovic DW Schmidt-Grimminger D Howell P Mayeaux EJ Tucker A Turbat-Herrera EA Mathis JM Placebo-controlled trial of indole-3-carbinol in the treatment of CIN. Gynecol Oncol. 2000;78(2):123–129. 10.1006/gyno.2000.5847 10926790
28 McAlindon TE Gulin J Chen T Klug T Lahita R Nuite M Indole-3-carbinol in women with SLE: effect on estrogen metabolism and disease activity. Lupus. 2001;10(11):779–783. http://dx.doi.org/10.1177/096120330101001104 11789487
29 Wilker C Johnson L Safe S Effects of developmental exposure to indole-3-carbinol or 2,3,7,8-tetrachlorodibenzo-p-dioxin on reproductive potential of male rat offspring. Toxicol Appl Pharmacol. 1996;141(1):68–75. http://dx.doi.org/10.1016/S0041-008X(96)80010-X 8917677
30 Pence BC Buddingh F Yang SP Multiple dietary factors in the enhancement of dimethylhydrazine carcinogenesis: main effect of indole-3-carbinol. J Natl Cancer Inst. 1986;77(1):269–276. 3459919
31 Dashwood RH Indole-3-carbinol: anticarcinogen or tumor promoter in brassica vegetables? Chem Biol Interact. 1998;110(1-2):1–5. http://dx.doi.org/10.1016/S0009-2797(97)00115-4 9566721
32 Bailey GS Hendricks JD Shelton DW Nixon JE Pawlowski NE Enhancement of carcinogenesis by the natural anticarcinogen indole-3-carbinol. J Natl Cancer Inst. 1987;78(5):931–934. 3106695
33 Kim DJ Han BS Ahn B Hasegawa R Shirai T Ito N Tsuda H Enhancement by indole-3-carbinol of liver and thyroid gland neoplastic development in a rat medium-term multiorgan carcinogenesis model. Carcinogenesis. 1997;18(2):377–381. http://dx.doi.org/10.1093/carcin/18.2.377 9054632
34 Wattenberg LW Loub WD Inhibition of polycyclic aromatic hydrocarbon-induced neoplasia by naturally occurring indoles. Cancer Res. 1978;38(5):1410–1413. 416908
35 Tanaka T Kojima T Morishita Y Mori H Inhibitory effects of the natural products indole-3-carbinol and sinigrin during initiation and promotion phases of 4-nitroquinoline 1-oxide-induced rat tongue carcinogenesis. Jpn J Cancer Res. 1992;83(8):835–842. http://dx.doi.org/10.1111/j.1349-7006.1992.tb01988.x 1399821
36 Grubbs CJ Steele VE Casebolt T Juliana MM Eto I Whitaker LM Dragnev KH Kelloff GJ Lubet RL Chemoprevention of chemically-induced mammary carcinogenesis by indole-3-carbinol. Anticancer Res. 1995;15(3):709–716. 7645947
37 Kojima T Tanaka T Mori H Chemoprevention of spontaneous endometrial cancer in female Donryu rats by dietary indole-3-carbinol. Cancer Res. 1994;54(6):1446–1449. 8137246
38 Bradlow HL Michnovicz J Telang NT Osborne MP Effects of dietary indole-3-carbinol on estradiol metabolism and spontaneous mammary tumors in mice. Carcinogenesis. 1991;12(9):1571–1574. http://dx.doi.org/10.1093/carcin/12.9.1571 1893517
39 Malloy VL Bradlow HL Orentreich N Interaction between a semisynthetic diet and indole-3-carbinol on mammary tumor incidence in Balb/cfC3H mice. Anticancer Res. 1997;17 6D:4333–4337. 9494529
40 Kim DJ Lee KK Han BS Ahn B Bae JH Jang JJ Biphasic modifying effect of indole-3-carbinol on diethylnitrosamine-induced preneoplastic glutathione S-transferase placental form-positive liver cell foci in Sprague-Dawley rats. Jpn J Cancer Res. 1994;85(6):578–583. http://dx.doi.org/10.1111/j.1349-7006.1994.tb02399.x 8063610
41 Oganesian A Hendricks JD Williams DE Long term dietary indole-3-carbinol inhibits diethylnitrosamine-initiated hepatocarcinogenesis in the infant mouse model. Cancer Lett. 1997;118(1):87–94. http://dx.doi.org/10.1016/S0304-3835(97)00235-8 9310264
42 Morse MA LaGreca SD Amin SG Chung F-L Effects of indole-3-carbinol on lung tumorigenesis and DNA methylation induced by 4-(methylnitrosamino)-1-(3-pyridyl)-1-butanone (NNK) and on the metabolism and disposition of NNK in A/J mice. Cancer Res. 1990;50(9):2613–2617. 2328487
43 Chung FL Morse MA Eklind KI Xu Y Inhibition of tobacco-specific nitrosamine-induced lung tumorigenesis by compounds derived from cruciferous vegetables and green tea. Ann N Y Acad Sci. 1993;686(1):186–201, discussion 201–202. http://dx.doi.org/10.1111/j.1749-6632.1993.tb39174.x 8512247
44 Stoner GD Adam-Rodwell G Morse MA Lung tumors in strain A mice: application for studies in cancer chemoprevention. J Cell Biochem Suppl. 1993;17F:95–103. http://dx.doi.org/10.1002/jcb.240531014 8412213
45 el-Bayoumy K Upadhyaya P Desai DH Amin S Hoffmann D Wynder EL Effects of 1,4-phenylenebis(methylene)selenocyanate, phenethyl isothiocyanate, indole-3-carbinol, and d-limonene individually and in combination on the tumorigenicity of the tobacco-specific nitrosamine 4-(methylnitrosamino)-1-(3-pyridyl)-1-butanone in A/J mouse lung. Anticancer Res. 1996;16 5A:2709–2712. 8917375
46 Jain MG Hislop GT Howe GR Ghadirian P Plant foods, antioxidants, and prostate cancer risk: findings from case-control studies in Canada. Nutr Cancer. 1999;34(2):173–184. http://dx.doi.org/10.1207/S15327914NC3402_8 10578485
47 Kolonel LN Hankin JH Whittemore AS Wu AH Gallagher RP Wilkens LR John EM Howe GR Dreon DM West DW Vegetables, fruits, legumes and prostate cancer: a multiethnic case-control study. Cancer Epidemiol Biomarkers Prev. 2000;9(8):795–804. 10952096
48 Voorrips LE Goldbohm RA van Poppel G Sturmans F Hermus RJJ van den Brandt PA Vegetable and fruit consumption and risks of colon and rectal cancer in a prospective cohort study: The Netherlands Cohort Study on Diet and Cancer. Am J Epidemiol. 2000;152(11):1081–1092. http://dx.doi.org/10.1093/aje/152.11.1081 11117618
49 Terry P Wolk A Persson I Magnusson C Brassica vegetables and breast cancer risk. JAMA. 2001;285(23):2975–2977. http://dx.doi.org/10.1001/jama.285.23.2975 11410091
50 Young TB Wolf DA Case-control study of proximal and distal colon cancer and diet in Wisconsin. Int J Cancer. 1988;42(2):167–175. http://dx.doi.org/10.1002/ijc.2910420205 3403062
51 Arnao MB Sanchez-Bravo J Acosta M Indole-3-carbinol as a scavenger of free radicals. Biochem Mol Biol Int. 1996;39(6):1125–1134. http://dx.doi.org/10.1080/15216549600201302 8876965
52 Kelloff GJ Boone CW Crowell JA Steele VE Lubet RA Doody LA Malone WF Hawk ET Sigman CC New agents for cancer chemoprevention. J Cell Biochem Suppl. 1996;26 S26:1–28. https://doi.org/10.1002/jcb.240630703 9154166
53 Keck A-S Finley JW Cruciferous vegetables: cancer protective mechanisms of glucosinolate hydrolysis products and selenium. Integr Cancer Ther. 2004;3(1):5–12. http://dx.doi.org/10.1177/1534735403261831 15035868
54 Kelloff GJ Crowell JA Hawk ET Steele VE Lubet RA Boone CW Covey JM Doody LA Omenn GS Greenwald P Strategy and planning for chemopreventive drug development: clinical development plans II. J Cell Biochem Suppl. 1996;26 S26:54–71. http://dx.doi.org/10.1002/jcb.240630705 9154168
55 Rosen CA Woodson GE Thompson JW Hengesteg AP Bradlow HL Preliminary results of the use of indole-3-carbinol for recurrent respiratory papillomatosis. Otolaryngol Head Neck Surg. 1998;118(6):810–815. http://dx.doi.org/10.1016/S0194-5998(98)70274-8 9627242
56 Rosen CA Bryson PC Indole-3-carbinol for recurrent respiratory papillomatosis: long-term results. J Voice. 2004;18(2):248–253. http://dx.doi.org/10.1016/j.jvoice.2003.05.005 15193659
57 Reed GA Peterson KS Smith HJ Gray JC Sullivan DK Mayo MS Crowell JA Hurwitz A A phase I study of indole-3-carbinol in women: tolerability and effects. Cancer Epidemiol Biomarkers Prev. 2005;14(8):1953–1960. http://dx.doi.org/10.1158/1055-9965.EPI-05-0121 16103443
58 Naik R Nixon S Lopes A Godfrey K Hatem MH Monaghan JM A randomized phase II trial of indole-3-carbinol in the treatment of vulvar intraepithelial neoplasia. Int J Gynecol Cancer. 2006;16(2):786–790. http://dx.doi.org/10.1111/j.1525-1438.2006.00386.x 16681761
59 Doppalapudi RS Riccio ES Rausch LL Shimon JA Lee PS Mortelmans KE Kapetanovic IM Crowell JA Mirsalis JC Evaluation of chemopreventive agents for genotoxic activity. Mutat Res. 2007;629(2):148–160. http://dx.doi.org/10.1016/j.mrgentox.2007.02.004 17387038
60 Kassie F Parzefall W Musk S Johnson I Lamprecht G Sontag G Knasmüller S Genotoxic effects of crude juices from Brassica vegetables and juices and extracts from phytopharmaceutical preparations and spices of cruciferous plants origin in bacterial and mammalian cells. Chem Biol Interact. 1996;102(1):1–16. http://dx.doi.org/10.1016/0009-2797(96)03728-3 8827059
61 Ochiai M Wakabayashi K Sugimura T Nagao M Mutagenicities of indole and 30 derivatives after nitrite treatment. Mutat Res. 1986;172(3):189–197. http://dx.doi.org/10.1016/0165-1218(86)90056-X 3537775
62 Tiedink HGM Davies JAR van Broekhoven LW van der Kamp HJ Jongen WMF Formation of mutagenic N-nitroso compounds in vegetable extracts upon nitrite treatment: a comparison with the glucosinolate content. Food Chem Toxicol. 1988;26(11-12):947–954. http://dx.doi.org/10.1016/0278-6915(88)90093-2 3209134
63 Tiedink HG Davies JA Jongen WM van Broekhoven LW Stability of mutagenic nitrosated products of indole compounds occurring in vegetables. IARC Sci Publ. 1991;105(105):584–587. 1855922
64 Sasagawa C Matsushima T Mutagen formation on nitrite treatment of indole compounds derived from indole-glucosinolate. Mutat Res. 1991;250(1-2):169–174. http://dx.doi.org/10.1016/0027-5107(91)90173-L 1944332
65 Agrawal RC Kumar S Prevention of chromosomal aberration in mouse bone marrow by indole-3-carbinol. Toxicol Lett. 1999;106(2-3):137–141. http://dx.doi.org/10.1016/S0378-4274(99)00060-0 10403657
66 Shukla Y Arora A Taneja P Antigenotoxic potential of certain dietary constituents. Teratog Carcinog Mutagen. 2003;23 Suppl 1:323–335. http://dx.doi.org/10.1002/tcm.10059 12616623
67 Schut HAJ Dashwood RH Inhibition of DNA adduct formation of 2-amino-1-methyl-6- phenylimidazo[4,5-b]pyridine (PhIP) by dietary indole-3-carbinol (I3C) in the mammary gland, colon, and liver of the female F-344 rat. Ann N Y Acad Sci. 1995;768(1):210–214. http://dx.doi.org/10.1111/j.1749-6632.1995.tb12124.x 8526350
68 Xu M Bailey AC Hernaez JF Taoka CR Schut HAJ Dashwood RH Protection by green tea, black tea, and indole-3-carbinol against 2-amino-3-methylimidazo[4,5-f]quinoline-induced DNA adducts and colonic aberrant crypts in the F344 rat. Carcinogenesis. 1996;17(7):1429–1434. http://dx.doi.org/10.1093/carcin/17.7.1429 8706244
69 Xu M Schut HA Bjeldanes LF Williams DE Bailey GS Dashwood RH Inhibition of 2-amino-3-methylimidazo[4,5-f]quinoline-DNA adducts by indole-3-carbinol: dose-response studies in the rat colon. Carcinogenesis. 1997;18(11):2149–2153. http://dx.doi.org/10.1093/carcin/18.11.2149 9395215
70 Schut HAJ Cummings DA Smale MHE Josyula S Friesen MD DNA adducts of heterocyclic amines: formation, removal and inhibition by dietary components. Mutat Res. 1997;376(1-2):185–194. http://dx.doi.org/10.1016/S0027-5107(97)00042-0 9202755
71 Arif JM Gairola CG Kelloff GJ Lubet RA Gupta RC Inhibition of cigarette smoke-related DNA adducts in rat tissues by indole-3-carbinol. Mutat Res. 2000;452(1):11–18. http://dx.doi.org/10.1016/S0027-5107(00)00010-5 10894885
72 Gross-Steinmeyer K Stapleton PL Tracy JH Bammler TK Strom SC Buhler DR Eaton DL Modulation of aflatoxin B1-mediated genotoxicity in primary cultures of human hepatocytes by diindolylmethane, curcumin, and xanthohumols. Toxicol Sci. 2009;112(2):303–310. http://dx.doi.org/10.1093/toxsci/kfp206 19770484
73 Kociba RJ Keyes DG Beyer JE Carreon RM Wade CE Dittenber DA Kalnins RP Frauson LE Park CN Barnard SD Results of a two-year chronic toxicity and oncogenicity study of 2,3,7,8-tetrachlorodibenzo-p-dioxin in rats. Toxicol Appl Pharmacol. 1978;46(2):279–303. http://dx.doi.org/10.1016/0041-008X(78)90075-3 734660
74 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 3,3',4,4',5-pentachlorobiphenyl (PCB 126) (CASRN 57465-28-8) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: US Departments of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 520. NIH Publication No. 06-4454.
75 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) (CASRN 1746-01-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: US Departments of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 521. NIH Publication No. 06-4455.
76 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,3,4,7,8-pentachlorodibenzofuran (PeCDF) (CASRN 57117-31-4) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: US Departments of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 525. NIH Publication No. 06-4461.
77 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of a mixture of TCDD, PeCDF, and PCB 126 (CASRNs 1746-01-6, 57117-31-4, and 57465-28-8) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: US Departments of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 526. NIH Publication No. 06-4462.
78 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,2',4,4',5,5'-hexachlorobiphenyl (PCB 153) (CASRN 35065-27-1) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: US Departments of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 529. NIH Publication No. 06-4465.
79 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of a binary mixture of PCB 126 and PCB 153 (CASRN 57465-28-8 and 35065-27-1) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: US Departments of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 530. NIH Publication No. 06-4466.
80 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of a binary mixture of PCB 126 and PCB 118 (CASRN 57465-28-8 and 31508-00-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: US Departments of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 531. NIH Publication No. 07-4467.
81 Schenkman JB Cinti DL Preparation of microsomes with calcium. Methods Enzymol. 1978;52:83–89. http://dx.doi.org/10.1016/S0076-6879(78)52008-9 672658
82 Lowry OH Rosebrough NJ Farr AL Randall RJ Protein measurement with the Folin phenol reagent. J Biol Chem. 1951;193(1):265–275. 14907713
83 Chang TK Waxman DJ Enzymatic analysis of cDNA-expressed human CYP1A1, CYP1A2, and CYP1B1 with 7-ethoxyresorufin as substrate. Methods Mol Biol. 1998;107:103–109. 14577217
84 Hamm JT Ross DG Richardson VM Diliberto JJ Birnbaum LS Methoxyresorufin: an inappropriate substrate for CYP1A2 in the mouse. Biochem Pharmacol. 1998;56(12):1657–1660. http://dx.doi.org/10.1016/S0006-2952(98)00241-X 9973187
85 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
86 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
87 Boyle MC Crabbs TA Wyde ME Painter JT Hill GD Malarkey DE Lieuallen WG Nyska A Intestinal lymphangiectasis and lipidosis in rats following subchronic exposure to indole-3-carbinol via oral gavage. Toxicol Pathol. 2012;40(4):561–576. http://dx.doi.org/10.1177/0192623311436178 22328411
88 McConnell EE Solleveld HA Swenberg JA Boorman GA Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986;76(2):283–289. 3456066
89 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53:457–481. 10.1080/01621459.1958.10501452
90 Cox DR Regression models and life-tables. J R Stat Soc [Ser A]. 1972;B34:187–220.
91 Tarone RE Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690. 10.1093/biomet/62.3.679
92 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. http://dx.doi.org/10.2307/2531856 3390507
93 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. http://dx.doi.org/10.1016/0272-0590(89)90004-3 2744275
94 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London: Chapman and Hall; 1997.
95 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
96 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. http://dx.doi.org/10.2307/2532200 8241374
97 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
98 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
99 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
100 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
101 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
102 Dunn OJ Multiple comparison using rank sums. Technometrics. 1964;6:241–252. 10.1080/00401706.1964.10490181
103 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1-2):133–145. 10.1093/biomet/41.1-2.133
104 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York: McGraw-HIll Book Company, Inc.; 1957. p. 276-278, 412. 10.2307/2332898
105 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
106 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. 10.2307/2531963 3567307
107 Haseman JK Rao GN Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992;20(1):52–60. http://dx.doi.org/10.1177/019262339202000107 1411131
108 Haseman JK Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26(2):191–200. 10.1177/009286159202600210
109 Haseman JK Data analysis: statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995;21(1):52–59, discussion 81–86. http://dx.doi.org/10.1006/rtph.1995.1009 7784636
110 Code of Federal Regulations (CFR). 21:Part 58.
111 Schmid W The micronucleus test. Mutat Res. 1975;31(1):9–15. http://dx.doi.org/10.1016/0165-1161(75)90058-8 48190
112 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983;123(1):61–118. http://dx.doi.org/10.1016/0165-1110(83)90047-7 6888413
113 Miller JA Miller EC Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH Watson JD Winsten JAeditors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
114 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67(2):233–241. 7021938
115 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA Flamm WG Lorentzen RJeditors. Advances in Modern Environmental Toxicology: Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co. Inc.; 1985. p. 13–59.
116 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991;257(3):229–306. http://dx.doi.org/10.1016/0165-1110(91)90003-E 1707500
117 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987;236(4804):933–941. http://dx.doi.org/10.1126/science.3554512 3554512
118 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RW Holden HE Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990;16 Suppl 18:1–14. http://dx.doi.org/10.1002/em.2850160502 2091921
119 Shelby MD Erexson GL Hook GJ Tice RR Evaluation of a three-exposure mouse bone marrow micronucleus protocol: results with 49 chemicals. Environ Mol Mutagen. 1993;21(2):160–179. http://dx.doi.org/10.1002/em.2850210210 8444144
120 Shelby MD Witt KL Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995;25(4):302–313. http://dx.doi.org/10.1002/em.2850250407 7607185
121 Witt KL Knapton A Wehr CM Hook GJ Mirsalis J Shelby MD MacGregor JT Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
122 Baldwin WS LeBlanc GA The anti-carcinogenic plant compound indole-3-carbinol differentially modulates P450-mediated steroid hydroxylase activities in mice. Chem Biol Interact. 1992;83(2):155–169. 10.1016/0009-2797(92)90043-K 1505058
123 Horn TL Reichert MA Bliss RL Malejka-Giganti D Modulations of P450 mRNA in liver and mammary gland and P450 activities and metabolism of estrogen in liver by treatment of rats with indole-3-carbinol. Biochem Pharmacol. 2002;64(3):393–404. http://dx.doi.org/10.1016/S0006-2952(02)01190-5 12147290
124 Szaefer H Krajka-Kuźniak V Bartoszek A Baer-Dubowska W Modulation of carcinogen metabolizing cytochromes P450 in rat liver and kidney by cabbage and sauerkraut juices: comparison with the effects of indole-3-carbinol and phenethyl isothiocyanate. Phytother Res. 2012;26(8):1148–1155. http://dx.doi.org/10.1002/ptr.3692 22173777
125 Sparnins VL Venegas PL Wattenberg LW Glutathione S-transferase activity: enhancement by compounds inhibiting chemical carcinogenesis and by dietary constituents. J Natl Cancer Inst. 1982;68(3):493–496. 6278195
126 Bradfield CA Bjeldanes LF Effect of dietary indole-3-carbinol on intestinal and hepatic monooxygenase, glutathione S-transferase and epoxide hydrolase activities in the rat. Food Chem Toxicol. 1984;22(12):977–982. http://dx.doi.org/10.1016/0278-6915(84)90147-9 6334634
127 Whitlock JP Jr Induction of cytochrome P4501A1. Annu Rev Pharmacol Toxicol. 1999;39(1):103–125. http://dx.doi.org/10.1146/annurev.pharmtox.39.1.103 10331078
128 Denison MS Nagy SR Activation of the aryl hydrocarbon receptor by structurally diverse exogenous and endogenous chemicals. Annu Rev Pharmacol Toxicol. 2003;43(1):309–334. http://dx.doi.org/10.1146/annurev.pharmtox.43.100901.135828 12540743
129 Mimura J Fujii-Kuriyama Y Functional role of AhR in the expression of toxic effects by TCDD. Biochim Biophys Acta. 2003;1619(3):263–268. http://dx.doi.org/10.1016/S0304-4165(02)00485-3 12573486
130 Hankinson O Role of coactivators in transcriptional activation by the aryl hydrocarbon receptor. Arch Biochem Biophys. 2005;433(2):379–386. http://dx.doi.org/10.1016/j.abb.2004.09.031 15581594
131 Whitlock JP Jr Mechanistic aspects of dioxin action. Chem Res Toxicol. 1993;6(6):754–763. http://dx.doi.org/10.1021/tx00036a003 8117913
132 Van den Berg M Birnbaum L Bosveld AT Brunström B Cook P Feeley M Giesy JP Hanberg A Hasegawa R Kennedy SW Toxic equivalency factors (TEFs) for PCBs, PCDDs, PCDFs for humans and wildlife. Environ Health Perspect. 1998;106(12):775–792. http://dx.doi.org/10.1289/ehp.98106775 9831538
133 Park JY Shigenaga MK Ames BN Induction of cytochrome P4501A1 by 2,3,7,8-tetrachlorodibenzo-p-dioxin or indolo(3,2-b)carbazole is associated with oxidative DNA damage. Proc Natl Acad Sci USA. 1996;93(6):2322–2327. http://dx.doi.org/10.1073/pnas.93.6.2322 8637871
134 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,3',4,4',5-pentachlorobiphenyl (PCB 118) (CASRN 31508-00-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: US Departments of Health and Human Services, Public Health Service, National Institutes of Health; 2010. Technical Report Series No. 531. NIH Publication No. 07-4467.
135 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992;19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
136 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990;14(3):513–522. http://dx.doi.org/10.1016/0272-0590(90)90255-I 2111256
137 Hwu JR Wein YS Leu Y-J Calcium metal in liquid ammonia for selective reduction of organic compounds. J Org Chem. 1996;61(4):1493–1499. 10.1021/jo951219c
138 Pouchert CJ, editor. The Aldrich Library of FT-IR Spectra, 2nd ed. Vol. 3, spectrum 3.3577C. Milwaukee, WI: Aldrich Chemical Company; 1997.
139 Irizarry RA Bolstad BM Collin F Cope LM Hobbs B Speed TP Summaries of Affymetrix GeneChip probe level data. Nucleic Acids Res. 2003;31(4):e15. http://dx.doi.org/10.1093/nar/gng015 12582260
140 Omiecinski CJ Vanden Heuvel JP Perdew GH Peters JM Xenobiotic metabolism, disposition, and regulation by receptors: from biochemical phenomenon to predictors of major toxicities. Toxicol Sci. 2011;120 Suppl 1:S49–S75. http://dx.doi.org/10.1093/toxsci/kfq338 21059794
141 Dhakshinamoorthy S Jaiswal AK Small maf (MafG and MafK) proteins negatively regulate antioxidant response element-mediated expression and antioxidant induction of the NAD(P)H:Quinone oxidoreductase1 gene. J Biol Chem. 2000;275(51):40134–40141. http://dx.doi.org/10.1074/jbc.M003531200 11013233
142 Kensler TW Curphey TJ Maxiutenko Y Roebuck BD Chemoprotection by organosulfur inducers of phase 2 enzymes: dithiolethiones and dithiins. Drug Metabol Drug Interact. 2000;17(1-4):3–22. http://dx.doi.org/10.1515/DMDI.2000.17.1-4.3 11201301
143 Kong AN Yu R Hebbar V Chen C Owuor E Hu R Ee R Mandlekar S Signal transduction events elicited by cancer prevention compounds. Mutat Res. 2001;480-481:231–241. http://dx.doi.org/10.1016/S0027-5107(01)00182-8 11506817
144 Kwak MK Itoh K Yamamoto M Sutter TR Kensler TW Role of transcription factor Nrf2 in the induction of hepatic phase 2 and antioxidative enzymes in vivo by the cancer chemoprotective agent, 3H-1, 2-dimethiole-3-thione. Mol Med. 2001;7(2):135–145. http://dx.doi.org/10.1007/BF03401947 11471548
145 Hernandez JP Mota LC Baldwin WS Activation of CAR and PXR by dietary, environmental and occupational chemicals alters drug metabolism, intermediary metabolism, and cell proliferation. Curr Pharmacogenomics Person Med. 2009;7(2):81–105. http://dx.doi.org/10.2174/187569209788654005 20871735
146 Ma Q Role of nrf2 in oxidative stress and toxicity. Annu Rev Pharmacol Toxicol. 2013;53:401–426. http://dx.doi.org/10.1146/annurev-pharmtox-011112-140320 23294312
147 Refetoff S Inherited thyroxine-binding globulin abnormalities in man. Endocr Rev. 1989;10(3):275–293. http://dx.doi.org/10.1210/edrv-10-3-275 2506004
148 Ameri K Harris AL Activating transcription factor 4. Int J Biochem Cell Biol. 2008;40(1):14–21. http://dx.doi.org/10.1016/j.biocel.2007.01.020 17466566
149 Polyak K Xia Y Zweier JL Kinzler KW Vogelstein B A model for p53-induced apoptosis. Nature. 1997;389(6648):300–305. http://dx.doi.org/10.1038/38525 9305847
150 Brew CT Aronchik I Hsu JC Sheen JH Dickson RB Bjeldanes LF Firestone GL Indole-3-carbinol activates the ATM signaling pathway independent of DNA damage to stabilize p53 and induce G1 arrest of human mammary epithelial cells. Int J Cancer. 2006;118(4):857–868. http://dx.doi.org/10.1002/ijc.21445 16152627