# Conclusions

Under the conditions of these 2-year gavage studies, there was no evidence of carcinogenic activity^1^ of indole-3-carbinol in male Harlan Sprague Dawley rats administered 75, 150, or 300 mg/kg. There was some evidence of carcinogenic activity of indole-3-carbinol in female Harlan Sprague Dawley rats based on increased incidences of malignant uterine neoplasms (primarily adenocarcinoma). The occurrences of fibroma and fibrosarcoma in the skin may have been related to indole-3-carbinol administration. There was clear evidence of carcinogenic activity of indole-3-carbinol in male B6C3F1/N mice based on increased incidences of liver neoplasms (hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma). There was no evidence of carcinogenic activity of indole-3-carbinol in female B6C3F1/N mice administered 62.5, 125, or 250 mg/kg.

1 See Explanation of Levels of Evidence of Carcinogenic Activity. A summary of the Peer Review Panel comments and the public discussion on this Technical Report appears in Appendix M.

Administration of indole-3-carbinol caused increased incidences of nonneoplastic lesions in the small intestine, mesenteric lymph node, and liver of male and female rats, the thyroid gland of male rats, the uterus of female rats, and the liver, glandular stomach, and nose of male and female mice.