# Discussion

Indole-3-carbinol was nominated by the National Cancer Institute based on its growing use as a dietary supplement and its potential use as a therapeutic agent for the prevention of various types of cancer. While substantial evidence exists that indole-3-carbinol can reduce the risk of cancers induced by several known carcinogens when administered to animals, indole-3-carbinol can also function as an initiator and tumor promoter in certain models. The carcinogenic potential of indole-3-carbinol has not been studied in a 2-year bioassay.

The effects of gavage exposure to indole-3-carbinol for 3 months or 2 years were studied in male and female F344/N (3-month study) or Harlan Sprague Dawley (2-year study) rats and B6C3F1/N mice at doses up to 300 mg/kg for rats and 250 mg/kg for mice. In general, 3 months of exposure to indole-3-carbinol exhibited more effects in F344/N rats than in mice. Decreased body weight gains were observed in male F344/N rats at 300 mg/kg, but not in female F344/N rats or either sex of mice. In F344/N rats, changes in organ weights were observed at all administered doses of indole-3-carbinol. Increased liver and kidney weights were observed in both sexes, and decreased thymus weights were observed only in female rats. No corresponding histopathology was noted in the liver, kidney, or thymus in either sex of F344/N rats. In male and female mice, the only treatment-related effects observed were increased liver weights in males at 125 mg/kg or greater and in females at 15.6 mg/kg or greater.

Increased liver weights have been reported in rats exposed to indole-3-carbinol in the presence and absence of hepatocyte hypertrophy^20; 21^. In the current 3-month studies, changes in liver weights in F344/N rats and mice were not accompanied by hepatocyte hypertrophy. In 28-day recovery studies, Crowell et al.^20^ demonstrated that the increased liver weights and hepatic hypertrophy induced by indole-3-carbinol were reversible effects.

In the liver, treatment-related increases in acetanilide-4-hydroxylase (A4H) and 7-ethoxyresorufin-O-deethylase (EROD) activities were observed in both sexes of F344/N rats and mice and the magnitude of induction was greater in rats than in mice. The induction of hepatic CYP1A1 and 1A2 has been widely demonstrated in repeat-dose studies of indole-3-carbinol^20; 21; 122-124^. Other studies in the literature have demonstrated that exposure to indole-3-carbinol induces other hepatic enzymes in rodents, including glutathione-S-transferase, UDP-glucuronosyl transferase, glutathione reductase, and quinone reductase^19; 125; 126^. In the current studies, increased pulmonary EROD activity was observed in F344/N rats, but not mice exposed to indole-3-carbinol.

Expression of CYP1A1 and 1A2 serves as a useful marker for activation of the aryl hydrocarbon receptor^127-130^. The induction of CYP1A1 is a very sensitive response to exposure to 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) and other dioxin-like compounds^131^ which are potent inducers in many tissues including the liver, lung, kidney, nasal passages, and small intestine. In fact, in many cases the relative potency for induction of CYP1A1 has provided the basis for establishing Toxic Equivalency Factors for the activity of dioxin-like compounds^132^. While increased activity or expression of CYP1A1 and 1A2 are widely accepted as sensitive markers for exposure to AhR-agonists, the potential role of the induction of hepatic CYP1A1 and 1A2 enzymes in the mechanism of toxicity and carcinogenicity of dioxin-like compounds is not fully understood. However, it has been hypothesized that AhR-dependent induction of the CYP1 family of cytochromes P450 may lead to induction of oxidative stress due to inefficient electron transfer during P450 metabolism^133^. CYP1A1 is also known to metabolize carcinogens like benzo[a]pyrene and aflatoxin B1 to epoxide intermediates. Therefore, the induction of these enzymes may have implications in coexposures to indole-3-carbinol and other such chemicals in humans.

In both sexes of F344/N rats, indole-3-carbinol administration for 3 months increased the incidences of lymphatic ectasia in the duodenum and jejunum, lipidosis in the lamina propria of the small intestine, and lymphatic dilatation in the mesenteric lymph node. To further clarify and elucidate the pathogenesis of these lesions, special evaluations were conducted on tissues from 1-week and 4-week euthanasia of special intestine study male Sprague Dawley rats in the 2-year bioassay^87^. Because different rat strains were evaluated in the 3-month and 2-year studies, the concordance of the development of these lesions between F344/N rats and Harlan Sprague Dawley rats was also evaluated. In both strains of rats, treatment-related dilatation of lymphatics (lymphangiectasis) of the duodenum, jejunum, and mesenteric lymph node was observed at 150 mg/kg or greater. Electron microscopy and special staining with Oil-red-O and Sudan Black confirmed extracellular lipid accumulation within the villar lamina propria, lacteals, and macrophages^87^. While lymphatic ectasia in the small intestine or mesenteric lymph node was observed in both strains of rats, it was not observed in B6C3F1/N mice administered indole-3-carbinol for 3 months or 2 years.

In the 2-year studies in Harlan Sprague Dawley rats, a positive trend in the incidences of uterine adenocarcinoma occurred in females; uterine masses observed grossly at necropsy were likely related to the increased incidences of uterine adenocarcinoma. The standard protocol for collection of uterine tissue outlined in the NTP Specifications for the Conduct of Toxicity and Carcinogenicity Studies requires that at necropsy a single transverse segment is collected from each uterine horn 0.5 cm from the cervix along with any grossly observed lesions; opening of the remaining segments of the horns is not required. The extended residual tissue review involved trimming, embedding and sectioning of the residual uterine tissue, cervix and vagina longitudinally. The reason for the residual tissue evaluation was to have a more comprehensive evaluation of the uteri in light of the occurrence of adenocarcinoma in the standard (initial) evaluation. During the extended review of the uteri, additional uterine masses were discovered mostly in uterine horns that were grossly dilated. The masses were small and would not have been discovered using the standard necropsy examination protocol unless the uterine horns were opened. During the extended microscopic evaluation, additional incidences of uterine adenocarcinomas and new incidences of adenomas were identified; adenomas were not diagnosed in the standard evaluation. In the combined standard and extended evaluations, the incidence of adenocarcinoma in the uterus was significantly increased in the 150 mg/kg group. The incidences of uterine adenoma were not significantly increased in the dosed groups.

Uterine adenocarcinomas are an uncommon background neoplasm in the Harlan Sprague Dawley rat. In the standard evaluation in the current 2-year study, no uterine adenocarcinomas were observed in vehicle control female rats. Based on the significant increase in the incidence of uterine adenocarcinomas in the 150 mg/kg group and the increased incidence in the 300 mg/kg group, these results were considered some evidence of carcinogenicity. In addition, the incidence of squamous metaplasia of the endometrium was significantly increased in 150 mg/kg female rats.

In the skin of female Sprague Dawley rats, there was a positive trend in the incidences of fibroma or fibrosarcoma (combined). Fibromas or fibrosarcomas were only observed in the vehicle control and 300 mg/kg groups. Because the incidence observed in the 300 mg/kg group was not significantly increased compared to the vehicle controls, this was an uncertain finding that may have been related to indole-3-carbinol administration.

In the thyroid gland of male Sprague Dawley rats, there were general, dose-dependent increases in the incidences and severities of follicular cell hypertrophy. While the thyroid gland has not been identified as a target organ for indole-3-carbinol exposure, indole-3-carbinol at 0.25% in the diet (total daily intake not provided) has previously been shown to promote thyroid gland follicular cell adenomas and adenocarcinomas in an initiation-promotion model^33^.

In the 2-year mouse studies, body weights were decreased by greater than 10% in 250 mg/kg female mice from weeks 32 to 92, but no treatment-related decreases in survival were noted in males or females. In male mice, treatment-related neoplasms occurred only in the liver, while nonneoplastic lesions occurred in the glandular stomach and the nose. In female mice, treatment-related nonneoplastic lesions occurred in the liver, glandular stomach, and nose.

In the liver, there were generally positive trends for the incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma as well as their combined incidences in indole-3-carbinol-treated male mice in the 2-year studies. Increased incidences of hepatocellular adenoma and hepatoblastoma occurred in 250 mg/kg males and included increased numbers of mice with multiple lesions. A significant increase in the incidence of multiple adenoma also occurred in 62.5 mg/kg males. An increased incidence of hepatocellular carcinoma occurred in 125 mg/kg males, but not in males administered 250 mg/kg. However, in early death animals the time to first observed incidence was 182 days less in the 250 mg/kg group than in the 125 mg/kg group, and 80 days less than in the vehicle controls. Although hepatocellular adenomas and hepatocellular carcinomas are relatively common neoplasms in male mice, the significantly increased incidences in indole-3-carbinol-treated males considerably exceeded the concurrent vehicle control and historical control rates. The combined incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma were significantly increased in 125 and 250 mg/kg males. Based on the observed increases, the incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma were considered related to indole-3-carbinol treatment and supportive of clear evidence of carcinogenicity in male mice.

Hepatic gene expression studies in 300 mg/kg females from the microarray study suggested the activation of multiple xenobiotic transcription factors in rat liver with the most pronounced activation being associated with AhR and Nrf2. Consistent with these findings was the up-regulation of genes associated with xenobiotic metabolism which suggests the potential for indole-3-carbinol to modify drug efficacy and safety. These findings are largely similar to results from other transcriptomic studies of indole-3-carbinol.

In the current 2-year study, treatment-related nonneoplastic lesions occurred in the glandular stomach and the nose of both male and female mice. Indole-3-carbinol-induced hyperplasia, pigmentation, and chronic inflammation in the glandular stomach occurred at lower doses in females (62.5 mg/kg) than in males (125 mg/kg). The spectra of nasal lesions in the olfactory and respiratory epithelia were similar in males and females. In both sexes, incidences of nerve atrophy, respiratory metaplasia and atrophy of the olfactory epithelium, and hyperplasia of the respiratory epithelium were significantly increased in mice administered 250 mg/kg. In addition, occurrences of olfactory epithelium necrosis and respiratory epithelium hyaline droplet accumulation in males and nasal inflammation in females were considered treatment-related. Nasal lesions have not been reported in shorter-term studies of indole-3-carbinol.

As an AhR agonist, indole-3-carbinol might be expected to elicit the same responses as other AhR agonists, most notably 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) and other dioxin-like compounds. However, it is important to note the absence of dioxin-like carcinogenicity in the current studies. In general, TCDD and other individual and relevant mixtures of dioxin-like compounds induce a characteristic spectrum of neoplasms in the three main target organs: liver, lung, and oral mucosa^74-80; 134^. In the liver, TCDD^75^, 3,3′,4,4′,5-pentachloro-biphenyl (PCB 126)^74^, 2,3,4,7,8-penta-chlorodibenzofuran (PeCDF)^76^, 2,3′,4,4′,5-pentachlorobiphenyl (PCB 118)^134^, and a tertiary mixture of TCDD, PCB 126, and PeCDF^77^ predominantly induce cholangiocarcinomas and hepatocellular adenomas. In addition to these neoplasms, a binary mixture of PCB 126 and PCB 153^79^ and a binary mixture of PCB 126 and PCB 118^80^ induce hepatocarcinomas. In general, exposure to these dioxin-like compounds induces cystic keratinizing epitheliomas in the lung^74; 75; 77-80; 134^. Gingival squamous cell carcinomas were induced by exposure to TCDD^75^, PCB 126^74^, PeCDF^76^, a binary mixture of PCB 126 and PCB 118^80^, and a binary mixture of PCB 126 and PCB 153^79^. None of these characteristic neoplasms induced by exposure to persistent dioxin-like compounds were observed in rats exposed to indole-3-carbinol, even at doses that elicited comparable fold-inductions of hepatic EROD activity, a marker of AhR activation. In addition to hepatic neoplasms, TCDD and other dioxin-like compounds induce dose-dependent increases in the incidences of a broad spectrum of nonneoplastic liver lesions, including hepatocyte hypertrophy, multinucleated hepatocytes, fatty change, bile duct hyperplasia and cyst, cholangiofibrosis, and oval cell hyperplasia^74-77; 79; 80; 134^. This broad spectrum of lesions was not observed in rats exposed to indole-3-carbinol for 2 years. Aside from increased liver weight, the only treatment-related lesions observed in the liver were increased incidences of clear cell and eosinophilic foci in female rats, and increased incidences of bile duct cysts in male rats.

Chronic exposure to dioxin-like compounds also induces nonneoplastic lesions in other tissues, including the lung, adrenal cortex, pancreas, kidney, heart, thyroid gland, and thymus^74-77; 80; 134^. The spectrum of toxicity and the specificity of target organs vary slightly between dioxin-like congeners, with exposure to some congeners affecting additional tissues. However, the general profiles of toxicity and carcinogenicity are similar. Therefore, the differences in the observed neoplastic and nonneoplastic responses between indole-3-carbinol and the dioxins demonstrate a clear difference between indole-3-carbinol and other persistent dioxin-like compounds.