# Results

## Three-month Study in F344/N Rats

All rats survived to the end of the study (Table 2). The mean body weight gain of males in the 300 mg/kg group was significantly less than that of the vehicle controls (Table 2; Figure 3). There were no clinical findings related to administration of indole-3-carbinol.

Table 2 Survival and Body Weights of F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 103 ± 1 | 309 ± 5 | 206 ± 4
18.75 | 10/10 | 103 ± 1 | 320 ± 9 | 217 ± 8 | 103
37.5 | 10/10 | 107 ± 1* | 325 ± 7 | 218 ± 7 | 105
75 | 10/10 | 105 ± 1 | 321 ± 8 | 215 ± 7 | 104
150 | 10/10 | 104 ± 1 | 309 ± 8 | 204 ± 8 | 100
300 | 10/10 | 104 ± 1 | 285 ± 6 | 182 ± 6* | 92
Female
0 | 10/10 | 91 ± 2 | 189 ± 2 | 99 ± 3
18.75 | 10/10 | 90 ± 1 | 192 ± 3 | 102 ± 3 | 101
37.5 | 10/10 | 90 ± 2 | 195 ± 2 | 105 ± 2 | 103
75 | 10/10 | 90 ± 1 | 185 ± 3 | 95 ± 3 | 98
150 | 10/10 | 89 ± 2 | 183 ± 3 | 94 ± 2 | 97
300 | 10/10 | 91 ± 2 | 183 ± 3 | 92 ± 3 | 97

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 3

Growth Curves for F344/N Rats Administered Indole-3-carbinol by Gavage for Three Months

There were no changes in the hematology and clinical chemistry data of rats that were considered attributable to indole-3-carbinol administration (Table F-1).

The absolute and relative liver weights of all dosed groups of males and females were significantly increased compared to the vehicle controls (Table 3 and Table G-1). The relative kidney weights of 75 mg/kg or greater males and all dosed groups of females were significantly increased, as were the absolute kidney weights of 75 mg/kg males and 18.75, 37.5, and 300 mg/kg females. The absolute and relative thymus weights of 75 mg/kg or greater females were significantly decreased. Microscopically, there were no histopathologic lesions that correlated with these organ weight changes.

Table 3 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 18.75 mg/kg | 37.5 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 309 ± 5 | 320 ± 9 | 325 ± 7 | 321 ± 8 | 309 ± 8 | 285 ± 6
R. Kidney
Absolute | 0.86 ± 0.02 | 0.94 ± 0.02 | 0.93 ± 0.03 | 0.97 ± 0.03* | 0.92 ± 0.03 | 0.90 ± 0.02
Relative | 2.785 ± 0.038 | 2.940 ± 0.033 | 2.844 ± 0.054 | 3.012 ± 0.038** | 2.981 ± 0.048** | 3.152 ± 0.055**
Liver
Absolute | 9.98 ± 0.30 | 11.19 ± 0.40* | 11.20 ± 0.40* | 11.85 ± 0.36** | 12.07 ± 0.38** | 12.57 ± 0.33**
Relative | 32.205 ± 0.594 | 34.924 ± 0.481** | 34.382 ± 0.716** | 36.941 ± 0.435** | 39.050 ± 0.472** | 44.047 ± 0.729**
Female
Necropsy body wt | 189 ± 2 | 192 ± 3 | 195 ± 2 | 185 ± 3 | 183 ± 3 | 183 ± 3
R. Kidney
Absolute | 0.57 ± 0.01 | 0.66 ± 0.01** | 0.63 ± 0.01* | 0.61 ± 0.01 | 0.62 ± 0.01 | 0.63 ± 0.02*
Relative | 3.034 ± 0.056 | 3.447 ± 0.053** | 3.233 ± 0.075** | 3.277 ± 0.046** | 3.375 ± 0.064** | 3.436 ± 0.063**
Liver
Absolute | 5.08 ± 0.11 | 5.94 ± 0.11** | 5.98 ± 0.07** | 5.92 ± 0.13** | 6.34 ± 0.14** | 6.92 ± 0.11**
Relative | 26.804 ± 0.441 | 30.985 ± 0.566** | 30.790 ± 0.547** | 32.061 ± 0.548** | 34.660 ± 0.614** | 37.857 ± 0.319**
Thymus
Absolute | 0.178 ± 0.005 | 0.173 ± 0.005 | 0.162 ± 0.007 | 0.149 ± 0.008** | 0.151 ± 0.007** | 0.145 ± 0.006**
Relative | 0.943 ± 0.027 | 0.901 ± 0.022 | 0.836 ± 0.042* | 0.805 ± 0.036** | 0.825 ± 0.029** | 0.792 ± 0.031**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Liver and lung samples were collected for determinations of P450 enzyme activities (Table 4). Microsomal suspensions were prepared from liver samples and were assayed for 7-ethoxyresorufin-O-deethylase (EROD) activity (a marker for CYP1A1 activity) and acetanilide-4-hydroxylase (A4H) activity (a marker for CYP1A2 activity). Microsomal samples from lung were analyzed for EROD activity only. In the liver, there were significant and dose-dependent increases in A4H and EROD activities in all dosed groups of male and female rats. Maximal inductions of A4H and EROD activities in males were greater than 5-fold and 100-fold, respectively, compared to the vehicle controls. In females, A4H and EROD activities were maximally increased 4.7-fold and 80-fold, respectively. Pulmonary EROD activity was significantly increased in all dosed groups of females and in males administered 75 mg/kg or greater.

Table 4 Liver and Lung Cytochrome P450 Data for F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 18.75 mg/kg | 37.5 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
Male
Liver Microsomes
n | 9 | 10 | 10 | 10 | 10 | 9
A4H (nmol/minute per mg microsomal protein)
| 0.404 ± 0.027 | 0.627 ± 0.071* | 0.999 ± 0.067** | 1.187 ± 0.086** | 1.546 ± 0.071* | 2.045 ± 0.077**
EROD (pmol/minute per mg microsomal protein)
| 7.1 ± 1.4 | 40.8 ± 5.1** | 160.8 ± 9.6** | 303.1 ± 34.8** | 485.9 ± 49.0** | 774.6 ± 41.7**
Lung Microsomes
n | 8 | 9 | 10 | 10 | 10 | 10
EROD (pmol/minute per mg microsomal protein)
| ND | 0.033 ± 0.023 | 0.008 ± 0.008 | 0.160 ± 0.042** | 1.146 ± 0.218** | 1.227 ± 0.250**
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Liver Microsomes
A4H (nmol/minute per mg microsomal protein)
| 0.343 ± 0.026 | 0.652 ± 0.069** | 0.826 ± 0.017** | 0.973 ± 0.043** | 1.408 ± 0.105** | 1.621 ± 0.088**
EROD (pmol/minute per mg microsomal protein)
| 6.1 ± 1.1 | 70.7 ± 15.1** | 172.8 ± 15.0** | 236.5 ± 24.7** | 440.5 ± 41.3** | 495.4 ± 39.9**
Lung Microsomes
EROD (pmol/minute per mg microsomal protein)
| 0.006 ± 0.004 | 1.050 ± 0.205** | 2.711 ± 0.267** | 2.671 ± 0.540** | 2.747 ± 0.364** | 3.008 ± 0.333**

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s test.

** P ≤ 0.01.

ND = None detected.

^a^ Data are presented as mean ± standard error. A4H = acetanilide-4-hydroxylase; EROD = 7-ethoxyresorufin-O-deethylase;

There were no significant differences in reproductive tissue weights or spermatid or epididymal spermatozoal measurements of males administered 75, 150, or 300 mg/kg when compared to the vehicle control group; therefore, indole-3-carbinol did not exhibit the potential to be a reproductive toxicant in male rats (Table H-1). Indole-3-carbinol did exhibit the potential to be a female reproductive toxicant based on the increased estrous cycle length (approximately 1 day), and an additional day of diestrus (Table H-2 and Table H-3; Figure H-1). This was manifested as the probability of extended diestrus being significantly higher in the 300 mg/kg group than in the vehicle control group when estrous cyclicity was analyzed using Markov transition matrix analysis.

Dose-related increased incidences and severities of minimal to mild ectasia of the lymphatic vessels and lipidosis of the lamina propria occurred in the villi of the small intestines (duodenum and jejunum) of males and females (Table 5). Compared to the vehicle controls, these incidences were significantly increased in the duodenum of 150 and 300 mg/kg males and females and in the jejunum of 75 mg/kg or greater males and females. The severity of lymphatic ectasia was minimal to moderate in the jejunum and minimal to mild in the duodenum. Affected lymphatics were variably dilated, lined by a single layer of endothelial cells, and occasionally contained fibrillar amphophilic material. Within the stroma of affected villi, there were occasional macrophages that contained clear cytoplasmic vacuoles (lamina propria) consistent with accumulated lipid (fat). Lesions of moderate severity often disrupted the architecture of the villi. In general, lesions in the jejunum were more severe than those in the duodenum. The cytoplasmic vacuoles within macrophages in the lamina propria of the villi stained positively with special histochemical stains (Oil-red-O and Sudan Black) for lipid.

Table 5 Incidences of Selected Nonneoplastic Lesions in F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol

| Vehicle Control | 18.75 mg/kg | 37.5 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
Male
Intestine Small, Duodenum^a^ | 10 | 10 | 10 | 10 | 10 | 10
Lamina Propria, Lipidosis^b^ | 0 | 0 | 0 | 1 (1.0)^c^ | 10** (1.2) | 10** (2.2)
Lymphatic, Ectasia | 0 | 0 | 0 | 1 (1.0) | 10** (1.2) | 10** (2.2)
Intestine Small, Jejunum | 10 | 9 | 10 | 10 | 10 | 10
Lamina Propria, Lipidosis | 0 | 1 (1.0) | 1 (1.0) | 5** (1.0) | 10** (2.3) | 10** (3.5)
Lymphatic, Ectasia | 0 | 1 (1.0) | 1 (1.0) | 5** (1.0) | 10** (2.3) | 10** (3.5)
Lymph Node, Mesenteric | 7 | 10 | 9 | 10 | 10 | 10
Lipidosis | 0 | 2 (1.0) | 1 (1.0) | 0 | 5* (1.4) | 10** (3.0)
Lymphatic, Ectasia | 0 | 2 (1.0) | 1 (1.0) | 0 | 5* (1.4) | 10** (3.0)
Female
Intestine Small, Duodenum | 10 | 10 | 10 | 10 | 10 | 10
Lamina Propria, Lipidosis | 0 | 0 | 0 | 0 | 9** (1.0) | 10** (2.4)
Lymphatic, Ectasia | 0 | 0 | 0 | 0 | 9** (1.0) | 10** (2.4)
Intestine Small, Jejunum | 10 | 10 | 10 | 10 | 10 | 10
Lamina Propria, Lipidosis | 0 | 0 | 1 (1.0) | 10** (1.0) | 10** (1.8) | 10** (3.0)
Lymphatic, Ectasia | 0 | 0 | 1 (1.0) | 10** (1.0) | 10** (1.8) | 10** (3.0)
Lymph Node, Mesenteric | 10 | 10 | 10 | 10 | 10 | 10
Lipidosis | 0 | 0 | 0 | 0 | 3 (1.3) | 9** (3.2)
Lymphatic, Ectasia | 0 | 0 | 0 | 0 | 3 (1.3) | 9** (3.2)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the mesenteric lymph node, dose-related increased incidences and severities of lymphatic ectasia and lipidosis occurred in males and females. These incidences were significantly increased in 150 and 300 mg/kg males and 300 mg/kg females compared to the vehicle controls. These lesions occurred primarily in the subcapsular sinuses, occasionally in the cortex and paracortex, and infrequently in the medullary sinuses. Microscopically, the ectatic lymphatics were dilated and contained macrophages with foamy-appearing cytoplasm suggestive of accumulated lipid and occasional multiinucleated giant cells. Lesions of moderate or marked severity often disrupted the nodal architecture. The cytoplasmic vacuoles within macrophages stained positively with special histochemical stains (Oil-red-O and Sudan Black) for lipid.

Dose Selection Rationale: In the 3-month study, chemical-related increases in liver and kidney weights were observed in F344/N rats. Lymphatic ectasia occurred in the small intestine and mesenteric lymph node, but the lesions were not considered severe enough to compromise survival in the 2-year study. At 300 mg/kg, there were 7% and 12% decreases in body weight gains of females and males, respectively, and an 8% decrease in terminal body weight in males. Decreased body weights were not considered sufficient to exclude 300 mg/kg as the highest dose in the 2-year study. There was concern, however, that higher doses would not be well tolerated. At 300 mg/kg, the induction of hepatic EROD activity by indole-3-carbinol was greater than 100-fold in treated males and 80-fold in treated females compared to the vehicle controls. These levels of induction were equivalent to or exceeded the levels of induction at which exposure to dioxin-like aryl hydrocarbon receptor ligands such as PCB 126 and TCDD induced moderate to marked hepatotoxicity in 2-year studies^74; 75^. The only liver toxicity observed in these studies at 14 weeks was hepatocyte hypertrophy, a lesion previously observed in some studies of indole-3-carbinol. Based on the available data, the doses selected for the 2-year gavage study in Harlan Sprague Dawley rats were 75, 150, and 300 mg/kg.

## Two-year Study in Sprague Dawley Rats

### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 6 and in the Kaplan-Meier survival curves (Figure 4). Survival of dosed groups was similar to that of the vehicle control groups.

Table 6 Survival of Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Male
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^a^ | 0 | 0 | 0 | 1
Moribund | 14 | 23 | 15 | 20
Natural deaths | 16 | 14 | 18 | 17
Animals surviving to study termination | 20 | 13 | 17 | 12
Percent probability of survival at end of study^b^ | 40 | 26 | 34 | 25
Mean survival (days)^c^ | 644 | 617 | 640 | 615
Survival analysis^d^ | P = 0.224 | P = 0.084 | P = 0.557 | P = 0.100
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental deaths^a^ | 0 | 1 | 0 | 1
Moribund | 24 | 22 | 23 | 11
Natural deaths | 5 | 8 | 7 | 8
Animals surviving to study termination | 21 | 19^e^ | 20^e^ | 30
Percent probability of survival at end of study | 42 | 39 | 38 | 61
Mean survival (days) | 637 | 634 | 625 | 648
Survival analysis | P = 0.055N | P = 1.000 | P = 0.837 | P = 0.079N

^a^ Censored in the survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^d^ The result of the life table trend test^91^ is in the vehicle control column, and the results of the life table pairwise comparisons^90^ with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

^e^ Includes one animal that died during the last week of the study.

Figure 4

Kaplan-Meier Survival Curves for Sprague Dawley Rats Administered Indole-3-carbinol by Gavage for Two Years

### Body Weights and Clinical Findings

Mean body weights of dosed groups of males and females were similar to those of the vehicle controls throughout the study (Figure 5; Table 7 and Table 8). No clinical findings related to the administration of indole-3-carbinol were observed in males or females.

Figure 5

Growth Curves for Sprague Dawley Rats Administered Indole-3-carbinol by Gavage for Two Years

Table 7 Mean Body Weights and Survival of Male Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

Day | Vehicle Control | | 75 mg/kg | | | 150 mg/kg | | | 300 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 134 | 50 | 134 | 100 | 50 | 133 | 100 | 50 | 133 | 100 | 50
8 | 182 | 50 | 182 | 100 | 50 | 181 | 99 | 50 | 180 | 99 | 50
15 | 225 | 50 | 226 | 101 | 50 | 225 | 100 | 50 | 224 | 100 | 50
22 | 262 | 50 | 264 | 101 | 50 | 263 | 100 | 50 | 264 | 101 | 50
29 | 289 | 50 | 291 | 101 | 50 | 291 | 101 | 50 | 290 | 100 | 50
36 | 311 | 50 | 315 | 101 | 50 | 313 | 101 | 50 | 311 | 100 | 50
43 | 331 | 50 | 334 | 101 | 50 | 330 | 100 | 50 | 328 | 99 | 50
50 | 351 | 50 | 354 | 101 | 50 | 348 | 99 | 50 | 345 | 98 | 50
57 | 363 | 50 | 367 | 101 | 50 | 359 | 99 | 50 | 357 | 98 | 50
64 | 373 | 50 | 378 | 101 | 50 | 369 | 99 | 50 | 365 | 98 | 50
71 | 385 | 50 | 388 | 101 | 50 | 382 | 99 | 50 | 375 | 97 | 50
78 | 392 | 50 | 397 | 101 | 50 | 388 | 99 | 50 | 382 | 98 | 50
85 | 403 | 50 | 406 | 101 | 50 | 399 | 99 | 50 | 391 | 97 | 50
113 | 427 | 50 | 429 | 101 | 50 | 420 | 99 | 50 | 411 | 96 | 50
141 | 451 | 50 | 456 | 101 | 50 | 434 | 96 | 50 | 432 | 96 | 50
169 | 473 | 50 | 475 | 100 | 50 | 455 | 96 | 50 | 443 | 94 | 50
197 | 488 | 48 | 488 | 100 | 49 | 469 | 96 | 50 | 455 | 93 | 49
225 | 493 | 48 | 497 | 101 | 49 | 474 | 96 | 50 | 464 | 94 | 49
253 | 500 | 48 | 504 | 101 | 49 | 485 | 97 | 50 | 472 | 94 | 49
281 | 521 | 48 | 523 | 100 | 49 | 506 | 97 | 50 | 493 | 95 | 48
309 | 525 | 48 | 527 | 100 | 49 | 506 | 97 | 50 | 495 | 94 | 47
337 | 539 | 48 | 543 | 101 | 49 | 520 | 97 | 50 | 508 | 94 | 47
365 | 546 | 48 | 554 | 101 | 48 | 526 | 96 | 50 | 521 | 95 | 47
393 | 554 | 48 | 558 | 101 | 47 | 538 | 97 | 49 | 526 | 95 | 47
421 | 566 | 47 | 568 | 100 | 47 | 546 | 97 | 49 | 536 | 95 | 45
449 | 574 | 45 | 574 | 100 | 45 | 559 | 97 | 48 | 542 | 94 | 45
477 | 581 | 44 | 584 | 101 | 43 | 564 | 97 | 47 | 546 | 94 | 43
505 | 585 | 42 | 588 | 101 | 41 | 566 | 97 | 42 | 556 | 95 | 41
533 | 582 | 42 | 586 | 101 | 39 | 566 | 97 | 41 | 552 | 95 | 38
561 | 580 | 41 | 584 | 101 | 38 | 567 | 98 | 38 | 545 | 94 | 37
589 | 578 | 39 | 585 | 101 | 35 | 567 | 98 | 35 | 543 | 94 | 35
617 | 584 | 38 | 575 | 98 | 29 | 567 | 97 | 31 | 543 | 93 | 30
645 | 580 | 34 | 554 | 96 | 26 | 558 | 96 | 29 | 547 | 94 | 26
673 | 566 | 32 | 555 | 98 | 20 | 555 | 98 | 26 | 533 | 94 | 20
701 | 565 | 23 | 572 | 101 | 14 | 533 | 95 | 23 | 518 | 92 | 18
Mean for Weeks
1–13 | 308 | | 310 | 101 | | 306 | 99 | | 304 | 99
14–52 | 491 | | 494 | 101 | | 474 | 97 | | 464 | 95
53–101 | 572 | | 572 | 100 | | 555 | 97 | | 539 | 94

Table 8 Mean Body Weights and Survival of Female Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

Day | Vehicle Control | | 75 mg/kg | | | 150 mg/kg | | | 300 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 126 | 50 | 125 | 100 | 50 | 125 | 99 | 50 | 125 | 100 | 50
8 | 150 | 50 | 150 | 100 | 50 | 149 | 99 | 50 | 148 | 99 | 50
15 | 172 | 50 | 172 | 100 | 50 | 170 | 99 | 50 | 171 | 99 | 50
22 | 190 | 50 | 189 | 99 | 50 | 187 | 98 | 50 | 187 | 99 | 50
29 | 202 | 50 | 203 | 100 | 50 | 198 | 98 | 50 | 197 | 97 | 50
36 | 213 | 50 | 212 | 100 | 50 | 206 | 97 | 50 | 205 | 96 | 50
43 | 221 | 50 | 220 | 99 | 50 | 215 | 97 | 50 | 212 | 96 | 50
50 | 228 | 50 | 227 | 100 | 50 | 222 | 98 | 50 | 217 | 95 | 50
57 | 233 | 50 | 230 | 99 | 50 | 222 | 95 | 50 | 222 | 95 | 50
64 | 237 | 50 | 233 | 98 | 50 | 227 | 96 | 50 | 225 | 95 | 50
71 | 240 | 50 | 237 | 99 | 50 | 231 | 96 | 50 | 228 | 95 | 50
78 | 243 | 50 | 239 | 99 | 50 | 234 | 97 | 50 | 230 | 95 | 50
85 | 246 | 50 | 243 | 99 | 50 | 236 | 96 | 50 | 233 | 94 | 50
113 | 254 | 50 | 251 | 99 | 50 | 244 | 96 | 50 | 241 | 95 | 50
141 | 263 | 50 | 260 | 99 | 50 | 253 | 96 | 50 | 248 | 94 | 50
169 | 268 | 50 | 263 | 98 | 50 | 255 | 95 | 49 | 250 | 93 | 50
197 | 276 | 50 | 271 | 98 | 49 | 262 | 95 | 48 | 257 | 93 | 46
225 | 275 | 50 | 273 | 99 | 49 | 262 | 95 | 48 | 257 | 93 | 46
253 | 277 | 50 | 273 | 99 | 49 | 264 | 95 | 48 | 262 | 94 | 46
281 | 285 | 50 | 283 | 99 | 49 | 272 | 96 | 48 | 271 | 95 | 46
309 | 285 | 49 | 285 | 100 | 49 | 275 | 96 | 47 | 274 | 96 | 46
337 | 288 | 49 | 290 | 101 | 47 | 275 | 96 | 46 | 282 | 98 | 46
365 | 295 | 49 | 294 | 100 | 47 | 279 | 94 | 46 | 286 | 97 | 45
393 | 302 | 47 | 301 | 100 | 45 | 285 | 94 | 45 | 290 | 96 | 45
421 | 307 | 47 | 306 | 100 | 44 | 287 | 93 | 44 | 296 | 96 | 44
449 | 315 | 44 | 312 | 99 | 44 | 292 | 93 | 43 | 299 | 95 | 44
477 | 323 | 44 | 319 | 99 | 43 | 297 | 92 | 43 | 305 | 94 | 44
505 | 329 | 42 | 322 | 98 | 41 | 301 | 92 | 43 | 309 | 94 | 44
533 | 331 | 40 | 324 | 98 | 39 | 303 | 92 | 41 | 311 | 94 | 44
561 | 335 | 37 | 330 | 99 | 39 | 314 | 94 | 40 | 317 | 95 | 44
589 | 338 | 37 | 334 | 99 | 39 | 318 | 94 | 40 | 320 | 95 | 42
617 | 342 | 33 | 338 | 99 | 37 | 314 | 92 | 34 | 322 | 94 | 40
645 | 350 | 28 | 343 | 98 | 31 | 319 | 91 | 28 | 329 | 94 | 36
673 | 346 | 27 | 338 | 98 | 26 | 321 | 93 | 24 | 326 | 94 | 35
701 | 353 | 24 | 340 | 96 | 26 | 313 | 89 | 21 | 325 | 92 | 31
Mean for Weeks
1–13 | 208 | | 206 | 99 | | 202 | 97 | | 200 | 96
14–52 | 275 | | 272 | 99 | | 262 | 95 | | 260 | 95
53–101 | 328 | | 323 | 98 | | 303 | 92 | | 310 | 95

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the uterus, skin, small intestine (duodenum and jejunum), mesenteric lymph node, liver, thyroid gland, and pituitary gland. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

Uterus: In the standard evaluation, the incidences of adenocarcinoma occurred with a positive trend and were increased in all dosed groups (Table 9, Table B-1, and Table B-2). Although the increased incidences of adenocarcinoma were not statistically significant, the incidences in the 150 and 300 mg/kg groups exceeded the historical control range for corn oil gavage studies (Table 9 and Table B-3). In the extended evaluation, additional neoplasms and nonneoplastic proliferative lesions were diagnosed in the uteri of the vehicle control and dosed groups. In addition, previously undiagnosed types of neoplasms and nonneoplastic proliferative lesions were diagnosed in the uteri of the vehicle control and dosed groups including atypical hyperplasias, low incidences of adenomas in each of the dosed groups, and one adenosquamous carcinoma and one benign basosquamous tumor each in the 150 mg/kg group (Table 9 and Table B-2).

Table 9 Incidences of Neoplasms and Nonneoplastic Lesions of the Uterus in Female Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Standard Evaluation
Number Necropsied | 50 | 50 | 50 | 50
Endometrium, Metaplasia, Squamous^a^ | 12 (1.9)^b^ | 18 (2.2) | 20* (2.1) | 11 (1.8)
Adenocarcinoma, Multiple | 0 | 0 | 0 | 1
Adenocarcinoma (includes multiple)^c^
Overall rate^d^ | 0/50 (0%) | 1/50 (2%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate^e^ | 0.0% | 2.7% | 10.9% | 9.8%
Terminal rate^f^ | 0/21 (0%) | 0/19 (0%) | 1/19 (5%) | 2/30 (7%)
First incidence (days) | –^h^ | 645 | 608 | 645
Poly-3 test^g^ | P = 0.040 | P = 0.503 | P = 0.059 | P = 0.074
Extended Evaluation
Number Necropsied | 50 | 50 | 50 | 50
Endometrium, Metaplasia, Squamous | 38 | 33 | 35 | 27**
Endometrium, Hyperplasia, Atypical | 15 | 14 | 21 | 16
Adenoma | 0 | 2 | 1 | 1
Basosquamous Tumor, Benign | 0 | 0 | 1 | 0
Adenocarcinoma, Multiple | 1 | 0 | 3 | 2
Adenocarcinoma (includes multiple)
Overall rate | 5/50 (10%) | 3/50 (6%) | 10/50 (20%) | 8/50 (16%)
Adjusted rate | 13.7% | 8.2% | 26.9% | 19.8%
Terminal rate | 3/21 (14%) | 2/19 (11%) | 5/19 (26%) | 7/30 (23%)
First incidence (days) | 719 | 719 | 615 | 674
Poly-3 test | P = 0.158 | P = 0.351N | P = 0.127 | P = 0.340
Adenoma or Adenocarcinoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 11/50 (22%) | 9/50 (18%)
Adjusted rate | 13.7% | 13.5% | 29.6% | 22.3%
Terminal rate | 3/21 (14%) | 3/19 (16%) | 6/19 (32%) | 8/30 (27%)
First incidence (days) | 719 | 645 | 615 | 674
Poly-3 test | P = 0.146 | P = 0.624N | P = 0.080 | P = 0.247
Adenosquamous Carcinoma | 0 | 0 | 1 | 0
Standard and Extended Evaluations (Combined)
Number Necropsied | 50 | 50 | 50 | 50
Endometrium, Metaplasia, Squamous | 38 | 33 | 36 | 27**
Endometrium, Hyperplasia, Atypical | 15 | 14 | 21 | 16
Adenoma | 0 | 2 | 1 | 1
Basosquamous Tumor, Benign | 0 | 0 | 1 | 0
Adenocarcinoma, Multiple | 1 | 0 | 3 | 2
Adenocarcinoma (includes multiple) | 5 | 4 | 13* | 10
Adenoma or Adenocarcinoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 14/50 (28%) | 11/50 (22%)
Adjusted rate | 13.7% | 13.5% | 36.6% | 27.0%
Terminal rate | 3/21 (14%) | 3/19 (16%) | 6/19 (32%) | 9/30 (30%)
First incidence (days) | 719 | 645 | 608 | 645
Poly-3 test | P = 0.052 | P = 0.624N | P = 0.018 | P = 0.119
Adenosquamous Carcinoma | 0 | 0 | 1 | 0
Adenocarcinoma or Adenosquamous Carcinoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 13/50 (26%) | 10/50 (20%)
Adjusted rate | 13.7% | 10.8% | 34.0% | 24.6%
Terminal rate | 3/21 (14%) | 2/19 (11%) | 5/19 (26%) | 8/30 (27%)
First incidence (days) | 719 | 645 | 608 | 645
Poly-3 test | P = 0.071 | P = 0.491N | P = 0.033 | P = 0.177

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 2/102.

^d^ Number of animals with neoplasm per number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal euthanasia.

^g^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A lower incidence in a dose group is indicated by N.

^h^ Not applicable; no neoplasms in animal group.

In the combined standard and extended evaluations, the incidence of adenocarcinoma was significantly increased in the 150 mg/kg group (Table 9). The incidences of adenoma were not significantly increased in the dosed groups; adenomas have not been observed in vehicle controls in gavage studies using female Harlan Sprague Dawley rats.

In the standard evaluation, a significantly increased incidence of squamous metaplasia of the endometrium occurred in the 150 mg/kg group (Table 9 and Table B-5). In the combined standard and extended evaluations, the incidence of squamous metaplasia of the endometrium was significantly decreased in the 300 mg/kg group (Table 9).

Uterine adenocarcinomas were large irregular, invasive masses that effaced the endometrium and commonly extended into the myometrium. They were composed of cuboidal to columnar neoplastic cells that formed irregular tubules, glandular structures or ducts that were surrounded by collagenous stroma. The neoplastic cells had scant eosinophilic cytoplasm and large vesicular nuclei and there was mild to marked pleomorphism and atypia. The neoplasm often contained areas of inflammation, hemorrhage, and/or necrosis (Figure 9 and Figure 10).

Uterine adenomas were solitary, non-invasive, nodular masses that were generally composed of a single layer of cuboidal to columnar epithelial cells typically arranged in glandular structures in which there was minimal to mild stratification or disorganized piling up of the epithelium (Figure 11 and Figure 12). The glandular structures were sometimes dilated and the neoplastic cells formed papillary infoldings or papillary projections into the lumen.

Atypical endometrial hyperplasia was observed in the luminal or glandular epithelium of the uterus. Epithelial atypia in the luminal epithelium consisted of a spectrum of changes that included increased cellular anisocytosis and anisokaryosis and increased cytoplasmic eosinophilia, epithelial blebbing, large cytoplasmic vacuoles and the presence of small papillary projections lined by disorganized epithelial cells. Occasionally, small branching papillary projections were characterized by epithelial lined, short, slender, fibrovascular stalks that extended into the uterine lumen (Figure 13). Epithelial atypia in the glands affected single glands or clusters that were separated by minimal amounts of stroma. The glands were lined by pseudostratified to stratified, cuboidal to tall columnar epithelial cells that exhibited cytoplasmic eosinophilia or basophilia, loss of cellular polarity, karyomegaly, mitoses, and minimal to mild cellular pleomorphism (Figure 14).

Squamous metaplasia of the endometrium was of minimal to moderate severity and consisted of replacement of the normal simple columnar epithelium lining the endometrium (uterine lumen) and occasional endometrial glands by keratinized squamous epithelium. In more severe cases, the uterine lumen was dilated and filled with varying amounts of keratin.

Skin: An increased incidence of fibroma occurred in 300 mg/kg females (Table 10, Table B-1, and Table B-2). Although the increased incidence of this neoplasm was not statistically significant, the incidence in 300 mg/kg females exceeded the historical control range for corn oil gavage studies (Table 10 and Table B-4). A single incidence each of fibrosarcoma occurred in vehicle control and 300 mg/kg females (Table 10 and Table B-1). The incidences of fibroma or fibrosarcoma (combined) occurred with a positive trend in females (Table 10 and Table B-2). Fibromas were circumscribed subcutaneous masses composed of well-differentiated fibrocytes interspersed between variable amounts of mature collagen stroma. Fibrosarcomas were large, invasive, masses that effaced the subcutaneous tissues and consisted of moderately well-differentiated neoplastic fibroblasts arranged in interlacing bundles and whorls.

Table 10 Incidences of Neoplasms of the Skin in Female Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Number Necropsied | 50 | 50 | 50 | 50
Fibroma^a,b^ | 1 | 0 | 0 | 4
Fibrosarcoma^c^ | 1 | 0 | 0 | 1
Fibroma or Fibrosarcoma^d^
Overall rate^e^ | 2/50 (4%) | 0/50 (0%) | 0/50 (0%) | 5/50 (10%)
Adjusted rate^f^ | 5.4% | 0.0% | 0.0% | 12.4%
Terminal rate^g^ | 1/21 (5%) | 0/19 (0%) | 0/19 (0%) | 3/30 (10%)
First incidence (days) | 645 | –^i^ | – | 692
Poly-3 test^h^ | P = 0.040 | P = 0.237N | P = 0.243N | P = 0.254

^a^ Number of animals with lesion.

^b^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 3/102.

^c^ Historical incidence for corn oil gavage studies: 1/102.

^d^ Historical incidence for corn oil gavage studies: 4/102.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A lower incidence in a dose group is indicated by N.

^i^ Not applicable; no neoplasms in animal group.

Small Intestine: Significantly increased incidences of lymphatic ectasia of the duodenum and jejunum with generally increased severities occurred in 150 and 300 mg/kg males and females; two incidences of lymphatic ectasia occurred in the jejunum of 75 mg/kg males (Table 11, Table A-3, and Table B-5). Lymphatic ectasia did not occur in vehicle control animals.

Table 11 Incidences of Selected Nonneoplastic Lesions in Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Male
Intestine Small, Duodenum^a^ | 43 | 48 | 47 | 48
Lymphatic, Ectasia^b^ | 0 | 0 | 15** (1.5)^c^ | 14** (1.4)
Intestine Small, Jejunum | 40 | 39 | 40 | 42
Lymphatic, Ectasia | 0 | 2 (1.0) | 27** (1.7) | 41** (2.0)
Lymph Node, Mesenteric | 50 | 50 | 50 | 50
Lymphatic, Ectasia | 0 | 0 | 1 (3.0) | 5* (1.4)
Liver | 50 | 50 | 50 | 50
Cholangiofibrosis | 0 | 1 (2.0) | 3 (2.7) | 1 (2.0)
Bile Duct, Cyst | 0 | 0 | 2 (2.0) | 5* (2.4)
Thyroid Gland | 50 | 46 | 48 | 47
Follicular Cell, Hypertrophy | 21 (1.8) | 34** (1.9) | 33** (2.1) | 36** (2.6)
Female
Intestine Small, Duodenum | 48 | 47 | 48 | 47
Lymphatic, Ectasia | 0 | 0 | 16** (1.2) | 38** (1.5)
Intestine Small, Jejunum | 47 | 46 | 48 | 48
Lymphatic, Ectasia | 0 | 0 | 30** (1.7) | 47** (2.5)
Lymph Node, Mesenteric | 50 | 50 | 50 | 48
Lymphatic, Ectasia | 0 | 0 | 1 (1.0) | 15** (1.7)
Liver | 50 | 50 | 50 | 48
Cholangiofibrosis | 0 | 1 (1.0) | 0 | 0
Clear Cell Focus | 6 | 7 | 4 | 18**
Eosinophilic Focus | 0 | 4 | 5* | 6*

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Lymphatic ectasia was of minimal to marked severity and characterized by dilation of lymphatic vessels in villi of the duodenum and jejunum (Figure 15 and Figure 16). The dilated lymphatics varied in size and number, and were lined by flattened endothelial cells. The lumens of the dilated lymphatics were generally empty, but a few lymphatics contained minimal amounts of lacy, amphophilic material. In general, the jejunum was more frequently and severely affected than the duodenum.

Mesenteric Lymph Node: Significantly increased incidences of lymphatic ectasia occurred in 300 mg/kg males and females (Table 11, Table A-3, and Table B-5). Single incidences of lymphatic ectasia occurred in a 150 mg/kg male and in a 150 mg/kg female. Lymphatic ectasia did not occur in vehicle control animals.

Lymphatic ectasia was of minimal to moderate severity and characterized by dilation of lymphatic vessels primarily in subcapsular and cortical regions of the nodes, but occasionally the paracortical and medullary lymphatics were affected. These dilated lymphatics varied in size and number, and were lined by flattened endothelial cells. In general, females were more frequently and severely affected than males (Figure 17 and Figure 18).

Liver: Incidences of cholangiofibrosis occurred in all dosed groups of males and in one 75 mg/kg female (Table 11, Table A-3, and Table B-5). The incidences of eosinophilic focus in 150 and 300 mg/kg females and of clear cell focus in 300 mg/kg females were significantly increased compared to the vehicle controls. The incidence of bile duct cyst was significantly increased in 300 mg/kg males.

Cholangiofibrosis was of minimal to marked severity and consisted of sharply demarcated, non-encapsulated, focal to locally extensive lesions that effaced the hepatic parenchyma. Frequently, cholangiofibrosis occurred as nodular lesions that protruded from the capsular surface of the liver. At necropsy, increased incidences of liver masses and cysts were grossly observed in dosed groups of males and females compared to the vehicle controls. Parenchymal lesions consisted of variable amounts of dense collagenous connective tissue that surrounded multiple, variably sized, randomly distributed, dilated, atypical bile ducts that invariably contained eosinophilic to amphophilic, mucinous material and cellular debris (Figure 19 and Figure 20). The atypical ducts were lined by low cuboidal to columnar hyperbasophilic epithelial cells among which were scattered goblet-like or mucous cells. At times, the epithelium lining the bile ducts was absent, resulting in crescent-shaped structures. Moderate numbers of inflammatory cells were scattered through the collagenous tissue. Capsular lesions were encapsulated and primarily composed of dilated atypical ducts surrounded by lesser amounts of collagenous tissue than in lesions within the hepatic parenchyma (Figure 21 and Figure 22).

Eosinophilic foci were variably-sized discrete focal areas of enlarged hepatocytes in which the cytoplasm stained more lightly or darkly eosinophilic than that of the surrounding hepatocytes; in some cases the cytoplasm appeared granular (Figure 23). Clear cell foci were discrete focal areas of normal-sized to slightly enlarged hepatocytes that had clear cytoplasmic spaces around the cell nuclei (Figure 24).

Bile duct cysts were single to multiple, variably dilated bile ducts that disrupted the hepatic parenchyma. The dilated ducts were lined by flattened to cuboidal epithelial cells and occasionally contained fibrillar eosinophilic material.

Transcriptome analysis was performed on RNA extracted from microarray study female rat livers from the 300 mg/kg and vehicle control groups after 3 months of exposure. The observed effects on transcription were consistent with induction of xenobiotic metabolism related processes that are initiated through the activation of the aryl hydrocarbon receptor and oxidative stress sensing transcription factor nuclear factor, erythroid 2-like 2. A detailed breakdown of the transcriptomic results can be found in Appendix L.

Thyroid Gland: The incidences of follicular cell hypertrophy were significantly increased in all dosed groups of males compared to the vehicle controls, and the severities of the hypertrophy increased with increasing dose (Table 11 and Table A-3).

Follicular cell hypertrophy was characterized by an increased height of follicular epithelial cells from normal cuboidal to tall columnar and a concomitant decrease in the diameter of the follicular lumens. In general, follicles contained decreased amounts of colloid and often contained aggregates of flocculent-appearing, amphophilic material. The following criteria were used when diagnosing follicular cell hypertrophy: minimal—30% to 40% of follicles affected; mild—40% to 60% of follicles affected; moderate—60% to 80% of follicles affected; marked—greater than 80% of follicles affected.

Pituitary Gland: Incidences of adenoma occurred in all groups of males and females and the incidence of this neoplasm was significantly decreased in 300 mg/kg females (males: vehicle control, 5/50; 75 mg/kg, 8/49; 150 mg/kg, 9/50; 300 mg/kg, 8/47; females: vehicle control, 18/50, 75 mg/kg, 18/50, 150 mg/kg, 19/50, 300 mg/kg, 8/49) (Table A-1, Table A-2, Table B-1, and Table B-2).

## Three-month Study in Mice

All mice survived to the end of the study (Table 12). The final mean body weights and mean body weight gains of dosed groups of males and females were similar to those of the vehicle controls (Table 12; Figure 6). There were no clinical findings related to administration of indole-3-carbinol.

Table 12 Survival and Body Weights of Mice in the Three-month Gavage Study of Indole-3-carbinol^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 23.6 ± 0.2 | 40.4 ± 0.6 | 16.8 ± 0.6
15.6 | 10/10 | 23.6 ± 0.2 | 40.5 ± 1.1 | 17.0 ± 1.1 | 100
31.25 | 10/10 | 23.6 ± 0.2 | 41.5 ± 0.9 | 17.9 ± 0.8 | 103
62.5 | 10/10 | 23.6 ± 0.1 | 40.0 ± 1.1 | 16.4 ± 1.2 | 99
125 | 10/10 | 23.6 ± 0.2 | 42.2 ± 1.6 | 18.6 ± 1.6 | 104
250 | 10/10 | 23.7 ± 0.3 | 41.0 ± 0.9 | 17.2 ± 0.8 | 101
Female
0 | 10/10 | 19.5 ± 0.2 | 34.2 ± 1.0 | 14.6 ± 1.0
15.6 | 10/10 | 19.5 ± 0.3 | 33.5 ± 1.0 | 14.0 ± 0.9 | 98
31.25 | 10/10 | 19.5 ± 0.3 | 33.8 ± 1.6 | 14.3 ± 1.7 | 99
62.5 | 10/10 | 19.4 ± 0.3 | 33.7 ± 0.6 | 14.3 ± 0.5 | 99
125 | 10/10 | 19.4 ± 0.3 | 33.1 ± 0.7 | 13.7 ± 0.6 | 97
250 | 10/10 | 19.4 ± 0.4 | 31.4 ± 1.3 | 12.1 ± 1.3 | 92

^a^ Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 6

Growth Curves for Mice Administered Indole-3-carbinol by Gavage for Three Months

There were no changes in the hematology data of mice that were considered attributable to indole-3-carbinol administration (Table F-2).

The absolute and relative liver weights of 125 and 250 mg/kg males and all dosed groups of females were significantly increased compared to the vehicle controls (Table 13 and Table G-2).

Table 13 Liver Weights and Liver-to Body-Weight Ratios for Mice in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 15.6 mg/kg | 31.25 mg/kg | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 40.4 ± 0.6 | 40.5 ± 1.1 | 41.5 ± 0.9 | 40.0 ± 1.1 | 42.2 ± 1.6 | 41.0 ± 0.9
Liver
Absolute | 1.50 ± 0.06 | 1.46 ± 0.07 | 1.54 ± 0.05 | 1.54 ± 0.05 | 1.77 ± 0.13* | 1.82 ± 0.06**
Relative | 37.329 ± 1.896 | 35.868 ± 0.799 | 37.166 ± 0.702 | 38.520 ± 0.632 | 41.960 ± 2.146* | 44.333 ± 0.817**
Female
Necropsy body wt | 34.2 ± 1.0 | 33.5 ± 1.0 | 33.8 ± 1.6 | 33.7 ± 0.6 | 33.1 ± 0.7 | 31.4 ± 1.3
Liver
Absolute | 1.04 ± 0.01 | 1.21 ± 0.05* | 1.11 ± 0.04* | 1.16 ± 0.03* | 1.22 ± 0.03** | 1.21 ± 0.04**
Relative | 30.559 ± 0.696 | 36.190 ± 1.253** | 32.906 ± 0.651** | 34.449 ± 0.693** | 36.878 ± 0.867** | 38.687 ± 0.778**

* Significantly different (P ≤ 0.05) from the vehicle control group by William’s or Dunnett’s test.

** P ≤ 0.01.

^a^ Liver weights (absolute weights) and body weights are given in grams; liver-weight-to-body-weight ratios (relative weights) are given as mg liver weight/g body weight (mean ± standard error).

Liver and lung samples were collected for determinations of P450 enzyme activities (Table 14). Microsomal suspensions were prepared from liver samples and were assayed for 7-ethoxyresorufin-O-deethylase (EROD) activity (a marker for CYP1A1 activity) and acetanilide-4-hydroxylase (A4H) activity (a marker for CYP1A2 activity). Microsomal samples from lung were analyzed for EROD activity only. In the liver, there were significant and dose-dependent increases in A4H activities in all dosed groups of male mice. Hepatic EROD activities were significantly increased in males administered 31.25 mg/kg or greater. Hepatic A4H and EROD activities were significantly increased in 125 and 250 mg/kg females. Maximal inductions of A4H and EROD activities in males were nearly 4-fold and 3-fold, respectively, compared to the vehicle controls. In females, A4H and EROD activities were maximally increased more than 2-fold and 3-fold, respectively. There were no treatment-related effects on pulmonary EROD activities in males or females.

Table 14 Liver and Lung Cytochrome P450 Data for Mice in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 15.6 mg/kg | 31.25 mg/kg | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Liver Microsomes
A4H (nmol/minute per mg microsomal protein)
| 0.335 ± 0.039 | 0.449 ± 0.011** | 0.515 ± 0.024** | 0.984 ± 0.037** | 1.124 ± 0.087** | 1.293 ± 0.109**
EROD (pmol/minute per mg microsomal protein)
| 16.7 ± 2.3 | 20.2 ± 1.1 | 24.5 ± 3.1* | 36.2 ± 3.5** | 45.4 ± 8.4** | 43.0 ± 10.4**
Lung Microsomes
EROD (pmol/minute per mg microsomal protein)
| 0.112 ± 0.062 | 0.048 ± 0.032 | 0.011 ± 0.011 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.010 ± 0.010
Female
Liver Microsomes
A4H (nmol/minute per mg microsomal protein)
| 0.601 ± 0.057 | 0.534 ± 0.063 | 0.635 ± 0.036 | 0.620 ± 0.059 | 1.094 ± 0.055** | 1.450 ± 0.085**
EROD (pmol/minute per mg microsomal protein)
| 14.3 ± 1.0 | 11.4 ± 2.2 | 18.8 ± 1.3 | 12.2 ± 2.5 | 28.1 ± 2.5** | 46.1 ± 3.8**
Lung Microsomes
EROD (pmol/minute per mg microsomal protein)
| 0.005 ± 0.005 | 0.011 ± 0.011 | 0.059 ± 0.059 | 0.000 ± 0.000 | 0.075 ± 0.056 | 0.139 ± 0.071

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. A4H = acetanilide-4-hydroxylase; EROD = 7-ethoxyresorufin-O-deethylase.

Sperm motility was significantly decreased in all dosed groups of males (Table H-4). The Markov transition matrix analyses of estrous cyclicity indicated that females in the 250 mg/kg group had a significantly higher probability of extended diestrus than the vehicle control females (Table H-5 and Table H-6; Figure H-2). Based on these results, indole-3-carbinol did exhibit the potential to be a reproductive toxicant in male and female mice.

No chemical-related histopathologic lesions were observed that could be attributed to the administration of indole-3-carbinol.

Dose Selection Rationale: There were no chemical-related effects on mortality, body weights, or lesion incidences in the 3-month study in mice. Chemical-related increases in liver weights were observed, and were consistent with increased hepatic cytochrome P450 activities. In 250 mg/kg females, there was an 8% decrease in final body weight and a slightly lower overall body weight gain. These effects were not considered sufficient to exclude 250 mg/kg as the highest dose in the 2-year study. However, studies in the literature at doses of 500 mg/kg have demonstrated treatment-related effects on survival and neurotoxicity; as a result, higher doses were not considered for the 2-year study. The doses selected for the 2-year gavage study in B6C3F1/N mice were 62.5, 125, and 250 mg/kg.

## Two-year Study in Mice

### Survival

Estimates of 2-year survival probabilities for male and female mice shown in Table 15 and in the Kaplan-Meier survival curves (Figure 7). Survival of 250 mg/kg females was significantly greater than that of the vehicle controls; survival of dosed groups of males was similar to that of the vehicle control group.

Table 15 Survival of Mice in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Male
Animals initially in study | 50 | 50 | 50 | 50
Accidental deaths^a^ | 0 | 0 | 1 | 1
Moribund | 17 | 12 | 11 | 9
Natural deaths | 6 | 7 | 6 | 8
Animals surviving to study termination | 27^e^ | 31 | 32 | 32
Percent probability of survival at end of study^b^ | 52 | 62 | 65 | 65
Mean survival (days)^c^ | 663 | 700 | 686 | 688
Survival analysis^d^ | P = 0.202N | P = 0.256N | P = 0.182N | P = 0.192N
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^a^ | 1 | 0 | 0 | 0
Moribund | 10 | 6 | 15 | 3
Natural deaths | 6 | 4 | 9 | 2
Animals surviving to study termination | 33 | 40 | 26^e^ | 45
Percent probability of survival at end of study | 67 | 80 | 52 | 90
Mean survival (days) | 702 | 704 | 672 | 713
Survival analysis | P = 0.099N | P = 0.263N | P = 0.082 | P = 0.016N

^a^ Censored in the survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^d^ The result of the life table trend test^91^ is in the vehicle control column, and the results of the life table pairwise comparisons^90^ with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

^e^ Includes one animal that died during the last week of the study.

Figure 7

Kaplan-Meier Survival Curves for Mice Administered Indole-3-carbinol by Gavage for Two Years

### Body Weights and Clinical Findings

Mean body weights of dosed groups of male mice were similar to those of the vehicle controls throughout the study; however, those of 250 mg/kg female mice were at least 10% less than those of the vehicle controls between weeks 32 and 92 (Table 16 and Table 17; Figure 8). No clinical findings related to the administration of indole-3-carbinol were observed in males or females.

Table 16 Mean Body Weights and Survival of Male Mice in the Two-year Gavage Study of Indole-3-carbinol

Day | Vehicle Control | | 62.5 mg/kg | | | 125 mg/kg | | | 250 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 22.8 | 50 | 22.9 | 101 | 50 | 22.8 | 100 | 50 | 22.8 | 100 | 50
8 | 23.9 | 50 | 24.1 | 101 | 50 | 24.1 | 101 | 50 | 24.1 | 101 | 50
15 | 24.7 | 50 | 25.0 | 101 | 50 | 24.8 | 101 | 50 | 24.9 | 101 | 50
22 | 26.4 | 50 | 26.7 | 101 | 50 | 26.6 | 101 | 50 | 26.5 | 101 | 50
29 | 27.0 | 50 | 27.7 | 103 | 50 | 27.4 | 101 | 50 | 27.3 | 101 | 50
36 | 28.8 | 50 | 29.5 | 103 | 50 | 29.3 | 102 | 50 | 28.9 | 100 | 50
43 | 30.0 | 50 | 30.7 | 102 | 50 | 30.2 | 101 | 50 | 29.7 | 99 | 50
50 | 31.7 | 50 | 32.2 | 101 | 50 | 31.6 | 100 | 50 | 31.1 | 98 | 50
57 | 32.9 | 50 | 33.8 | 103 | 50 | 33.1 | 101 | 50 | 32.7 | 99 | 50
64 | 33.7 | 50 | 34.7 | 103 | 50 | 33.5 | 100 | 50 | 33.3 | 99 | 50
71 | 34.5 | 50 | 35.6 | 103 | 50 | 34.5 | 100 | 50 | 34.1 | 99 | 50
78 | 36.4 | 50 | 37.7 | 104 | 50 | 36.4 | 100 | 50 | 36.1 | 99 | 50
85 | 36.4 | 50 | 37.7 | 103 | 50 | 36.5 | 100 | 50 | 36.2 | 99 | 50
113 | 39.8 | 50 | 42.1 | 106 | 50 | 40.8 | 103 | 50 | 40.5 | 102 | 50
141 | 43.6 | 50 | 45.5 | 104 | 50 | 44.1 | 101 | 49 | 43.2 | 99 | 50
169 | 46.1 | 50 | 48.0 | 104 | 50 | 47.1 | 102 | 49 | 45.8 | 99 | 50
197 | 47.8 | 50 | 48.9 | 102 | 50 | 48.9 | 102 | 49 | 46.8 | 98 | 50
225 | 50.8 | 50 | 51.9 | 102 | 50 | 51.9 | 102 | 49 | 49.7 | 98 | 50
253 | 51.4 | 50 | 52.1 | 101 | 50 | 52.4 | 102 | 49 | 50.3 | 98 | 50
281 | 51.9 | 50 | 52.6 | 101 | 50 | 52.9 | 102 | 49 | 51.5 | 99 | 50
309 | 53.8 | 50 | 54.3 | 101 | 50 | 54.6 | 102 | 49 | 52.8 | 98 | 50
337 | 54.0 | 50 | 54.5 | 101 | 50 | 54.6 | 101 | 49 | 52.7 | 98 | 50
365 | 54.5 | 49 | 55.2 | 101 | 50 | 55.3 | 101 | 49 | 53.8 | 99 | 50
393 | 54.5 | 49 | 55.9 | 103 | 49 | 55.4 | 102 | 49 | 54.6 | 100 | 49
421 | 55.2 | 49 | 56.4 | 102 | 49 | 55.7 | 101 | 49 | 55.0 | 100 | 49
449 | 55.6 | 49 | 56.6 | 102 | 49 | 55.9 | 101 | 48 | 55.6 | 100 | 48
477 | 55.5 | 46 | 57.3 | 103 | 49 | 56.1 | 101 | 48 | 55.7 | 100 | 48
505 | 55.6 | 44 | 57.1 | 103 | 49 | 55.5 | 100 | 48 | 56.0 | 101 | 47
533 | 55.4 | 41 | 57.5 | 104 | 49 | 55.2 | 100 | 48 | 56.4 | 102 | 46
561 | 54.7 | 40 | 56.5 | 103 | 49 | 53.8 | 98 | 48 | 55.6 | 102 | 46
589 | 54.5 | 39 | 56.8 | 104 | 47 | 53.7 | 99 | 46 | 55.6 | 102 | 45
617 | 54.6 | 38 | 55.9 | 102 | 45 | 53.1 | 97 | 42 | 55.0 | 101 | 42
645 | 55.0 | 34 | 54.8 | 100 | 43 | 52.9 | 96 | 40 | 53.8 | 98 | 40
673 | 54.4 | 32 | 53.8 | 99 | 41 | 53.0 | 98 | 38 | 52.5 | 97 | 38
701 | 53.3 | 30 | 53.9 | 101 | 36 | 52.9 | 99 | 35 | 50.9 | 96 | 35
Mean for Weeks
1–13 | 29.9 | | 30.6 | 102 | | 30.1 | 101 | | 29.8 | 100
14–52 | 48.8 | | 50.0 | 102 | | 49.7 | 102 | | 48.1 | 99
53–101 | 54.8 | | 56.0 | 102 | | 54.5 | 99 | | 54.7 | 100

Table 17 Mean Body Weights and Survival of Female Mice in the Two-year Gavage Study of Indole-3-carbinol

Day | Vehicle Control | | 62.5 mg/kg | | | 125 mg/kg | | | 250 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 18.6 | 50 | 18.6 | 100 | 50 | 18.5 | 99 | 50 | 18.8 | 101 | 50
8 | 19.3 | 50 | 19.1 | 99 | 50 | 19.2 | 100 | 50 | 19.3 | 100 | 50
15 | 20.3 | 50 | 20.0 | 99 | 50 | 20.1 | 99 | 50 | 20.3 | 100 | 50
22 | 21.6 | 50 | 21.0 | 97 | 50 | 21.2 | 98 | 50 | 21.4 | 99 | 50
29 | 22.5 | 50 | 21.9 | 98 | 50 | 22.2 | 99 | 50 | 22.0 | 98 | 50
36 | 23.6 | 50 | 22.8 | 97 | 50 | 23.4 | 99 | 50 | 23.2 | 98 | 50
43 | 24.8 | 50 | 23.9 | 97 | 50 | 24.8 | 100 | 50 | 24.6 | 99 | 50
50 | 25.5 | 50 | 24.7 | 97 | 50 | 25.6 | 101 | 50 | 25.1 | 99 | 50
57 | 26.5 | 50 | 25.9 | 98 | 50 | 26.8 | 101 | 50 | 25.9 | 98 | 50
64 | 28.3 | 50 | 27.5 | 97 | 50 | 28.5 | 101 | 50 | 27.4 | 97 | 50
71 | 29.0 | 50 | 28.8 | 99 | 50 | 29.7 | 103 | 50 | 28.6 | 99 | 50
78 | 29.8 | 50 | 29.0 | 98 | 50 | 30.8 | 103 | 50 | 29.7 | 100 | 50
85 | 30.0 | 50 | 30.1 | 100 | 50 | 31.2 | 104 | 50 | 30.3 | 101 | 50
113 | 35.0 | 50 | 33.8 | 96 | 50 | 36.3 | 104 | 50 | 34.4 | 98 | 50
141 | 37.7 | 50 | 36.2 | 96 | 50 | 39.0 | 103 | 50 | 36.9 | 98 | 50
169 | 40.3 | 50 | 38.6 | 96 | 50 | 41.6 | 103 | 50 | 39.2 | 97 | 50
197 | 44.4 | 50 | 41.7 | 94 | 49 | 44.2 | 99 | 50 | 40.9 | 92 | 50
225 | 48.1 | 50 | 45.2 | 94 | 49 | 47.7 | 99 | 50 | 42.5 | 88 | 50
253 | 50.9 | 50 | 47.8 | 94 | 49 | 50.0 | 98 | 50 | 43.7 | 86 | 50
281 | 51.8 | 50 | 48.1 | 93 | 49 | 51.4 | 99 | 50 | 44.4 | 86 | 50
309 | 56.9 | 50 | 53.0 | 93 | 49 | 56.3 | 99 | 50 | 47.5 | 84 | 50
337 | 59.1 | 50 | 54.9 | 93 | 49 | 57.6 | 97 | 50 | 48.1 | 81 | 50
365 | 61.9 | 50 | 57.5 | 93 | 49 | 59.6 | 96 | 50 | 49.0 | 79 | 50
393 | 63.4 | 50 | 59.0 | 93 | 49 | 61.0 | 96 | 49 | 50.4 | 80 | 50
421 | 63.0 | 50 | 59.7 | 95 | 49 | 61.5 | 98 | 49 | 50.8 | 81 | 50
449 | 65.2 | 50 | 62.3 | 96 | 49 | 63.4 | 97 | 49 | 53.0 | 81 | 50
477 | 65.2 | 50 | 62.6 | 96 | 49 | 63.2 | 97 | 49 | 53.8 | 83 | 50
505 | 65.3 | 50 | 63.5 | 97 | 49 | 64.0 | 98 | 48 | 54.9 | 84 | 48
533 | 65.8 | 49 | 63.8 | 97 | 49 | 63.6 | 97 | 45 | 55.7 | 85 | 48
561 | 66.6 | 49 | 63.7 | 96 | 48 | 63.8 | 96 | 45 | 55.7 | 84 | 47
589 | 66.3 | 46 | 64.1 | 97 | 48 | 62.5 | 94 | 44 | 55.7 | 84 | 47
617 | 65.0 | 46 | 62.9 | 97 | 48 | 62.0 | 95 | 41 | 56.3 | 87 | 46
645 | 62.6 | 44 | 61.8 | 99 | 45 | 61.0 | 97 | 34 | 55.8 | 89 | 46
673 | 61.1 | 41 | 60.9 | 100 | 44 | 59.2 | 97 | 30 | 55.5 | 91 | 46
701 | 59.2 | 36 | 60.9 | 103 | 40 | 58.4 | 99 | 27 | 55.5 | 94 | 46
Mean for Weeks
1–13 | 24.6 | | 24.1 | 98 | | 24.8 | 101 | | 24.4 | 99
14–52 | 47.1 | | 44.4 | 94 | | 47.1 | 100 | | 42.0 | 89
53–101 | 63.9 | | 61.7 | 97 | | 61.8 | 97 | | 54.0 | 85

Figure 8

Growth Curves for Mice Administered Indole-3-carbinol by Gavage for Two Years

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the liver, glandular stomach, and nose. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Liver: Incidences of hepatocellular adenoma occurred with a positive trend in males and the incidence of this neoplasm was significantly increased in the 250 mg/kg group (Table 18, Table C-1, and Table C-2). In addition, the incidences of multiple hepatocellular adenoma were significantly increased in 62.5 and 250 mg/kg males.

Table 18 Incidences of Neoplasms and Nonneoplastic Lesions of the Liver in Mice in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Male
Number Examined Microscopically | 50 | 50 | 49 | 50
Clear Cell Focus^a^ | 7 | 17* | 22** | 20**
Hepatocellular Adenoma, Multiple | 15 | 25* | 16 | 33**
Hepatocellular Adenoma (includes multiple)^b^
Overall rate^c^ | 26/50 (52%) | 32/50 (64%) | 31/49 (63%) | 41/50 (82%)
Adjusted rate^d^ | 62.1% | 66.5% | 67.9% | 85.4%
Terminal rate^e^ | 19/26 (73%) | 21/31 (68%) | 23/32 (72%) | 28/32 (88%)
First incidence (days) | 463 | 381 | 437 | 385
Poly-3 test^f^ | P = 0.005 | P = 0.411 | P = 0.360 | P = 0.006
Hepatocellular Carcinoma, Multiple | 5 | 3 | 18** | 8
Hepatocellular Carcinoma (includes multiple)^g^
Overall rate | 12/50 (24%) | 11/50 (22%) | 29/49 (59%) | 14/50 (28%)
Adjusted rate | 27.7% | 24.2% | 63.4% | 30.9%
Terminal rate | 3/26 (12%) | 8/31 (26%) | 18/32 (56%) | 8/32 (25%)
First incidence (days) | 465 | 682 | 567 | 385
Poly-3 test | P = 0.217 | P = 0.449N | P < 0.001 | P = 0.461
Hepatocellular Adenoma or Carcinoma^h^
Overall rate | 35/50 (70%) | 36/50 (72%) | 43/49 (88%) | 44/50 (88%)
Adjusted rate | 77.6% | 74.6% | 90.6% | 91.1%
Terminal rate | 21/26 (81%) | 24/31 (77%) | 29/32 (91%) | 30/32 (94%)
First incidence (days) | 463 | 381 | 437 | 385
Poly-3 test | P = 0.012 | P = 0.459N | P = 0.062 | P = 0.049
Hepatoblastoma, Multiple | 0 | 1 | 3 | 7*
Hepatoblastoma (Includes Multiple)^i^
Overall rate | 3/50 (6%) | 4/50 (8%) | 4/49 (8%) | 14/50 (28%)
Adjusted rate | 7.6% | 8.9% | 9.3% | 31.6%
Terminal rate | 3/26 (12%) | 4/31 (13%) | 3/32 (9%) | 10/32 (31%)
First incidence (days) | 730 (T) | 730 (T) | 702 | 617
Poly-3 test | P < 0.001 | P = 0.567 | P = 0.543 | P = 0.005
Hepatocellular Carcinoma or Hepatoblastoma^j^
Overall rate | 15/50 (30%) | 13/50 (26%) | 30/49 (61%) | 25/50 (50%)
Adjusted rate | 34.6% | 28.7% | 65.6% | 54.5%
Terminal rate | 6/26 (23%) | 10/31 (32%) | 19/32 (59%) | 17/32 (53%)
First incidence (days) | 465 | 682 | 567 | 385
Poly-3 test | P = 0.005 | P = 0.353N | P = 0.002 | P = 0.042
Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma^k^
Overall rate | 36/50 (72%) | 36/50 (72%) | 44/49 (90%) | 45/50 (90%)
Adjusted rate | 79.8% | 74.6% | 92.7% | 92.8%
Terminal rate | 22/26 (85%) | 24/31 (77%) | 30/32 (94%) | 30/32 (94%)
First incidence (days) | 463 | 381 | 437 | 385
Poly-3 test | P = 0.007 | P = 0.354N | P = 0.050 | P = 0.044
Hepatocholangiocarcinoma^l^
Overall rate | 0/50 (0%) | 3/50 (6%) | 1/49 (2%) | 0/50 (0%)
Adjusted rate | 0.0% | 6.6% | 2.3% | 0.0%
Terminal rate | 0/26 (0%) | 0/31 (0%) | 1/32 (3%) | 0/32 (0%)
First incidence (days) | –^m^ | 630 | 730 (T) | –
Poly-3 test | P = 0.319N | P = 0.146 | P = 0.515 | –^n^
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Eosinophilic Focus | 16 | 26* | 26* | 21
Hepatocellular Adenoma, Multiple | 0 | 3 | 2 | 4
Hepatocellular Adenoma, (includes multiple)^o^
Overall rate | 7/50 (14%) | 14/50 (28%) | 8/50 (16%) | 11/50 (22%)
Adjusted rate | 15.2% | 30.0% | 19.5% | 22.9%
Terminal rate | 5/33 (15%) | 13/40 (33%) | 7/26 (27%) | 10/45 (22%)
First incidence (days) | 568 | 687 | 621 | 603
Poly-3 test | P = 0.390 | P = 0.071 | P = 0.405 | P = 0.247
Hepatocellular Carcinoma, Multiple | 0 | 2 | 1 | 0
Hepatocellular Carcinoma (includes multiple)^p^
Overall rate | 6/50 (12%) | 8/50 (16%) | 9/50 (18%) | 4/50 (8%)
Adjusted rate | 13.2% | 17.1% | 21.5% | 8.4%
Terminal rate | 5/33 (15%) | 7/40 (18%) | 5/26 (19%) | 4/45 (9%)
First incidence (days) | 709 | 650 | 606 | 729 (T)
Poly-3 test | P = 0.246N | P = 0.409 | P = 0.228 | P = 0.341N
Hepatoblastoma^q^ | 0 | 0 | 1 | 1

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

(T)Terminal euthanasia.

^a^ Number of animals with lesion.

^b^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 145/250 (58.0% ± 5.1%), range 52%–64%; all routes: 594/949 (62.6% ± 9.1%), range 48%–78%.

^c^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal euthanasia.

^f^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in a dose group is indicated by N.

^g^ Historical incidence for corn oil gavage studies: 87/250 (34.8% ± 10.9%), range 22%–44%; all routes: 348/949 (36.7% ± 11.4%), range 22%–56%.

^h^ Historical incidence for corn oil gavage studies: 189/250 (75.6% ± 3.3%), range 70%–78%; all routes: 742/949 (78.2% ± 7.2%), range 64%–90%.

^i^ Historical incidence for corn oil gavage studies: 9/250 (3.6% ± 2.6%), range 0%–6%; all routes: 40/949 (4.2% ± 3.5%), range 0%–12%.

^j^ Historical incidence for corn oil gavage studies: 93/250 (37.2% ± 10.0%), range 24%–48%; all routes: 371/949 (39.1% ± 11.6%), range 22%–58%.

^k^ Historical incidence for corn oil gavage studies: 190/250 (76.0% ± 2.5%), range 72%–78%; all routes: 746/949 (78.6% ± 7.2%), range 64%–90%.

^l^ Historical incidence for corn oil gavage studies: 4/250 (1.6% ± 3.6%), range 0%–8%; all routes: 10/949 (1.1% ± 2.2%), range 0%–8%.

^m^ Not applicable; no neoplasms in animal group.

^n^ Value of statistic cannot be computed.

^o^ Historical incidence for corn oil gavage studies: 62/250 (24.8% ± 9.6%), range 14%–34%; all routes: 378/948 (39.9% ± 18.7%), range 14%–78%.

^p^ Historical incidence for corn oil gavage studies: 26/250 (10.4% ± 5.6%), range 4%–18%; all routes: 152/948 (16.0% ± 10.6%), range 4%–46%.

^q^ Historical incidence for corn oil gavage studies: 1/250 (0.4% ± 0.9%), range 0%–2%; all routes: 4/948 (0.4% ± 0.8%), range 0%–2%.

Significantly increased incidences of hepatocellular carcinoma and multiple hepatocellular carcinoma occurred in 125 mg/kg males (Table 18, Table C-1, and Table C-2).

Incidences of hepatoblastoma occurred with a positive trend in males; the incidence of this neoplasm was significantly increased in the 250 mg/kg group and exceeded the historical control ranges for corn oil gavage studies and for all routes combined (Table 18, Table C-1, Table C-2, and Table C-3). In males, the incidences of multiple hepatoblastoma increased with increasing dose and the incidence of multiple hepatoblastoma was significantly increased in the 250 mg/kg group. One 125 mg/kg female and one 250 mg/kg female had a single hepatoblastoma (Table 18 and Table D-1).

The combined incidences of hepatocellular adenoma, hepatocellular carcinoma, or hepatoblastoma occurred with a positive trend in males and were significantly increased in males administered 125 or 250 mg/kg (Table 18, Table C-1, and Table C-2). The combined incidences of hepatocellular carcinoma or hepatoblastoma were significantly increased in 125 and 250 mg/kg males.

In males, a single hepatocholangioma occurred in the 250 mg/kg group (Table C-1). In addition, three and one hepatocholangiocarcinomas occurred in the 62.5 and 125 mg/kg groups, respectively (Table 18, Table C-1, and Table C-2); these incidences were within the historical control ranges and were not dose-dependent (Table 18, Table C-1, and Table C-2).

The incidences of clear cell focus were significantly increased in all dosed groups of males and the incidences of eosinophilic focus were significantly increased in 62.5 and 125 mg/kg females (Table 18, Table C-4, and Table D-4).

Hepatocellular adenomas were relatively well-circumscribed, nodular masses that compressed the adjacent hepatic parenchyma (Figure 25 and Figure 26). They were composed of well-differentiated hepatocytes that formed irregular hepatic plates that often compressed sinusoids and obliquely impinged on the adjacent parenchyma. In general, there was loss of normal lobular architecture with absence of central veins and portal tracts. The cytoplasm of the neoplastic cells varied tinctorially and often appeared eosinophilic, basophilic, clear, or mixed. When more than one hepatocellular adenoma was observed in an animal, the diagnosis of multiple hepatocellular adenoma was recorded.

Hepatocellular carcinomas were generally locally invasive, compressive, irregularly-shaped masses that effaced the normal hepatic parenchyma. Neoplastic hepatocytes were often pleomorphic and in some areas formed trabeculae three or more neoplastic hepatocytes thick (Figure 27 and Figure 28). Cellular atypia and mitotic figures were frequently observed. When more than one hepatocellular carcinoma was observed in an animal, the diagnosis of multiple hepatocellular carcinoma was recorded.

Hepatoblastomas were well-demarcated, irregular-shaped, hypercellular, deeply basophilic masses that occasionally occurred within hepatocellular carcinomas or adjacent to hepatocellular adenomas or hepatocellular carcinomas (Figure 29 and Figure 30). They were composed of sheets of small, elongate to spindle-shaped cells with hyperchromatic nuclei and scant, deeply basophilic cytoplasm that were separated by scant connective tissue stroma. The cells were sometimes arranged radially around small blood vessels and formed poorly defined rosettes or pseudoglandular structures. When more than one hepatoblastoma was observed in an animal, the diagnosis of multiple hepatoblastoma was recorded; when hepatoblastoma was observed within a hepatocellular carcinoma, only the hepatoblastoma was diagnosed. Hepatocholangiocarcinomas were morphologically similar to hepatocellular carcinomas, but also contained elements of malignant biliary epithelium. The one hepatocholangioma was morphologically similar to a hepatocellular adenoma, but also contained elements of benign neoplastic biliary epithelium.

Clear cell foci consisted of foci of hepatocytes that were of normal size to slightly enlarged containing cytoplasmic clear space and centrally located nuclei. Eosinophilic foci were characterized by focal regions of enlarged hepatocytes with granular, pink cytoplasm.

Glandular Stomach: The incidences of epithelium hyperplasia, chronic inflammation, and pigmentation were significantly increased in 125 and 250 mg/kg males and all dosed groups of females compared to the vehicle controls, and the severities generally increased with increasing dose (Table 19, Table C-4, and Table D-4).

Table 19 Incidences of Nonneoplastic Lesions of the Glandular Stomach in Mice in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Male
Number Examined Microscopically | 50 | 47 | 47 | 49
Epithelium, Hyperplasia^a^ | 0 | 1 (1.0)^b^ | 22** (1.2) | 40** (1.5)
Inflammation, Chronic | 1 (1.0) | 1 (1.0) | 18** (1.0) | 45** (1.0)
Pigmentation | 0 | 1 (1.0) | 38** (1.0) | 48** (1.1)
Female
Number Examined Microscopically | 48 | 50 | 49 | 50
Epithelium, Hyperplasia | 1 (2.0) | 7* (1.3) | 10** (1.2) | 35** (1.4)
Inflammation, Chronic | 0 | 15** (1.0) | 29** (1.1) | 47** (1.3)
Pigmentation | 0 | 15** (1.0) | 31** (1.2) | 49** (1.9)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Hyperplasia of the glandular stomach epithelium consisted of multifocal proliferation of the chief cells at the base of the gastric glands in the fundic region of the stomach. This change was subtle and of minimal severity. Compared to the glandular stomach of the vehicle controls (Figure 31), there was minimal increase in the number and disorganized crowding of the chief cells within the fundic glands; proliferating cells appeared to be slightly more basophilic than those in unaffected fundic glands (Figure 32). Chronic inflammation consisted of small aggregates of macrophages that were randomly distributed among the glands at the base of the mucosa and in the submucosa. The cytoplasm of macrophages contained a lightly staining, globular, golden yellow material presumed to be the test article and diagnosed as pigment. Multifocally, coarse aggregates of golden brown pigment similar to that within the macrophages were randomly distributed within minimally to mildly dilated gastric glands and the lamina propria. Mixed infiltrates of low numbers of lymphocytes and/or neutrophils were sparsely scattered within the lamina propria and submucosa.

Nose: Significantly increased incidences of nerve atrophy occurred in 250 mg/kg males and females compared to the vehicle controls (Table 20, Table C-4, and Table D-4). A single incidence of nerve atrophy without statistical significance occurred in a 125 mg/kg female. This lesion was most frequent in females.

Table 20 Incidences of Nonneoplastic Lesions of the Nose in Mice in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Nerve, Atrophy^a^ | 0 | 0 | 0 | 8** (2.0)
Olfactory Epithelium, Respiratory Metaplasia | 14 (1.1)^b^ | 14 (1.3) | 20 (1.5) | 27* (1.4)
Olfactory Epithelium, Atrophy | 3 (2.0) | 5 (1.6) | 11* (1.4) | 17** (1.5)
Olfactory Epithelium, Degeneration | 1 (1.0) | 1 (1.0) | 4 (1.8) | 2 (2.0)
Olfactory Epithelium, Necrosis | 0 | 0 | 0 | 6* (2.2)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 18 (1.2) | 34** (1.1) | 30* (1.1) | 26 (1.2)
Respiratory Epithelium, Hyperplasia | 35 (1.0) | 40 (1.2) | 41 (1.2) | 45* (1.3)
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Nerve, Atrophy | 0 | 0 | 1 (2.0) | 50** (3.0)
Olfactory Epithelium, Respiratory Metaplasia | 7 (1.0) | 8 (1.0) | 16* (1.0) | 49** (2.9)
Olfactory Epithelium, Atrophy | 1 (1.0) | 2 (1.0) | 3 (2.0) | 45** (2.0)
Olfactory Epithelium, Degeneration | 0 | 0 | 2 (2.0) | 3 (3.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 47 (1.4) | 38** (1.1) | 42 (1.1) | 50 (2.4)
Respiratory Epithelium, Hyperplasia | 32 (1.0) | 31 (1.0) | 38 (1.0) | 50** (3.0)
Inflammation | 4 (1.5) | 1 (1.0) | 8 (1.1) | 39** (1.2)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Incidences of respiratory metaplasia of the olfactory epithelium were significantly increased in 250 mg/kg males and in 125 and 250 mg/kg females compared to the vehicle controls (Table 20, Table C-4, and Table D-4). The incidences of atrophy of the olfactory epithelium were significantly increased in 125 and 250 mg/kg males and 250 mg/kg females. Slightly increased incidences of mild to moderate olfactory epithelium degeneration occurred in 125 mg/kg males and in 125 and 250 mg/kg females. A significantly increased incidence of mild olfactory epithelium necrosis occurred in the 250 mg/kg males.

The incidences of respiratory epithelium hyaline droplet accumulation were significantly increased in 62.5 and 125 mg/kg males (Table 20 and Table C-4). The incidence of respiratory epithelium hyaline droplet accumulation was significantly decreased in 62.5 mg/kg females compared to the vehicle controls; however, the incidence and severity increased in 250 mg/kg females (Table 20 and Table D-4).

Significantly increased incidences of respiratory epithelium hyperplasia occurred in 250 mg/kg males and females (Table 20, Table C-4, and Table D-4). The severity was increased in 250 mg/kg females.

The incidence of inflammation was significantly increased in 250 mg/kg females (Table 20 and Table D-4). The incidence of inflammation was also increased in 125 mg/kg females, but not significantly.

Atrophy of olfactory epithelium was of minimal to moderate severity primarily affecting segments of the ethmoid turbinates and nasal septum in the olfactory region of the Level III nasal histologic section and occasionally in olfactory epithelium lining the dorsal meatus of the Level II nasal histologic section. In affected segments, the height of the epithelium was noticeably shorter than that of unaffected segments of comparable segments in the vehicle controls (Figure 33 and Figure 34).

Nerve atrophy occurred predominantly in the lamina propria of segments of the turbinates (ethmoid) and nasal septum in the olfactory region of the Level III nasal histologic section and occasionally in olfactory epithelium lining the dorsal meatus of the Level II nasal histologic section. In affected segments, the nerve bundles were smaller in diameter and fewer in number than in comparable sections of the vehicle controls.histologic section. In affected segments, the nerve bundles were smaller in diameter and fewer in number than in comparable sections of the vehicle controls.

Olfactory epithelium respiratory metaplasia was observed frequently and affected the olfactory epithelium lining the nasal septum and ethmoturbinates in Level III, and occasionally the dorsal meatus of Level II, in predominantly dosed animals but occasionally in vehicle controls. The incidences and severities of this lesion increased with increasing dose. Olfactory epithelium respiratory metaplasia was of minimal to moderate severity and was characterized by replacement of olfactory epithelium by cuboidal to columnar, ciliated epithelial cells similar to those lining the maxilloturbinates (Figure 35 and Figure 36). Often, the metaplastic epithelium extended into the submocosal glands replacing duct and glandular epithelium.

Degeneration of the olfactory epithelium was characterized by segmental loss of and disorganization of the olfactory epithelia cells along with increased clear intercellular spaces with or without an overall decrease in height of the epithelium.

Olfactory epithelium necrosis, of minimal to moderate severity, was observed predominantly in ethmoid turbinates and occasionally the septum of Level III. Necrosis was characterized by disorganization of olfactory epithelial cells, which had scant eosinophilic cytoplasm and pyknotic nuclei. Degenerate neutrophils and fibrinous eosinophilic material were frequently associated with necrotic olfactory epithelial cells and occasionally effaced the epithelial cell layer.

Hyaline droplet accumulation in the respiratory epithelium was primarily observed in the ventral aspects of the nasal cavity, adjacent to the squamous-respiratory junction in the Level II histologic section and to the olfactory-respiratory junction in the Level III histologic section. Hyaline droplet accumulation consisted of intracytoplasmic, homogenous, eosinophilic, globular material in respiratory epithelial cells.

Hyperplasia of the respiratory epithelium was typically observed in the Level II histologic section and less frequently at the Level I section and was characterized by proliferation of ciliated columnar cells that occasionally formed villous structures that projected into nasal passages. Frequently, the hyperplastic cells extended into the submucosal glands that were often dilated.

Inflammation was of minimal to mild severity and consisted of protein accumulations and/or infiltration of neutrophils and mononuclear inflammatory cells in the dorsal aspects of the nasal passages in the Level II and III histologic sections.

## Genetic Toxicology

Indole-3-carbinol was tested in three independent bacterial mutagenicity studies, and results were varied. The first study, which employed Salmonella typhimurium strains TA97, TA98, TA100, TA1535, and TA1537 and used a concentration range of 3.3 to 3,333 μg indole-3-carbinol/plate with and without 10% or 30% rat or hamster liver S9, yielded results that were judged to be equivocal in TA97 in the absence of S9 (Table E-1). A second study, using strains TA97, TA98, TA100, TA102, TA104, TA1535, and TA1537, and concentrations ranging from 33 to 10,000 μg/plate, yielded weak positive responses in strain TA100 without and with 30% hamster liver S9 (no mutagenicity was seen in this strain in the presence of other concentrations or species of S9) (Table E-1). Results of the third study were judged to be equivocal in S. typhimurium strain TA100 (concentration range 500 to 5,000 μg/plate) in the presence of 10% rat liver S9 and in Escherichia coli strain WP2 uvrA/pKM101 (concentration range of 500 to 7,500 μg/plate) in the absence of S9 activation; no mutagenic activity was seen in this assay in S. typhimurium strain TA98, with or without S9, tested up to 5,000 μg/plate (Table E-2).

In vivo, no increase in the frequency of micronucleated PCEs was seen in the bone marrow of male F344/N rats given three doses of indole-3-carbinol (500 to 2,000 mg/kg per day) via gavage; however, a significant decrease in the percent PCEs was seen in the bone marrow of treated rats, indicating that indole-3-carbinol was toxic to the bone marrow (Table E-3). In addition to the rat study, micronucleus frequencies in NCEs of male and female B6C3F1/N mice were assessed in peripheral blood following 3 months of daily gavage treatment with indole-3-carbinol (15.6 to 250 mg/kg per day) in corn oil; no significant increases in micronucleated NCEs were seen in either sex, and no significant changes in percent PCEs occurred over the dose range tested (Table E-4).

Figure 9

Adenocarcinoma of the Endometrium in the Uterus of a Female Harlan Sprague Dawley Rat Administered 300 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Note the invasion through the myometrium and out to the serosal surface (arrows).

Figure 10

Higher Magnification of Figure 9 (H&E)

Note the glandular neoplastic structures (arrows) invading into the myometrium.

Figure 11

Adenoma (Arrows) of the Endometrium in the Uterus of a Female Harlan Sprague Dawley Rat Administered 300 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Figure 12

Higher Magnification of Figure 11 (H&E)

The adenoma is composed of irregular glandular structures lined by cuboidal to columnar epithelium that is disorganized in some areas.

Figure 13

Atypical Hyperplasia of the Endometrium in the Uterus of a Female Harlan Sprague Dawley Rat Administered 300 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Compared to the normal appearing epithelium lining the lumen of the uterus (thin arrows), a segment of the uterine lumen is lined by disorganized atypical epithelial cells (thick arrows).

Figure 14

Atypical Hyperplasia of the Endometrium in the Uterus of a Female Harlan Sprague Dawley Rat Administered 300 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Compared to the normal appearing glands (thin arrows), the affected glands are lined by disorganized atypical epithelial cells (thick arrows).

Figure 15

Lymphatic Ectasia in the Jejunum of a Female Harlan Sprague Dawley Rat Administered 300 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Note multiple dilated lymphatics (arrows) in the lamina propria of the villi.

Figure 16

Higher Magnification of Figure 15 (H&E)

A single layer of endothelial cells lines the dilated lymphatics (arrows).

Figure 17

Lymphatic Ectasia in the Mesenteric Lymph Node of a Female Harlan Sprague Dawley Rat Administered 300 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Note multiple dilated lymphatics in the medulla (arrows).

Figure 18

Higher Magnification of Figure 17 (H&E)

Note the dilated lymphatics (long arrows) and aggregates of macrophages that have golden brown cytoplasmic pigment (short arrows).

Figure 19

Cholangiofibrosis in the Liver of a Male Harlan Sprague Dawley Rat Administered 150 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Note that the lesion has effaced an extensive area of the hepatic parenchyma (arrows).

Figure 20

Higher Magnification of Figure 19 (H&E)

Cholangiofibrosis consists of multiple, variably sized, irregular, atypical bile ducts surrounded by abundant fibrous tissue infiltrated by inflammatory cells (arrows). Ducts contain mucous material, exfoliated cells, and cellular debris.

Figure 21

Cholangiofibrosis in the Liver of a Male Harlan Sprague Dawley Rat Administered 150 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Note the nodular lesions (arrows) protruding from the capsular surface.

Figure 22

Higher Magnification of Figure 21 (H&E)

Note the dilated bile ducts lined by atypical epithelial cells (arrows). The ducts contain mucous and cellular debris.

Figure 23

Eosinophilic Focus in the Liver of a Male Harlan Sprague Dawley Rat Administered 75 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Note the discrete lesion (arrows) that is well-demarcated from the surrounding hepatic parenchyma.

Figure 24

Clear Cell Focus (Arrows) in the Liver of a Male Harlan Sprague Dawley Rat Administered 75 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Figure 25

Hepatocellular Adenoma (Arrows) in the Liver of a Male B6C3F1/N Mouse Administered 250 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Figure 26

Higher Magnification of Figure 25 (H&E)

Note the loss of normal hepatic architecture (left of arrows) within the adenoma (right of arrows) and distorted hepatic plates obliquely impinging upon the surrounding hepatic parenchyma.

Figure 27

Large, Well-demarcated, Nodular Hepatocellular Carcinoma (Arrows) in a Male B6C3F1/N Mouse Administered 250 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

The neoplasm has completely effaced the hepatic parenchyma.

Figure 28

Higher Magnification of Figure 27 (H&E)

Note the thick trabeculae of neoplastic hepatocytes (arrows) that are a characteristic feature of hepatocellular carcinoma.

Figure 29

Hepatoblastoma (Arrows) in the Liver of a Male B6C3F1/N Mouse Administered 250 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

The neoplasm is well-demarcated from the surrounding hepatic parenchyma and stains deeply basophilic.

Figure 30

Higher Magnification of Figure 29 (H&E)

Cells of the hepatoblastoma are small, elongate to spindle-shaped with hyperchromatic nuclei, and are separated by scant connective tissue stroma.

Figure 31

Normal Glandular Stomach Epithelium in a Vehicle Control Female B6C3F1/N Mouse in the Two-year Gavage Study of Indole-3-carbinol (H&E)

Note elongate gastric glands (arrows) lined by large parietal cells with granular, eosinophilic cytoplasm, and deeply basophilic chief cells at the base of the glands.

Figure 32

Hyperplasia of the Glandular Epithelium of the Stomach in a Male B6C3F1/N Mouse Administered 250 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Note that there is disorganization (piling up) and a slight increase in the number of epithelial (chief) cells lining the gland (arrows).

Figure 33

Low Magnification of the Ethmoid Turbinates (Level III Section) in the Nose of a Female B6C3F1/N Mouse Administered 250 mg/kg Indole-3-carbinol by Gavage for Two Years (H&E)

Histologically normal olfactory epithelium is indicated on the left side and along the nasal septum of the nasal cavity (thin arrows). Note that the olfactory epithelium lining the dorsal meatus (thick arrows) is thinner (atrophy) than the normal epithelium.

Figure 34

Higher Magnification of Figure 33 (H&E)

Note that the height of segments of the olfactory epithelium is reduced (atrophy) to a single layer of cells (thick arrows) compared to the histologically normal olfactory epithelium (thin arrows).

Figure 35

Low Magnification of the Ethmoid Turbinates (Level III Section) in the Nose of a Female B6C3F1/N Mouse Administered 250 mg/kg Indole-3-carbinol by Gavage for Two Years Showing Respiratory Epithelial Metaplasia in the Olfactory Epithelium (H&E)

Note that the olfactory epithelium lining the upper one-third of the nasal septum and the adjacent meatuses is bilaterally replaced by a metaplastic respiratory epithelium (arrows).

Figure 36

Higher Magnification of Figure 35 (H&E)

Compared to histologically normal olfactory epithelium (thin arrows), in the affected segment, normal olfactory epithelium is replaced by ciliated, cuboidal to tall, columnar epithelial cells (thick arrows). The ciliated epithelium extends into and replaces the epithelium of the submucosal glands. Note inflammatory cells and cellular debris in the nasal passage (asterisks).