# Materials and Methods

## Procurement and Characterization

### Indole-3-carbinol

Indole-3-carbinol was obtained from ChemPacific Corporation (Baltimore, MD) in one lot (CHP801001) that was used during the 3-month and 2-year studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle Columbus Support Services (Columbus, OH) and the study laboratories, Southern Research Institute (SRI) (Birmingham, AL) for the 3-month studies and Battelle Columbus Operations (Columbus, OH) for the 2-year studies (Appendix I). Karl Fischer titration and elemental analyses were performed by Galbraith Laboratories, Inc. (Knoxville, TN). Reports on analyses performed in support of the indole-3-carbinol studies are on file at the National Institute of Environmental Health Sciences.

Lot CHP801001 of the test chemical, a yellow crystalline solid, was identified as indole-3-carbinol by the analytical chemistry laboratory using infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by the study laboratories using IR and proton NMR (SRI only) spectroscopy. Karl Fischer titration was used to determine the water content; elemental analyses were used to determine the carbon, hydrogen, and nitrogen content; and the melting point was determined using a differential scanning calorimeter. The purity was determined by the analytical chemistry laboratory using high-performance liquid chromatography (HPLC) with ultraviolet detection. Karl Fischer titration indicated 1.3% water. Elemental analyses for carbon, hydrogen, and nitrogen were consistent with the theoretical values, and the melting point was 99.3°C, consistent with the manufacturer’s Certificate of Analysis. HPLC analysis indicated one major peak with six impurities, each 0.1% or greater of the total peak area with a combined area of 2.8% of total peak area in the chromatogram. The overall purity of lot CHP801001 was determined to be approximately 97%.

To ensure stability, the bulk chemical was stored at −20°C, protected from light in amber glass containers sealed with Teflon^®^-lined lids. Periodic reanalyses of the bulk chemical were performed by the study laboratory twice during the 3-month studies and approximately every 6 months during the 2-year studies using HPLC; no degradation of the bulk chemical was detected.

### Corn Oil

Corn oil was used as the vehicle for the formulations and was obtained from Red Diamond, Inc. (Birmingham, AL), in one lot that was used in the 3-month studies and from Spectrum Chemicals and Laboratory Products (Gardena, CA) in seven lots and Sigma-Aldrich (St. Louis, MO) in three lots that were used in the 2-year studies. Analysis of the corn oil for peroxides was performed by potentiometric titration, and each lot was within the acceptable range of less than or equal to 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing the appropriate amount of milled indole-3-carbinol with corn oil to achieve the required concentrations (Table I-2). Dose formulations were stored in amber glass vials sealed with Teflon^®^-lined lids at 5°C for up to 41 days.

Homogeneity, gavageability, and resuspendability studies were performed on 60 mg/mL dose formulations, and stability studies were performed on 1 mg/mL formulations by the analytical chemistry laboratory using HPLC. Homogeneity was confirmed, and gavageability was confirmed for a 20-gauge gavage needle. Resuspendability was confirmed for dose formulations that had been stored for 14 days at 5°C. Stability was confirmed for at least 8 days for formulations stored in amber glass vials sealed with Teflon^®^-lined lids at 5°C and for 3 hours under simulated animal room conditions. The study laboratory at SRI performed stability studies with 1.6 mg/mL dose formulations using HPLC, and stability was confirmed for at least 41 days for dose formulations stored in amber glass vials sealed with Teflon^®^-lined lids at 5°C. Prior to the 2-year studies, the study laboratory at Battelle Columbus Operations performed homogeneity studies on 6.25, 15, 25, and 60 mg/mL dose formulations and gavageability studies on 60 mg/mL dose formulations using HPLC; homogeneity and gavagability were confirmed.

Periodic analyses of the dose formulations of indole-3-carbinol were performed by the study laboratories using HPLC. During the 3-month studies, the dose formulations were analyzed three times; all 15 of the dose formulations for rats and all 15 for mice were within 10% of the target concentrations (Table I-3). Animal room samples of these dose formulations were also analyzed; all 15 for rats and all 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 2 months (Table I-4). Of the dose formulations analyzed, all 72 for rats and all 36 for mice were within 10% of the target concentrations; all 24 of the animal room samples for rats and all 12 for mice were within 10% of the target concentrations.

## Animal Source

Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY) for the 3-month studies. For the 2-year studies, male and female Harlan Sprague Dawley rats and B6C3F1/N mice were obtained from Harlan Sprague Dawley, Inc. (Indianapolis, IN), and Taconic Farms, Inc. (Germantown, NY), respectively. In the interim between conducting the 3-month studies and the initiation of the 2-year studies, NTP discontinued use of the F344/N rat in toxicity and carcinogenicity studies.

NTP has previously conducted seven separate 2-year studies in Sprague Dawley rats based on prior observations by Kociba et al.^73^ that Sprague Dawley rats are sensitive to the effects of dioxin-like compounds^74-80^. Based on the role of indole-3-carbinol as an agonist ligand for the aryl hydrocarbon receptor, a dioxin-responsive mechanism, Harlan Sprague Dawley rats were selected for the 2-year study.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to indole-3-carbinol and to determine the appropriate doses to be used in the 2-year studies. The doses selected for the 3-month studies were based on study results supplied by the National Cancer Institute (NCI) that provided sufficient information in rats to determine appropriate doses to obtain a no-observed-adverse-effect level and a possible maximum tolerated dose. On receipt, the rats and mice were 4 to 5 weeks old. Rats were quarantined for 12 (females) or 13 (males) days and mice were quarantined for 14 (males) or 15 (females) days. Rats were 5 (females only) to 6 weeks old and mice were 6 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K).

Groups of 10 male and 10 female core study rats were administered 0, 18.75, 37.5, 75, 150, or 300 mg indole-3-carbinol/kg body weight in corn oil by gavage, and groups of 10 male and 10 female mice were administered 0, 15.6, 31.25, 62.5, 125, or 250 mg/kg, 5 days per week for 14 weeks. These initial doses were selected based on published literature, additional data provided from a 3-month rat study being conducted by the NCI^20^, and a pilot study conducted in Sprague Dawley rats (unpublished data). Crowell et al.^20^ demonstrated effects in rats at 100 mg/kg; increased incidences of centrilobular hepatocyte hypertrophy, and increased liver, kidney, and spleen weights were observed in males, and increased liver and kidney weights were observed in females at this dose. In a pilot study, exposure to 200 mg/kg indole-3-carbinol for 6 weeks induced a 10% decrease in body weight and a 20% increase in liver weight. In mice, neurological effects and increased mortality have been observed at doses of 500 mg/kg. Clinical pathology study groups of 10 male and 10 female rats were administered the same doses as the core study rats 5 days per week for 25 days. Vehicle control animals received the corn oil vehicle alone. Feed and water were available ad libitum. Rats and female mice were housed five per cage; male mice were housed individually. Clinical findings for core study rats and mice were recorded weekly. The animals were weighed initially; on day 2 (female mice), 3 (male animals), or 4 (female rats); weekly; and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Gavage Studies of Indole-3-carbinol

Three-month Studies | Two-year Studies
Study Laboratory
Southern Research Institute (Birmingham, AL) | Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/N rats B6C3F1/N mice | Harlan Sprague Dawley rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Rats: Harlan Sprague Dawley, Inc. (Indianapolis, IN)
| Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 12 (females) or 13 (males) days Mice: 14 (males) or 15 (females) days | Rats: 13 (males) or 14 (females) days Mice: 18 (females) or 19 (males) days
Average Age When Studies Began
Rats: 5 to 6 weeks Mice: 6 to 7 weeks | 6 to 7 weeks
Date of First Dose
Core study rats: August 30 (females) or 31 (males), 2004 Mice: September 1 (males) or 2 (females), 2004 | Rats: March 14 (males) or 15 (females), 2007 Mice: April 2 (females) or 3 (males), 2007
Duration of Dosing
5 days per week for 14 weeks | 5 days per week for 104 (male rats) or 105 weeks
Date of Last Dose
Core study rats: November 30 (females) or December 1 (males), 2004 Mice: December 2 (males) or 3 (females), 2004 | Rats: March 10 (males) or 12 (females), 2009 Mice: March 31 (females) or April 2 (males), 2009
Necropsy Dates
Core study rats: December 1 (females) or 2 (males), 2004 Mice: December 3 (males) or 4 (females), 2004 | Rats: March 9 to 11 (males) or 12 and 13 (females), 2009 Mice: March 30 to April 1 (females) or April 1 to 3 (males), 2009
Average Age at Necropsy
19 to 20 weeks | Rats: 110 to 111 weeks
| Mice: 110 (females) to 112 weeks
Size of Study Groups
Core study: 10 male and 10 female rats and mice | Core study: 50 males and 50 females
Clinical pathology study: 10 male and 10 female rats | Special intestine study: 10 male rats Microarray study: Five vehicle control female rats and five 300 mg/kg female rats
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
Rats: 5 Mice: 1 (males) or 5 (females) | Rats: 3 (males) or 5 (females) Mice: 1 (males) or 5 (females)
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least once weekly | Same as 3-month studies
Water
Tap water (Birmingham municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum
Cages
Polycarbonate (Lab Products, Inc., Maywood, NJ), changed once (male mice) or twice weekly | Same as 3-month studies except from Lab Products, Inc., Seaford, DE; rotated every 2 weeks
Bedding
Irradiated hardwood bedding chips (P.J. Murphy Forest Products, Inc., Montville, NJ), changed once (male mice) or twice weekly | Irradiated Sani-Chips® (P.J. Murphy Forest Products, Inc., Montville, NJ), changed once (male mice) or twice weekly
Rack Filters
Reemay^®^ spun-bonded polyester (Andico, Birmingham, AL), changed every 2 weeks | Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Maywood, NJ), changed every 2 weeks | Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Doses
Rats: 0, 18.75, 37.5, 75, 150, or 300 mg/kg in corn oil by gavage (dosing volume 5 mL/kg) Mice: 0, 15.6, 31.25, 62.5, 125, or 250 mg/kg in corn oil by gavage (dosing volume 10 mL/kg) | Rats: Core study rats and special intestine study male rats 0, 75, 150, or 300 mg/kg and microarray study female rats 0 or 300 mg/kg in corn oil by gavage (dosing volume 5 mL/kg) Mice: 0, 62.5, 125, or 250 mg/kg in corn oil by gavage (dosing volume 10 mL/kg)
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, day 2 (female mice), day 3 (male rats and mice), day 4 (female rats), weekly, and at the end of the studies; clinical findings for core study animals were recorded weekly. | Observed twice daily; core study animals were weighed initially, weekly for the first 13 weeks, monthly thereafter, and upon study termination; clinical findings for core study animals were recorded at week 5, monthly, and at the end of the studies.
Method of Euthanasia
Carbon dioxide asphyxiation | Same as 3-month studies
Necropsy
Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus of core study rats and mice. | Necropsies were performed on all core study animals and special intestine study male rats.
Clinical Pathology
Blood was collected from the retroorbital sinus of clinical pathology rats on days 4 and 25 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats). Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, nucleated erythrocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids | None
Histopathology
Complete histopathology was performed on core study vehicle control rats and mice, 300 mg/kg rats, and 250 mg/kg mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice only), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lungs, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. In addition, the liver, mesenteric lymph node, and small intestine were examined in all dosed groups of rats, and the liver and mesenteric lymph node (females only) were examined in all dosed groups of mice. | Complete histopathology was performed on all core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. The small intestines were examined in five special intestine study male rats at 1 week and five special intestine study male rats at 4 weeks. Extended gross and microscopic reviews were performed on the residual uterine wet tissue from all experimental groups of female rats.
Sperm Motility and Vaginal Cytology
At the end of the studies, spermatid and sperm samples were collected from 0, 75, 150, and 300 mg/kg core study male rats and 0, 62.5, 125, and 250 mg/kg male mice. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from 0, 75, 150, and 300 mg/kg core study female rats and 0, 62.5, 125, and 250 mg/kg female mice. | None
Cytochrome P450 Activities
Liver (median, left, and right lobes) and lung (right lobe) samples were collected from 10 male and 10 female core study rats and mice at necropsy. CYP1A1 activity in the liver and lung and CYP1A2 activity in the liver were measured. | None
Microarray Study
None | Liver tissue of five vehicle control female rats and five 300 mg/kg female rats was collected and processed to evaluate transcriptional changes in the liver at a 3 months (Appendix L).

Liver (median, left, and right lobes) and lung (right lobe) samples were collected from 10 male and 10 female core study rats and mice at necropsy for determination of cytochrome P450 1A1 and 1A2 activities. Liver and lung samples were weighed, minced, and frozen until analysis. CYP1A1 in the liver and lung and CYP1A2 in the liver were measured based on the activities of 7-ethoxyresorufin-O-deethylase (EROD) or acetanilide-4-hydroxylase (A4H), respectively. Microsomal suspensions were prepared using the CaCl_2_ aggregation method described by Schenkman and Cinti^81^. The concentration of protein in each suspension was determined by the Lowry method^82^. EROD activities were determined by spectrofluorometric methods, including those of Chang and Waxman^83^ for liver, and A4H activities were determined using HPLC^84^.

Blood was collected from the retroorbital plexus of clinical pathology study rats under carbon dioxide anesthesia on days 4 and 25 and, using the same method, blood was collected from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats) analyses. For hematology analyses, blood from each animal was collected into a tube containing EDTA. Erythrocyte, platelet, and leukocyte counts, hematocrit values, hemoglobin concentration, mean cell volume, mean cell hemoglobin, mean cell hemoglobin concentration, and reticulocyte counts were determined using an Advia^®^ 120 Hematology System (Bayer, Inc., Tarrytown, NY) and reagents from the instrument manufacturer. For clinical chemistry analyses, blood was collected into a tube containing no anticoagulant. Clinical chemistry analyses were performed using a Hitachi 911 Chemistry Analyzer (Roche Diagnostics Corporation, Indianapolis, IN). Reagents were supplied by the instrument manufacturer. The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on core study rats administered to 0, 75, 150, or 300 mg/kg and mice administered to 0, 62.5, 125, or 250 mg/kg. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, right testis, and thymus of core study rats and mice were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on all vehicle control and 300 mg/kg core study rats and all vehicle control and 250 mg/kg mice. In rats, the liver, mesenteric lymph node, and small intestine were examined in all dosed groups; in mice, the liver and mesenteric lymph node (females only) were examined in all dosed groups. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^85^ and Boorman et al.^86^.

## Two-year Studies

### Study Design

Groups of 50 male and 50 female rats were administered 0, 75, 150, or 300 mg indole-3-carbinol/kg body weight in corn oil gavage, and groups of 50 male and 50 female mice were administered 0, 62.5, 125, or 250 mg/kg, 5 days per week for 104 (male rats) or 105 weeks. To further investigate the pathogenesis of treatment-related increased incidences of dilation of lymphatics of the duodenum, jejunum, and mesenteric lymph nodes observed in the 3-month studies^87^, an additional five male rats per special intestine study group were administered indole-3-carbinol for 1 or 4 weeks. To evaluate transcriptional changes in the liver, liver tissue from five vehicle control female rats and five 300 mg/kg female rats was collected and processed for microarray analyses at 3 months (Appendix L).

Rats were quarantined for 13 (males) or 14 (females) days and mice were quarantined for 18 (females) or 19 (males) days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats and mice were approximately 6 to 7 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K).

Male rats were housed up to three per cage, female rats and mice were housed up to five per cage, and male mice were housed individually. Feed and water were available ad libitum. Cages and racks were rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix J.

### Clinical Examinations and Pathology

All animals were observed twice daily. Body weights of core study animals were recorded initially, weekly for the first 13 weeks, monthly thereafter, and upon study termination. Clinical findings were recorded at week 5, monthly, and upon study termination.

Complete necropsies and microscopic examinations were performed on all core study rats and mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except, initially, eyes were fixed in Davidson’s solution and testes were fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. In the standard evaluation of the uterus, a transverse section through each uterine horn, approximately 0.5 cm cranial to the cervix, was collected for histopathological evaluation. In an extended review, all residual uterine, cervical and vaginal tissue stored in 10% neutral buffered formalin were opened (longitudinally) and examined for untrimmed potential gross lesions. All untrimmed potential lesions found were collected and in addition to the remaining segments of uterus were processed histologically and sectioned longitudinally for histopathological examination. Tissues examined microscopically are listed in Table 1.

Complete necropsies were performed on all special intestine study male rats. At necropsy, the small intestines (duodenum and jejunum) were collected, fixed, and preserved in 10% neutral buffered formalin. Additionally, samples of the duodenum and jejunum were cryopreserved. Microscopic evaluations of the small intestine were performed on five special study male rats at 1 week and five special study male rats at 4 weeks. The cryosections of the small intestine (duodenum and jejunum) were stained with the Oil-red-O and Sudan Black histochemical stains that are specific for detecting fat (lipid) in tissue sections.

At 3 months, liver tissue from the left lateral lobe of five vehicle control female rats and five 300 mg/kg female rats was collected, frozen in liquid nitrogen, and transported to Battelle Biomedical Research Center (Columbus, OH) to be processed for RNA isolation and purification, cDNA synthesis, and array hybridization (Appendix L).

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included the liver of rats and mice, small intestine of rats, uterus of female rats, and nose and glandular stomach of mice.

The quality assessment report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^85^ and Boorman et al.^86^. For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^88^.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^89^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^90^ method for testing two groups for equality and Tarone’s^91^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-3, Table B-1, Table B-4, Table C-1, Table C-4, Table D-1, and Table D-4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^92-94^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died prior to terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time^92^. Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^92^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1/N mice^95^. Bailer and Portier^92^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams^96^.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^97^ and Williams^98; 99^. Hematology, clinical chemistry, cytochrome P450, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^100^ (as modified by Williams^101^) and Dunn^102^. Jonckheere’s test^103^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^104^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the Fisher exact test^105^. Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager^106^. For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^107-109^. In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current study. In the historical control database for Sprague Dawley rats, there are only two studies, the current study of indole-3-carbinol and PCB 118. Because both studies were corn oil gavage studies, only same route of administration historical data are presented in this Technical Report for female Sprague Dawley rats.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations^110^. In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of indole-3-carbinol was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli, micronucleated erythrocytes in rat bone marrow, and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division^111; 112^. The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^113^ and the somatic mutation theory of cancer^114; 115^. However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites^116^. A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens)^117; 118^. Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test^119; 120^. However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies^121^. Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.