# Introduction

Figure 1

Indole-3-carbinol (CASRN 700-06-1; Chemical Formula: C_9_H_9_NO; Molecular Weight: 147.18)

Synonyms: 3-(Hydroxymethyl)indole; indole-3-methanol; 3-indolemethanol; 3-indolylcarbinol; 3-indolylmethanol.

## Chemical and Physical Properties

Indole-3-carbinol is an off-white powder with a melting point of 96° to 99°C^1^. It is soluble in benzene, ethanol, and pentane.^2^ Indole-3-carbinol is an unstable compound that undergoes rapid oligomerization in acid pH environments, like the stomach. At low pH, a wide variety of condensation products are formed, ranging from linear and cyclic dimers, trimers, and tetramers to extended heterocyclic compounds such as indolocarbazoles.^3-6^

## Production, Use, and Human Exposure

Indole-3-carbinol is a naturally formed breakdown product of glucosinolate glucobrassicin, a component found in cruciferous vegetables in the Brassica genus, which includes brussels sprouts, cauliflower, cabbage, kale, rape, turnips, and broccoli. Although indole-3-carbinol is not naturally occurring in these vegetables, it is readily formed from glucobrassicin via a thioglucosidase-mediated autolytic process during the simple mechanics of cutting, chewing, mashing, or cooking. Myrosinase, an enzyme that is usually compartmentalized within the plant cells, is released when the cells are physically damaged. Free myrosinase readily catalyzes the hydrolysis of glucobrassicin to indole-3-carbinol^7^. Indole-3-carbinol is also marketed and promoted as a dietary supplement that is available at health food stores, pharmacies, and via the internet. Indole-3-carbinol may be sold as the sole ingredient in products or in combination nutraceuticals that contain a variety of botanicals and/or vitamins. The health claims for indole-3-carbinol-containing supplements include cancer prevention, antioxidant protection, hormone balance, immune system enhancement, and hepatic and intestinal detoxification.

The most widespread exposure of humans to indole-3-carbinol occurs through the consumption of glucobrassicin, the indole-3-carbinol precursor found in Brassica vegetables. Brassica vegetables are frequently consumed in the diets of both Western and Eastern cultures.^6^ In the United States population, the daily intake of indole-3-carbinol from cruciferous vegetables has been estimated to be 2.6 mg or less.^2^ Estimated mean daily intake of glucobrassicin in the United Kingdom is approximately 12.5 and 7 mg per person from fresh and cooked sources, respectively, and the average daily consumption of indole-3-carbinol is approximately 0.1 mg/kg body weight. Based on levels of brassica consumption in the Japanese diet, the average daily intake of indole precursors can range up to 112 mg per day, which corresponds to a daily dose of approximately 1.6 mg/kg for a 70 kg person^8; 9^. Carlson et al.^10^ reported concentrations of 3-indolylmethyl glucosinolates in broccoli (42.2 to 71.7 mmol/100 g fresh weight), brussels sprouts (327.8 to 469.4 mmol/100 g), cauliflower (18.8 to 104.7 mmol/100 g), collard greens (67.2 to 165.3 mmol/100 g), kale (44.2 to 102.3 mmol/100 g), mustard greens (4.2 to 12.2 mmol/100 g), and kohlrabi (27.7 mmol/100 g).

Humans are also exposed to indole-3-carbinol as a dietary supplement. The daily dose of 200 to 400 mg that has been used to investigate the therapeutic value of indole-3-carbinol in clinical trials is also the recommended dose indicated by package labeling on indole-3-carbinol products. These daily exposures are equivalent to 2.9 to 5.7 mg/kg for a 70 kg person.

## Regulatory Status

While the U.S. Food and Drug Administration (FDA) does not regulate food that contains precursors of indole-3-carbinol, compounds that are marketed as dietary supplements are regulated under the Dietary Supplement Health and Education Act of 1994. Indole-3-carbinol is not listed by the FDA as a Generally Recognized as Safe substance.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

The disposition of indole-3-carbinol has been studied in experimental animals. In rainbow trout, 25% of an oral dose of 40 mg/kg [^3^H]indole-3-carbinol given via feed or gavage was recovered in the water 72 hours following exposure reflecting the excretion via urine and gills^11^. Radioactivity in the liver between 48 and 72 hours following exposure accounted for 1% to 1.5% of the total administered dose. In goats, approximately 80% of the dose was recovered in urine 72 hours following a 2-hour infusion of 0.27 mmol/kg [^3^H]indole-3-carbinol. Following exposure of F344 rats to 2,000 ppm [^3^H]indole-3-carbinol in the diet, steady-state excretion in urine and feces was achieved at 40 hours and 112 hours, respectively, following the beginning of exposure. Excretion in these two routes accounted for approximately 75% of the dose with about 77% of the excreted dose recovered in the feces^12^. Although not demonstrated in rats, biliary excretion has been shown to be a major route of excretion in rainbow trout, suggesting that the high fecal excretion in rats could be due to biliary excretion and not due to poor absorption. Following repeated gavage administration of 1 mmol/kg indole-3-carbinol in rats (a comparable daily dose as in the feeding study above) for 6 days followed by 1 day of dosing with [^3^H]indole-3-carbinol, indole-3-carbinol-equivalents in the liver at 1.5, 3, and 6 hours, respectively, were 0.97%, 1.34%, and 2.45% of the total administered dose. However, the concentration of indole-3-carbinol equivalents in blood, kidney, tongue, or lung changed slightly over the same time period. Of the total radioactive equivalents in the liver, the extractable radioactivity decreased from 45% to 31% from 1.5 to 6 hours. In female CD-1 mice following gavage administration of 250 mg/kg, indole-3-carbinol was rapidly absorbed, and the peak plasma concentration was reached within 15 minutes^13^. The concentration in plasma fell below the limit of detection 1 hour following administration suggesting rapid excretion. As observed in rats, indole-3-carbinol was extensively distributed to tissues including the kidney, liver, heart, and brain, with the highest levels detected in the liver.

Acidic incubation of indole-3-carbinol in vitro resulted in the formation of multiple condensation products^14-16^. The major products formed were the dimer, 3,3′-diindolylmethane (DIM), and two trimers, [2-(indol-3-yl-methyl)-indol-3-yl]indol-3-ylmethane (LTR) and 5,6,11,12,17,18-hexahydrodiindolo [2′,3′:4,5;2″,3″:7,8] cyclonona[1,2-b]indole (CTI). The formation of oligo-mers was strongly pH dependent. Incubation of indole-3-carbinol at pHs less than 3 resulted in approximately equal formation of the three oligomers, whereas incubation at pHs greater than 3 produced large amounts of DIM and LTR but not CTI; CTI was detected at pHs greater than 4.5^14^.

The metabolism of indole-3-carbinol has been investigated in in vitro preparations of rat and chicken embryo liver.^6^ These studies demonstrated that the first step in the metabolic route was the formation of indole-3-carboxaldehyde, via both the mixed function oxidase and alcohol dehydrogenase systems. Further metabolism by these systems resulted in the formation of 5-hydroxy-indole-carboxaldehyde and indole-3-carbox-ylic acid.

The oligomeric products of indole-3-carbinol are thought to be primarily responsible for eliciting the biological effects observed for indole-3-carbinol. In rats and fish, DIM, LTR, and 1-(3-hydroxymethyl)-indolyl-3-indolyl-methane were detected in the liver following oral administration of indole-3-carbinol; the parent indole-3-carbinol was not detected^11; 12; 14^. The pattern of condensation products in the gastric contents strongly resembled the pattern obtained after in vitro acid condensation at pHs between 4.5 and 5. In extracts from stomach tissue, small intestine, and liver, the patterns of oligomers were similar to that found in the stomach contents^14^. In addition, indolo[3,2b] carbazole (ICZ), a potent aryl hydrocarbon receptor (AhR) agonist was also identified^14^. When male Sprague Dawley rats were fed dietary indole-3-carbinol or a cabbage-supplemented diet (25% cabbage) for 5 days, ICZ levels were increased in tissues and excreta.^5^ In mice as in rats, acid condensation products were detected in plasma and in some tissues; the parent was also detected in plasma, suggesting that indole-3-carbinol was not completely converted to acid condensation products in the gut. In mice, ICZ was detected only in the liver^13^. The peak plasma concentrations of DIM and LTR were approximately one sixth and one tenth that of indole-3-carbinol and the levels persisted much longer than the parent. In addition to the acid condensation products, minor oxidative metabolites of indole-3-carbinol, indol-3-carboxylic acid and indole-3-carboxalde-hyde were also detected in plasma from mice. Tissues profiles of metabolites were similar to the plasma profile suggesting that these metabolites were in equilibrium with the plasma^13^. The proposed metabolic scheme for indole-3-carbinol following oral administration in rodents is shown in Figure 2.

Figure 2

Proposed Metabolic Scheme for Indole-3-carbinol following Oral Administration in Rodents

Adapted from Stresser et al.^12^ and Anderton et al.^13^.

### Humans

No published data are available regarding the absorption, distribution, metabolism, or excretion of indole-3-carbinol in humans.

## Toxicity

### Experimental Animals

The results of short-term studies suggest that the liver is a target organ for indole-3-carbinol. In male guinea pigs, indole-3-carbinol exposure induced steatosis in the liver, primarily in periportal hepatocytes^17^. In male CD-1 mice exposed to 500 or 750 mg/kg per day in the feed for 5 days, indole-3-carbinol significantly increased liver weight and microsomal protein content^18^. This study also showed that indole-3-carbinol alters cholesterol homeostasis. Doses of 500 and 750 mg/kg caused significant increases in hepatic acyl-CoA:cholesterol acyltransferase activity and lowered hepatic cholesterol levels. In male CD-1 mice exposed to 100 mg indole-3-carbinol/kg for 10 days, hepatotoxicity was indicated by reduced glutathione levels and dose-dependent increases in plasma alanine aminotransferase and ornithine transcarbamylase activities^19^. This dose also elicited a 16-fold increase in ethoxyresorufin-O-deethylase activity. Increased liver weights and hepatic cytochrome P450 (CYP) activities were also observed in male and female CD rats exposed to 50 mg indole-3-carbinol/kg body weight^20^. In Sprague Dawley rats exposed to 50 mg/kg, indole-3-carbinol significantly induced total hepatic CYP levels in both sexes^21^. Hepatic CYP1A1 and CYP1A2 were significantly induced in both sexes. Indole-3-carbinol also induced expression of hepatic CYP3A2 and CYP1A1 in the colon of both sexes of rats.

The hepatic induction of CYP1A by indole-3-carbinol is mediated via the AhR, a transcription factor that plays a critical mechanistic role in the toxicity and carcinogenicity of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD). Indole-3-carbinol and its major acid condensation products are AhR agonists^22-24^. The toxicological implication of indole-3-carbinol-induced AhR activation is not clearly understood.

Studies also suggest that the nervous system is a target organ for indole-3-carbinol. In male Sprague Dawley rats treated with a single subcutaneous dose of 225, 300, or 500 mg/kg, indole-3-carbinol induced sedation ataxia and loss of righting reflex and sleep^25^. Three out of four rats died 1 to 3 hours after exposure to 500 mg/kg; animals were comatose before death. In male CD-1 mice administered doses of 100 to 500 mg/kg, indole-3-carbinol produced dose-dependent increases in neurological impairment, primarily associated with locomotion, as measured by subjective evaluation of appearance, posture, and motor activities^19^. At 500 mg/kg, animals became comatose. In male guinea pigs, clinical signs of intoxication were apparent within 48 hours of administration (per os) of 0.3 mg indole-3-carbinol/kg body weight in 10% Cremophor^®^ castor oil^17^. Signs included moderate depression, trembling, tachypnea, polypnea, irregular breathing, and increased vesicular lung sounds. In the lung, indole-3-carbinol induced interstitial pneumonia with septal hyperemia.

### Humans

In general, most studies in humans have not reported overt toxicity of indole-3-carbinol. In a double-blind, placebo-controlled dose range-finding study, women at risk for breast cancer were administered up to 400 mg indole-3-carbinol for 4 weeks^26^. A slight increase in alanine aminotransferase, indicating hepatocellular membrane leakage, was observed in two participants (dose not specified). Doses of 300 mg (4.2 mg/kg for a 70 kg person) increased the ratio of 2-hydroxyestrone to 16α-hydroxyestrone in the urine, which reflects a shift in estrogen metabolism towards less estrogenic metabolites. Similar results on urinary estrogen metabolites were observed in women with cervical dysplasia administered 200 or 400 mg indole-3-carbinol/day^27^ and women with systemic lupus erythematosis administered 375 mg/day for 3 months^28^. A single subject developed a skin rash that went away after cessation of treatment, and then reappeared after indole-3-carbinol was readministered^28^.

## Reproductive and Developmental Toxicity

### Experimental Animals

Two investigative studies have reported on the results of in utero exposure to indole-3-carbinol on reproduction and development. Pregnant Harlan Sprague Dawley rats were administered indole-3-carbinol in corn oil via gavage (1 or 100 mg/kg body weight; three to five dams per dose group) on gestational day (GD) 15 and reproductive parameters were assessed in male offspring on postnatal day (PND) 62^29^. Indole-3-carbinol significantly decreased anogenital distance and crown-rump length on PND 1. When normalized to pup body weight on PND 1 however, there were no effects on these endpoints. Daily sperm production/g testicular parenchyma was significantly decreased at both doses of indole-3-carbinol; however, daily sperm production/testis was only reduced at 100 mg/kg. Exposure did not adversely affect sperm number in the total epididymis or in the head plus body or tail of the epididymis, but did increase epididymal transit time of sperm by more than 1 day in rats exposed to 1 mg/kg. Pregnant Holtzman rats (up to four dams/group) were administered either 200 or 300 mg indole-3-carbinol/kg on GDs 8 and 9^25^. Dams dosed with 300 mg/kg displayed lower body weight gain over GDs 9 to 11. Fetal weights on GD 20 were significantly depressed only in the 200 mg/kg group. There were no effects of indole-3-carbinol on embryonic death or fetal development.

### Humans

No reports on the effect of indole-3-carbinol on reproduction or development in humans were found in the literature.

## Carcinogenicity

### Experimental Animals

No 2-year carcinogenicity studies of indole-3-carbinol in animals were found in the literature. However, several studies have investigated the effect of indole-3-carbinol on chemical-induced tumorigenesis. In initiation-promotion models of carcinogenesis, indole-3-carbinol is a tumor promoter that enhances colon tumors in rats and mice as well as pancreatic tumors in hamsters^30; 31^. Exposure to indole-3-carbinol promotes aflatoxin B_1_-initiated hepatocarcinogenesis in rainbow trout^32^ and thyroid gland tumors in Sprague Dawley rats^33^. In studies designed to assess inhibition, indole-3-carbinol did not induce tumors when administered without an initiator in Sprague Dawley rats, ACI/N rats, or ICR/Ha mice^34-36^. In female Donryu rats, a strain with a high incidence of endometrial cancer, exposure to 200, 500, or 1,000 ppm indole-3-carbinol in the diet for 660 days resulted in a dose-dependent decrease in the incidence of endometrial adenocarcinoma^37^.

Dietary administration of indole-3-carbinol inhibited benzo[a]pyrene-induced neoplasia in the forestomach in ICR/Ha mice and 7,12-dimethylbenz[a]anthracene-induced mammary gland tumor formation in Sprague Dawley rats^34^. In female C3H/OuJ mice exposed to indole-3-carbinol in the diet, mammary gland tumor incidence and multiplicity were significantly decreased, and tumor latency was prolonged^38^. In a three-generation study in Balb/cfC3H mice, exposure to indole-3-carbinol did not affect mammary gland tumor incidence, however the latency of mammary gland tumors was increased^39^. Inhibition of tumorigenesis has been observed for diethylnitrosamine-induced hepatocarcinogenesis in ACI/N and Sprague Dawley rats and in the infant mouse model^35; 40; 41^. Indole-3-carbinol also inhibits tumorigenesis in the lung in various animal models^42-45^.

### Humans

Consumption of cruciferous vegetables has been associated with a decreased risk of cancer in humans^46-49^. Based on epidemiologic evidence and results from animal studies, the National Research Council, Committee on Diet, Nutrition, and Cancer has recommended increased consumption of Brassica vegetables as a measure to decrease the incidence of human cancer. The anticarcinogenic activity of cruciferous vegetables has been attributed to indole-3-carbinol and its acid-condensation products^3; 50-53^.

Indole-3-carbinol has been promoted and investigated for treatment and prevention of various types of common cancers. Indole-3-carbinol has been shown to inhibit tumorigenesis in multiple tissues. As a result, it has been the focus of several early-phase clinical trials to assess efficacy in the treatment of breast cancer, cervical dysplasia, systemic lupus erythematosus, and recurrent respiratory papillomatosis in adults and children^26-28; 52; 54-58^. In general, doses in these clinical studies ranged between 200 and 400 mg indole-3-carbinol per day.

## Genetic Toxicity

The genotoxic potential of indole-3-carbinol has been evaluated in a limited number of bacterial mutagenicity assays and in vitro and in vivo mammalian cell tests. In the majority of tests, indole-3-carbinol gave negative results. However, indole-3-carbinol undergoes chemical reactions in the acidic environment of the stomach to produce compounds that are mutagenic or that can increase the mutagenic potential of other compounds.

Indole-3-carbinol was weakly mutagenic in Salmonella typhimurium strain TA100 [lowest effective dose (LED) of 312.5 μg/plate] in the presence or absence of metabolic activation (S9 mix)^59^. In contrast, no mutagenicity was detected with indole-3-carbinol in S. typhimurium strains TA98, TA1535, or TA1537 [highest ineffective dose (HID) of 1,250 μg/plate] or Escherichia coli strain WP2 uvrA/pKM101 (HID of 2,500 μg/plate), with or without S9 mix^59^. Additionally, in a differential survival assay, E. coli deficient for nucleotide excision repair and recombinational repair were no more sensitive to indole-3-carbinol (5 µg/mL) than a strain proficient for these DNA repair pathways^60^.

Indole compounds present in Brassica vegetables (e.g., broccoli, brussels sprouts, and cabbage) may be precursors of mutagens formed during the process of digestion as, in the presence of nitrites, they can be converted to N-nitroso compounds at low pH^61-63^. One study investigated whether indole-3-carbinol became mutagenic following reaction with sodium nitrite at pH 3 at 37°C. Under those conditions, indole-3-carbinol formed a nitrosated product that was reported to be directly mutagenic to E. coli WP2 uvrA/pKM101 (LED of 12.5 nmol) and to S. typhimurium strains TA98 and TA100 (LEDs of 12.5 nmol and 50 nmol, respectively)^64^. Furthermore, the mutagenic effects of the nitrosated product were reduced to near-baseline levels in the presence of S9 mix, and the parent molecule, indole-3-carbinol, was not mutagenic in any of the three tester strains, with or without S9 mix^64^. However, the authors did not report the concentration range that was used to study indole-3-carbinol and no actual data were provided, thus preventing independent assessment of the findings.

No increase in mutant frequency was observed in mouse lymphoma L5178Y tk^+/–^ cells treated with indole-3-carbinol in the presence of S9 (HID of 30 μg/mL) or in the absence of S9 (HID of 325 μg/mL)^59^. In vivo, no induction of chromosomal aberrations was observed in bone marrow cells of male Swiss albino mice following a single intraperitoneal injection of 500 mg/kg indole-3-carbinol^65^ or five daily exposures to 5 mg/kg indole-3-carbinol by gavage^66^. In a micronucleus assay, male and female Swiss-Webster mice were administered single doses of indole-3-carbinol (375, 750, or 1,500 mg/kg) by oral gavage and assessed at 24 or 48 hours postexposure for the frequency of micronucleated polychromatic erythrocytes (MN-PCE) in bone marrow^59^. Although no increases in the frequency of MN-PCEs were observed in male mice, a dose-dependent increase in the frequency of MN-PCEs was observed in female mice at 24 hours (LED of 750 mg/kg)^59^.

Indole-3-carbinol has been studied for antimutagenic effects in bacterial mutagenicity assays and mammalian cell in vitro and in vivo assays. No clear evidence of antimutagenic activity was seen in the bacterial mutagenicity assays and effects were mixed for in vitro mammalian cell assays. Evidence of antimutagenicity in the in vivo studies is more consistent, with decreases reported for induction of cytogenetic damage (sister chromatid exchanges and micronuclei) and adduct formation in various tissues following treatment with known genotoxicants such as cyclophosphamide, benzo[a] pyrene, 2-amino-3-methylimidazo[4,5-f]quinoline, and tobacco smoke^66-71^.

In addition to N-nitrosation as described above, indole-3-carbinol can undergo acid condensation in the stomach to produce 3,3′-diindolylmethane. One study showed that 3,3′-diindolylmethane can increase the genotoxic effects of a known carcinogen, aflatoxin B1 (AFB1). Pre-incubating primary human hepatocytes for 48 hours with 3,3′-diindolylmethane at concentrations of 10 or 50 µM increased the formation of AFB1-DNA adducts fourfold or sixfold, respectively^72^. Furthermore, incubation with 3,3′-diindolylmethane for 48 hours increased the expression of CYP1A1 and CYP1A2 and downregulated glutathione S-transferase mu 1 at the transcriptional level^72^. Therefore, in primary human hepatocytes, 3,3′-diindolylmethane appears to increase the level of Phase I enzymes that produce the genotoxic form of AFB1 (AFB1-8,9-exo-epoxide) and to decrease one of the Phase II enzymes that can detoxify AFB1-8,9-exo-epoxide. No other studies on the genotoxic effects of 3,3′-diindolylmethane were identified.

In summary, results from the few evaluations of the genotoxicity of indole-3-carbinol that were identified in the literature were negative, except for one weakly positive bacterial mutagenicity test result and one study in which a significant increase was observed in MN-PCEs in female (but not male) mice following administration of indole-3-carbinol by oral gavage. In addition, several studies were identified that reported indole-3-carbinol-mediated inhibition of chemical-induced genotoxicity in vivo. However, indole-3-carbinol may undergo reactions in the stomach to produce genotoxic compounds or compounds that can enhance the genotoxicity of other compounds through modulation of key metabolic processes.

## Study Rationale

Indole-3-carbinol was nominated by the National Cancer Institute for toxicity and carcinogenicity testing because of its occurrence in natural products and its potential use as a breast cancer chemopreventive agent. There is very little known about the toxicity of long-term exposure.