# Appendix M Summary of Peer Review Panel Comments

On May 22, 2014, the draft Technical Report on the toxicology and carcinogenesis studies of indole-3-carbinol received public review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. M.E. Wyde, NIEHS, introduced the toxicology and carcinogenesis studies of indole-3-carbinol, a commercially available dietary supplement and natural product by discussing the uses of the chemical and the rationale for study, describing the experimental design, reporting on survival and body weight effects, and commenting on compound-related neoplastic and nonneoplastic lesions in rats and mice. The proposed conclusions for the 2-year studies were no evidence of carcinogenic activity in male Sprague Dawley rats, some evidence of carcinogenic activity in female Sprague Dawley rats, clear evidence of carcinogenic activity in male B6C3F1/N mice, and no evidence of carcinogenic activity in female B6C3F1/N mice.

Dr. Carpenter noted that there were no written or oral public comments concerning this report.

Dr. Perdew, the first primary reviewer, noted the study was well done. He questioned if high concentrations of indole-3-carbinol were insoluble in corn oil, and if the insolubility might affect the results. He asked whether any inflammatory markers were examined in tissues or serum. Dr. Wyde said all doses used in the studies were suspensions, and no inflammatory markers were looked at in tissue or serum. Dr. Perdew asked if it was standard practice to not look at inflammatory markers, and Dr. Wyde replied it was. Dr. Perdew questioned a statement in the report regarding comparative affinity for the aryl hydrocarbon receptor (AhR). Dr. Wyde said he could adjust the language accordingly. Dr. Perdew recommended more careful wording for the discussion concerning the mechanism of toxicity for indole-3-carbinol and 2,3,7,8-tetrachlorodibenzo-p-dioxin. Dr. Wyde said National Toxicology Program staff had discussed how much to write about the AhR and dioxins, versus just the mechanism associated with indole-3-carbinol.

Dr. Regan, the second primary reviewer, said the standard and extended uterine examinations should be presented together, as that is the basis of the carcinogenicity conclusion. She suggested less emphasis on the findings from the standard and extended examinations alone in the report, focusing instead on positive trends and statistical significance seen when the two are combined. She noted there was no observable increase in atypical endometrial hyperplasia in the uterine neoplasms. She suggested clarifying the estrous cycle data in cycling F344/N rats. Regarding nose inflammation, she said the animals with foreign material present in the nasal cavity should be shown separately in the incidence table, as inflammation could be attributed to the foreign material. She asked if assays for cytochrome P450 (CYP) induction were conducted on the nose.

Dr. Wyde, responding to Dr. Regan’s comments, said the carcinogenicity call in female rats was based on the combined data, both the standard and extended examinations of the uterus. Dr. Regan recommended limiting discussion in the text to the combined incidences. Dr. J.R. Bucher, NIEHS, noted this was presented based on a historical precedent, with substantial historical control information available. Because there was no substantial historical database in this study, he understood Dr. Regan’s suggestion. Dr. Wyde said he could clarify the estrous cycle characterization data for female F344/N rats. He stated that NTP staff had not conducted assays for CYP induction in the nose. Dr. R.A. Herbert, the NIEHS study pathologist, said foreign bodies are often diagnosed in the nose and often associated with inflammation. NTP diagnoses the foreign body, not the inflammatory change, because the inflammatory change is considered secondary to the foreign body. He described how this issue was approached in the indole-3-carbinol studies. He said in female mice there was only one diagnosis of foreign body in the mid dose group with no associated evidence of inflammation and two diagnoses in the high dose group, both of which were in animals that had a treatment-related diagnosis of inflammation. Dr. Regan suggested adding more information in the report reflective of Dr. Herbert’s statement.

Dr. Mirsalis, the third primary reviewer, said lower doses may not impact the overall conclusions, but it would be good to see if there was a threshold by using lower doses. He said the increases in liver weights were equally striking in rats and mice and recommended bringing the table for mice into the main body of the text from the appendix. The report has an extended discussion about how indole-3-carbinol is an AhR agonist, and compares the responses to those seen with dioxin. The increases in mouse liver tumors could be explained by induction of CYPs resulting in increased liver size, which has been shown to be a significant risk factor for mouse liver tumors; therefore, he recommended removing the dioxin discussion.

Dr. Perdew asked Dr. Mirsalis to clarify his point, because the CYP induction is through the AhR in the liver. Dr. Mirsalis said the response in the mice is different than that seen with dioxin, and noted that in the report, after extensive discussion about dioxin, the conclusion was that the response was not similar to dioxin. Dr. Bucher noted the nomination of this substance was related to the question about how there could be an AhR agonist that was unlike dioxin, and perhaps there was overemphasis in the discussion about dioxin. Dr. Wyde said it would be remiss not to mention the dioxin comparison at all. Dr. Fanucchi recommended adding language to the discussion related to Dr. Bucher’s comments. Dr. Wyde agreed with Dr. Mirsalis that the liver weight data in mice could be brought forward in the report.

Dr. Mirsalis moved to accept the proposed conclusions as written. Dr. Perdew seconded the motion. Dr. Regan recommended changing the conclusion in the female rats from some evidence to equivocal evidence because there was no dose-related increase in malignant uterine neoplasms at the high dose or positive trend test, and because no preneoplastic changes were noted in the uterus. Dr. N.J.Walker, NIEHS, explained that in the level of evidence criteria, some evidence is used when there are treatment-related increases; in this case, there was a pairwise significance against the concurrent vehicle control. Dr. Conner disagreed with mentioning an increase that did not reach statistical significance; thus, he agreed that the call should be equivocal evidence rather than some evidence. Dr. Mirsalis said with the multiple adenocarcinomas involved, the some evidence call was appropriate. Dr. G.E. Kissling, NIEHS, stated statistical significance is only one piece of evidence used to make calls, and that there are cases where a biological increase is seen without reaching statistical significance. Dr. D.E. Malarkey, NIEHS, said it could be difficult to interpret preneoplastic lesions. Dr. Regan said even if the preneoplastic lesions were added in this case, it would not change the numbers. Dr. Carpenter called for a vote on the motion. The panel voted 4 to 2 in favor of the motion, so the conclusions were accepted as written. Drs. Regan and Connor cited their previous comments regarding the uterine neoplasms in rats as their reasons for voting against the motion.