# Appendix L Microarray Analysis

## L.1 Objective

The objective of the microarray study was to evaluate the transcriptional changes in liver from rats exposed to 0 or 300 mg/kg indole-3-carbinol. At 3 months, livers were analyzed from female Harlan Sprague Dawley rats in the 2-year gavage study of indole-3-carbinol.

## L.2 Methods

### L.2.1 RNA Isolation, cDNA Synthesis, and Array Hybridization

Liver tissues were excised from five female rats gavaged with corn oil (vehicle control group) and five female rats gavaged with 300 mg/kg of indole-3-carbinol in corn oil (treated group) Monday through Friday for 3 months and on the termination day approximately 3 hours prior to tissue harvest.

Tissues were immediately frozen in liquid nitrogen at collection and transported to the Battelle Biomedical Research Center (Columbus, OH). The liver tissues were removed and added to lysis buffer. Each sample was then homogenized for 45 seconds using OmniTip^™^ plastic disposable probes (Omni International, Marietta, GA). Following homogenization, samples were centrifuged and the RNA was extracted from the supernatant using the Qiagen RNeasy Midi Kit (Qiagen, Valencia, CA). RNA concentration and purity were determined by ultraviolet analysis using a NanoDrop 1000 spectrophotometer (NanoDrop Technologies, Wilmington, DE). All samples were evaluated by gel electrophoresis using the FlashGel^®^ RNA cassette system (Lonza, Rockland, ME).

Total RNA (5 μg) was used to synthesize double-stranded cDNA for each sample using Affymetrix GeneChip^®^ 3’-Amplification One-Cycle cDNA Synthesis Reagents (Affymetrix, Inc., Santa Clara, CA) according to the manufacturer’s protocol. All incubation steps were performed using a GeneAmp^®^ 2400 thermal cycler (PerkinElmer, Waltham, MA). The cDNA served as a template to synthesize biotin-labeled antisense cRNA using an IVT Labeling Kit (Affymetrix, Inc.). Labeled cRNA was fragmented and hybridized to the Affymetrix Rat Genome 230 2.0 Array as described in the Affymetrix GeneChip^®^ protocol. Chip hybridization, washing, and staining were performed according to the Affymetrix-recommended protocol EukGE-Ws2v5. After washing, the chips were scanned using an Affymetrix GeneChip Scanner 3000 and the acquired data was then further processed by the Affymetrix GeneChip^®^ Operating Software (GCOS) version 1.2.

### L.2.2 Microarray Analysis

The 10 .CEL files representing the 10 liver samples from the study were normalized using the robust multiarray algorithm (RMA)^139^ using GeneSpring v12.6 (Agilent Technologies, Santa Clara, CA). Normalized expression values were baseline-transformed to the median of all samples. A Principal Component Analysis demonstrated clear separation of the samples by treatment group. All chips had a Gapdh 3′/5′ hybridization rate ranging from 1.1 to 1.6. Probesets were filtered to 26,253 (from 31,099) based on signal intensity values, specifically a probeset was retained if its expression values were between 20.0 and 100 percent in 1 out of 10 samples. Identification of probe sets that exhibited a statistically significant difference in intensity was determined by t-test (unpaired) with a P value of < 0.05 and the Benjamini-Hochburg post-hoc test. Probesets that were significantly altered were further filtered using a minimum 1.5-fold difference.

### L.2.3 Ingenuity Pathway Analysis^™^

The 343 probesets exhibiting significant (P < 0.05) differential expression and > 1.5-fold change (up- or down-regulation) were analyzed using the Ingenuity Pathway Analysis^™^ (IPA) (Ingenuity Systems^®^, Inc., Redwood City, CA; <www.ingenuity.com>). The probeset list when translated into genes in IPA corresponded to a total of 243 altered genes (referred to as differentially expressed genes (DEGs). The IPA Core Analysis was performed on February 12, 2014. Enrichment and activation analysis was carried out for IPA Disease or Biological Functions, Toxicity Functions, and Upstream Analysis.

Enrichment P values were calculated using a right-tailed Fisher’s Exact Test combined with a Benjamini-Hochberg method of multiple testing correction. The P value (P < 0.05) was determined by how many DEGs overlapped genes annotated into gene groups (e.g., canonical pathways, biological processes). Activation/inhibition analysis was performed using the annotation in the Ingenuity^®^ Knowledge Base. In order to determine if there was plausible activation/inhibition of Disease or Biological Functions, Toxicity Functions, Transcription Factors, and Chemical Signaling Signatures, a Z-score was calculated. The Z-score was determined by concordance of observed patterns of regulation (up or down) with known effects on biological functions or effects of transcription factors/chemicals (activation or inhibition of target genes) as annotated in the Ingenuity^®^ Knowledge Base. Based on the Z-score, a potential transcription factor was deemed to be activated (Z-score > 2), inhibited (Z-score < −2), or not affected.

## L.3 Results

### L.3.1 Differential Gene Expression

Whole-rat genome Affymetrix 230 2.0 microarrays were used to assess the effect of 300 mg/kg per day of indole-3-carbinol for 3 months on female Sprague Dawley rat liver. Significant differential expression between treated and vehicle control animals occurred in 973 probesets (mapped to 751 Entrez Gene IDs). Of 973 altered probesets, 553 were up-regulated and 420 were down-regulated. When the 973 probesets were subjected to a > 1.5 cutoff, then 343 probesets (corresponding to 243 genes) were altered. The genes represented by the 343 probesets were used for analysis in IPA. The top five up- and down-regulated genes are shown in Table L-1.

The IPA Disease or Biological Functions and liver Toxicity Functions that were activated by indole-3-carbinol treatment primarily relate to phase I and phase 2 xenobiotic/endogenous chemical metabolism and redox pathways. The enriched/activated functions are listed in Table L-2 and Table L-3.

Consistent with the Disease or Biological Functions enrichment results, indole-3-carbinol treatment caused notable differential expression of genes involved in phase I and phase II xenobiotic/endogenous chemical metabolism along with the signaling pathways that mediate the changes in expression of these genes (e.g., Nrf2-mediated Oxidative Stress Response, Aryl Hydrocarbon Receptor Signaling, and Pxr/Rxr Activation). The enriched pathways are listed in Table L-4.

Transcription factor enrichment/activation in IPA suggests a strong activation of Nrf2 (Nfe2l2) signaling along with notable activation of a variety of hepatic chemical response transcription factors Car (Nrli3), Pxr (Nrli2) and AhR/Arnt^140^. Results of the transcription factor upstream analysis are shown in Table L-5.

Chemical response pattern activation analysis in IPA is consistent with other results above. Chemicals known to activate Nrf2 (e.g., 1,2-dithiol-3-thione, tert-butyl-hydroquinone, oltipraz, and butylated hydroxyanisole)^141-144^, AhR/Arnt (e.g., tetrachlorodibenzodioxin, benzo(a)pyrene, 2,3,4,7,8-pentachlorodibenzofuran, and 3-methylcholanthrene)^128^ and Car/Pxr signaling (e.g., phenobarbital)^145^ exhibit similar patterns of gene expression compared to indole-3-carbinol. Results of the chemical response pattern activation analysis are shown in Table L-6.

## L.4 Conclusions

The results strongly suggest that treatment with indole-3-carbinol strongly activates AhR and Nrf2 (Nfe2l2) signaling, but also appears to activate Car (Nrli3)/Pxr (Nrli2) signaling. These finding are most clearly demonstrated in the transcription factor enrichment analysis where Nfe2l2 has the strongest activation signal followed by Car/Pxr and then AhR/Arnt. Nfe2l2 coordinates the cellular defense against the cytotoxic effects of oxidative stress^146^. The finding that Nfe2l2 is activated is supported by the activation of glutathione conjugation and enrichment of the oxidative stress signaling and glutathione-mediated detoxification. Additionally, the gene expression pattern elicited by indole-3-carbinol treatment parallels strongly the gene expression patterns of 1,2-dithiol-3-thione, a soft electrophile known to activate Nfe2l2 signaling through effects on the redox status of cellular sulfhydryl groups. Activation of AhR/Arnt along with Car/Pxr is supported by the activation/enrichment of a number of biological functions/pathways associated with xenobiotic and endogenous chemicals and enrichment, a result consistent with hepatocyte hypertrophy/liver enlargement. Patterns of gene expression produced by 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD), benzo(a)pyrene, and 3-methylcholanthrene (prototype AhR activators) that have been curated in IPA strongly parallel patterns of gene expression produced by indole-3-carbinol. The patterns of AhR gene expression are supported by the high level of induction of Cyp1a1 and Cyp1b1. The finding that AhR signaling is activated by indole-3-carbinol treatment is consistent with previous findings that acid condensates of indole-3-carbinol formed in the gut are high affinity ligands for the AhR^23^. From the standpoint of chemical signatures, Car/Pxr activation by indole-3-carbinol is supported by the positive correlation patterns of gene expression from phenobarbital curated in IPA and the strong induction of Cyp2b1/2b2 (a documented target of Car/Pxr) by indole-3-carbinol.

Other notable findings:

1. Down-regulation of Serpina7 (gene that encodes the major thyroid hormone transport protein, TBG, in serum) may have effects on systemic thyroid hormone signaling^147^.
2. Activation of Atf4 is likely related to endoplasmic reticulum stress that may be due to increased protein synthesis associated with xenobiotic metabolizing enzyme induction in combination with soft electrophile stress produced by indole-3-carbinol that can cause proteins to unfold^148^.
3. Activation of Tp63 along with enrichment of p53 signaling and Gadd45 signaling is potentially a secondary effect of the soft electrophile-induced oxidative stress and subsequent change in redox status^149^ that can be elicited by indole-3-carbinol^150^.

Table L-1 Top Five Up- and Down-regulated Genes in the Liver of Female Sprague Dawley Rats Administered Daily Doses of 300 mg/kg Indole-3-carbinol by Gavage for Three Months

Probeset ID | Gene Symbol | Entrez Gene | Fold Change Indole-3-carbinol Treated versus Vehicle Control
Up-regulated
1370269_at | Cyp1a1 | 24296 | 334.6
1368990_at | Cyp1b1 | 25426 | 75.1
1371076_at | Cyp2b1///Cyp2b2///LOC100362704 | 100362704///24300///361523 | 32.4
1374056_at | Rbm24 | 690139 | 29.6
1373188_at | Scn4b | 315611 | 17.1
Down-regulated
1369657_at | Cpa1 | 24269 | −4.3
1370387_at | Cyp3a9 | 171352 | −4.4
1371143_at | Serpina7 | 81806 | −4.9
1387053_at | Fmo1 | 25256 | −5.5
1367896_at | Car3 | 54232 | −16.0

Table L-2 Enriched Ingenuity Pathway Analysis^™^ Disease or Biological Functions that Exhibit Activation/inhibition in the Liver of Female Sprague Dawley Rats Administered Daily Doses of 300 mg/kg Indole-3-carbinol by Gavage for Three Months

Disease or Function Annotation | P Value | Predicted Activation State | Activation Z-score | Number of Molecules
Metabolism of terpenoid | 1.03E−08 | Increased | 2.726 | 19
Conjugation of glutathione | 1.08E−09 | Increased | 2.605 | 7
Steroidogenesis of hormone | 3.00E−03 | Increased | 2.425 | 6
Metabolism of hormone | 2.77E−03 | Increased | 2.404 | 8
Steroid metabolism | 3.98E−09 | Increased | 2.372 | 18
Joining of glutathione | 2.99E−11 | Increased | 2.320 | 8
Metabolism of retinoid | 4.32E−05 | Increased | 2.204 | 6
Hydroxylation of hormone | 1.42E−07 | Increased | 2.189 | 5
Binding of DNA | 1.27E−06 | Increased | 2.188 | 23
Oxidation of lipid | 2.14E−04 | Increased | 2.063 | 10
Synthesis of fatty acid | 2.04E−03 | Decreased | −2.138 | 11
Quantity of vitamin | 3.14E−06 | Decreased | −2.183 | 8
Quantity of GPT in blood | 4.54E−04 | Decreased | −2.200 | 5
Tumorigenesis of epithelial tumor | 2.93E−04 | Decreased | −2.348 | 11
Organismal death | 6.47E−04 | Decreased | −2.371 | 54
Quantity of enzyme | 1.41E−03 | Decreased | −2.420 | 6
Inflammation of organ | 4.83E−03 | Decreased | −2.679 | 28
Hyperplasia | 8.43E−03 | Decreased | −2.928 | 15

Table L-3 Enriched Ingenuity Pathway Analysis™ Toxicity Functions that Exhibit Activation/inhibition in the Liver of Female Sprague Dawley Rats Administered Daily Doses of 300 mg/kg Indole-3-carbinol by Gavage for Three Months

Disease or Function Annotation | P Value | Predicted Activation State | Activation Z-score | Number of Molecules
Conjugation of glutathione | 1.08E-09 | Increased | 2.605 | 7

Table L-4 Ingenuity Pathway Analysis™ Canonical Pathways Exhibiting Significant (P < 0.05) Enrichment in the Liver of Female Sprague Dawley Rats Administered Daily Doses of 300 mg/kg Indole-3-carbinol by Gavage for Three Months

Ingenuity Canonical Pathways | −log(P Value)
Xenobiotic metabolism signaling | 16.1
Nrf2-mediated oxidative stress response | 12.6
Aryl hydrocarbon receptor signaling | 12.3
Glutathione-mediated detoxification | 10.8
LPS/IL-1 mediated inhibition of RXR function | 10
Nicotine degradation II | 8.75
Nicotine degradation III | 8.15
Melatonin degradation I | 7.93
Superpathway of melatonin degradation | 7.58
Pxr/Rxr activation | 7.15
Bupropion degradation | 6.39
Acetone degradation I (to methylglyoxal) | 6.28
Estrogen biosynthesis | 5.36
Asparagine degradation I | 3.88
p53 signaling | 3.86
Glutathione redox reactions II | 3.41
Serine biosynthesis | 3.11
Gadd45 signaling | 2.83
Cell cycle: G2/M DNA damage checkpoint regulation | 2.79
Superpathway of serine and glycine biosynthesis I | 2.72
Atm signaling | 2.3
Serotonin degradation | 2.27
Hepatic cholestasis | 2.26
Thyroid hormone metabolism II (via conjugation and/or degradation) | 2.24
Antigen presentation pathway | 2.06
Vitamin-C transport | 1.96
Asparagine biosynthesis I | 1.94
4-Hydroxybenzoate biosynthesis | 1.94
4-Hydroxyphenylpyruvate biosynthesis | 1.94
Methylglyoxal degradation III | 1.9
Prostate cancer signaling | 1.81
Glutathione redox reactions I | 1.8
Fxr/Rxr activation | 1.76
Bladder cancer signaling | 1.71
Glutamine biosynthesis I | 1.64
Glutamine degradation I | 1.64
Ppar signaling | 1.63
Antioxidant action of vitamin C | 1.59
Protein ubiquitination pathway | 1.55
Phospholipases | 1.54
Coenzyme A biosynthesis | 1.47
Ascorbate recycling (cytosolic) | 1.47
Hypoxia signaling in the cardiovascular system | 1.39
Hereditary breast cancer signaling | 1.35
1,25-Dihydroxyvitamin D3 biosynthesis | 1.34

Table L-5 Enriched Ingenuity Pathway Analysis™ Transcription Factors that Exhibit Activation/inhibition in the Liver of Female Sprague Dawley Rats Administered Daily Doses of 300 mg/kg Indole-3-carbinol by Gavage for Three Months

Upstream Regulator | Fold Change^a^ | Molecule Type | Predicted Activation State | Activation Z-score | P Value of Overlap
Nfe212 | 2.075 | Transcription regulator | Activated | 4.399 | 2.31E−23
Nrli3 | 2.492 | Ligand-dependent nuclear receptor | Activated | 4.155 | 2.60E−20
Atf4 | 1.684 | Transcription regulator | Activated | 3.085 | 3.20E−07
Tp63 | – | Transcription regulator | Activated | 2.743 | 2.46E−04
Nr1i2 | – | Ligand-dependent nuclear receptor | Activated | 2.366 | 5.49E−16
Brca1 | – | Transcription regulator | Activated | 2.359 | 1.35E−07
Nupr1 | – | Transcription regulator | Activated | 2.309 | 5.10E−03
Xbp1 | – | Transcription regulator | Activated | 2.207 | 1.70E−02
Arnt | – | Transcription regulator | Activated | 2.165 | 8.36E−10
AhR | 2.026 | Ligand-dependent nuclear receptor | Activated | 2.062 | 1.43E−11
Trim24 | – | Transcription regulator | Activated | 2.000 | 1.75E−02

^a^ Indicates whether the gene encoding the transcription factor was differentially expressed by indole-3-carbinol. Blank cells indicate that the transcription factor was not differentially expressed.

Table L-6 Enriched Ingenuity Pathway Analysis™ Chemical Signaling Patterns that Exhibit Activation/inhibition in the Liver of Female Sprague Dawley Rats Administered Daily Doses of 300 mg/kg Indole-3-carbinol by Gavage for Three Months

Upstream Regulator | Molecule Type | Predicted Activation State | Activation Z-score | P Value of Overlap
1,2-Dithiol-3-thione | Chemical reagent | Activated | 4.182 | 1.12E−19
Tetrachlorodibenzodioxin | Chemical toxicant | Activated | 3.728 | 3.66E−14
Benzo(a)pyrene | Chemical toxicant | Activated | 3.722 | 5.51E−16
Phenobarbital | Chemical drug | Activated | 3.640 | 7.04E−18
3,4,5,3′,4′-Pentachlorobiphenyl | Chemical toxicant | Activated | 3.356 | 3.86E−15
2,3,4,7,8-Pentachlorodibenzofuran | Chemical toxicant | Activated | 3.080 | 4.15E−15
1,4-Bis[2-(3,5-dichloropyridyloxy)]benzene | Chemical toxicant | Activated | 3.064 | 2.41E−12
Pirinixic acid | Chemical toxicant | Activated | 3.056 | 5.26E−13
3-Methylcholanthrene | Chemical toxicant | Activated | 3.009 | 9.62E−16
Tert-butyl-hydroquinone | Chemical reagent | Activated | 2.908 | 3.16E−10
Tunicamycin | Chemical—endogenous non-mammalian | Activated | 2.782 | 1.35E−07
Thapsigargin | Chemical toxicant | Activated | 2.781 | 4.06E−06
Ethoxyquin | Chemical toxicant | Activated | 2.779 | 2.34E−12
Beta-naphthoflavone | Chemical toxicant | Activated | 2.749 | 8.28E−14
Troglitazone | Chemical drug | Activated | 2.734 | 5.67E−04
Bardoxolone | Chemical drug | Activated | 2.621 | 1.36E−08
Tosedostat | Chemical drug | Activated | 2.619 | 1.76E−08
Pxr ligand-Pxr-Retinoic Acid-Rxr α | Complex | Activated | 2.593 | 1.76E−07
Oltipraz | Chemical drug | Activated | 2.576 | 4.33E−09
Arsenic trioxide | Chemical drug | Activated | 2.504 | 9.92E−07
Diallyl disulfide | Chemical—endogenous non-mammalian | Activated | 2.425 | 3.15E−09
8-Bromo-camp | Chemical reagent | Activated | 2.407 | 7.91E−03
Allyl sulfide | Chemical drug | Activated | 2.388 | 7.79E−09
Cholic acid | Chemical—endogenous mammalian | Activated | 2.359 | 1.28E−04
Bilirubin | Chemical—endogenous mammalian | Activated | 2.236 | 8.16E−07
Sulforafan | Chemical drug | Activated | 2.212 | 2.12E−14
Pregnenolone carbonitrile | Chemical drug | Activated | 2.193 | 2.23E−06
Polycyclic aromatic hydrocarbons | Chemical toxicant | Activated | 2.188 | 7.93E−08
Benz[a]anthracene | Chemical toxicant | Activated | 2.156 | 6.31E−10
Cigarette smoke | Chemical toxicant | Activated | 2.154 | 7.73E−13
15-Deoxy-delta-12,14 -PGJ 2 | Chemical—endogenous non-mammalian | Activated | 2.136 | 5.22E−04
Butylated hydroxyanisole | Chemical toxicant | Activated | 2.050 | 1.96E−10
Cephaloridine | Chemical drug | Activated | 2.025 | 1.04E−07
Capsaicin | Chemical drug | Activated | 2.000 | 1.95E−03