# Appendix K Sentinel Animal Program

## K.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each animal and allowed to clot and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and evaluated for the presence of pathogens. Samples were sent to BioReliance Corporation (Rockville, MD) or the Research Animal Diagnostic Laboratory (RADIL) at the University of Missouri (Columbia, MO). The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Table K-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Three-month Study
ELISA
PVM (pneumonia virus of mice) | Study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study termination
Sendai | Study termination
Immunofluorescence Assay
Parvovirus | Study termination
Two-year Study
ELISA
PVM | End of quarantine, 4 weeks, 6 months
RCV/SDA | End of quarantine, 4 weeks, 6 months
Sendai | End of quarantine, 4 weeks, 6 months
Immunofluorescence Assay
Parvovirus | End of quarantine, 4 weeks, 6 months
RCV/SDA | 4 weeks, 6 months
Multiplex Fluorescent Immunoassay
H-1 (Toolan’s H-1 virus) | 12 and 18 months, study termination
KRV (Kilham rat Virus) | 12 and 18 months, study termination
Mycoplasma pulmonis | 12 and 18 months, study termination
Parvo NS-1 | 12 and 18 months, study termination
PVM | 12 and 18 months, study termination
RCV/SDA | 12 and 18 months, study termination
RMV (rat minute virus) | 12 and 18 months, study termination
RPV (rat parvovirus) | 12 and 18 months, study termination
RTV (rat theilovirus) | 12 and 18 months, study termination
Sendai | 12 and 18 months, study termination
TMEV GDVII (Theiler’s murine encephalomyelitis virus— mouse poliovirus, strain GDVII) | 12 and 18 months, study termination
Mice
Three-month Study
ELISA
Ectromelia virus | Study termination
EDIM (epizootic diarrhea of infant mice) | Study termination
LCM (lymphocytic choriomeningitis virus) | Study termination
Mouse adeno virus-1 (Mad-1) | Study termination
MHV (mouse hepatitis virus) | Study termination
MMV VP2 (mouse minute virus) | Study termination
MPV VP2 (mouse parvovirus) | Study termination
PVM | Study termination
Reovirus | Study termination
Sendai | Study termination
TMEV GDVII | Study termination
Immunofluorescence Assay
LCM | Study termination
Two-year Study
ELISA
Ectromelia virus | End of quarantine, 4 weeks, 6 months
EDIM | End of quarantine, 4 weeks, 6 months
LCM | End of quarantine, 4 weeks, 6 months
Mad-1 | End of quarantine, 4 weeks, 6 months
MHV | End of quarantine, 4 weeks, 6 months
MMV VP2 | End of quarantine, 4 weeks, 6 months
MPV VP2 | End of quarantine, 4 weeks, 6 months
PVM | End of quarantine, 4 weeks, 6 months
Reovirus | End of quarantine, 4 weeks, 6 months
Sendai | End of quarantine, 4 weeks, 6 months
TMEV GDVII | End of quarantine, 4 weeks, 6 months
Immunofluorescence Assay
MHV | 4 weeks
MPV | End of quarantine
LCM | 4 weeks
Multiplex Fluorescent Immunoassay
Ectromelia virus | 12 and 18 months, study termination
EDIM | 12 and 18 months, study termination
LCM | 12 and 18 months, study termination
MHV | 12 and 18 months, study termination
MMV | 12 and 18 months, study termination
MNV (mouse norovirus) | 12 and 18 months, study termination
MPV | 12 and 18 months, study termination
M. pulmonis | 12 and 18 months, study termination
Parvo NS-1 | 12 and 18 months, study termination
PVM | 12 and 18 months, study termination
Reovirus 3 | 12 and 18 months, study termination
Sendai | 12 and 18 months, study termination
TMEV GDVII | 12 and 18 months, study termination
Polymerase Chain Reaction
Helicobacter species | 18 months

## K.2 Results

All test results were negative.