# Appendix I Chemical Characterization and Dose Formulation Studies

## I.1 Procurement and Characterization

### I.1.1 Indole-3-carbinol

Indole-3-carbinol was obtained from ChemPacific Corporation (Baltimore, MD) in one lot (CHP801001) that was used during the 3-month and 2-year studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle Columbus Support Services (Columbus, OH) and the study laboratories, Southern Research Institute (SRI) (Birmingham, AL) for the 3-month studies and Battelle Columbus Operations (Columbus, OH) for the 2-year studies. Karl Fischer titration and elemental analyses were performed by Galbraith Laboratories, Inc. (Knoxville, TN). Reports on analyses performed in support of the indole-3-carbinol studies are on file at the National Institute of Environmental Health Sciences.

Lot CHP801001 of the test chemical, a yellow crystalline solid, was identified as indole-3-carbinol by the analytical chemistry laboratory using infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by the study laboratories using IR and proton NMR (SRI only) spectroscopy. All spectra were consistent with the literature spectra^137; 138^ and the structure of indole-3-carbinol. Representative IR and proton NMR spectra are presented in Figure I-1 and Figure I-2, respectively.

For lot CHP801001, Karl Fischer titration was used to determine the water content; elemental analyses were used to determine the carbon, hydrogen, and nitrogen content; and the melting point was determined using a differential scanning calorimeter. The purity was determined by the analytical chemistry laboratory using high-performance liquid chromatography (HPLC) with ultraviolet detection by systems A and B (Table I-1).

Karl Fischer titration indicated 1.3% water. Elemental analyses for carbon, hydrogen, and nitrogen were consistent with the theoretical values, and the melting point was 99.3°C, consistent with the manufacturer’s Certificate of Analysis. HPLC analysis indicated one major peak with six impurities, each 0.1% or greater of the total peak area with a combined area of 2.8% of total peak area in the chromatogram. The overall purity of lot CHP801001 was determined to be approximately 97%.

Stability studies of the bulk chemical were performed by the analytical chemistry laboratory using HPLC by system B. These studies indicated that indole-3-carbinol was stable as a bulk chemical for at least 2 weeks when stored in sealed amber glass vials protected from light at temperatures up to 25°C. However, at 60°C, physical changes were observed in the test chemical. To ensure stability, the bulk chemical was stored at −20°C, protected from light in amber glass containers sealed with Teflon^®^-lined lids. Periodic reanalyses of the bulk chemical were performed by the study laboratory twice during the 3-month studies and approximately every 6 months during the 2-year studies using HPLC by a system similar to system B; no degradation of the bulk chemical was detected.

### I.1.2 Corn Oil

Corn oil was used as the vehicle for the formulations and was obtained from Red Diamond, Inc. (Birmingham, AL), in one lot that was used in the 3-month studies and from Spectrum Chemicals and Laboratory Products (Gardena, CA) in seven lots and from Sigma-Aldrich (St. Louis, MO) in three lots that were used in the 2-year studies. Analysis of the corn oil for peroxides was performed by potentiometric titration, and each lot was within the acceptable range of less than or equal to 3 mEq/kg.

## I.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing the appropriate amount of milled indole-3-carbinol with corn oil to achieve the required concentrations (Table I-2). The dose formulations were prepared seven times during the 3-month studies and approximately every 4 weeks during the 2-year studies. Dose formulations were stored in amber glass vials sealed with Teflon^®^-lined lids at 5°C for up to 41 days.

Homogeneity, gavageability, and resuspendability studies were performed on 60 mg/mL dose formulations, and stability studies were performed on 1 mg/mL formulations by the analytical chemistry laboratory using HPLC by system B (Table I-1). To achieve acceptable chromatography, all samples containing corn oil were clarified by centrifuging 1-mL aliquots of each dose formulation for approximately 5 minutes at 14,000 rpm, then diluting (1:1) with the mobile phase prior to HPLC analysis. Homogeneity was confirmed, and gavageability was confirmed for a 20-gauge gavage needle. Resuspendability was confirmed for dose formulations that had been stored for 14 days at 5°C. Stability was confirmed for at least 8 days for 1 mg/mL formulations stored in amber glass vials sealed with Teflon^®^-lined lids at 5°C and for 3 hours under simulated animal room conditions. The study laboratory at SRI performed stability studies with 1.6 mg/mL dose formulations using HPLC by a system similar to system B, and stability was confirmed for at least 41 days for dose formulations stored in amber glass vials sealed with Teflon^®^-lined lids at 5°C. Prior to the 2-year studies, the study laboratory at Battelle Columbus Operations performed homogeneity studies on 6.25, 15, 25, and 60 mg/mL dose formulations and gavageability studies on 60 mg/mL dose formulations using HPLC by a system similar to system B; homogeneity and gavagability were confirmed.

Periodic analyses of the dose formulations of indole-3-carbinol were performed by the study laboratories using HPLC by systems similar to system B. During the 3-month studies, the dose formulations were analyzed three times; all 15 dose formulations for rats and all 15 for mice were within 10% of the target concentrations (Table I-3). Animal room samples of these dose formulations were also analyzed; all 15 for rats and all 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 2 months (Table I-4). Of the dose formulations analyzed, all 72 for rats and all 36 for mice were within 10% of the target concentrations; all 24 of the animal room samples for rats and all 12 for mice were within 10% of the target concentrations.

Table I-1 High-Performance Liquid Chromatography Systems Used in the Gavage Studies of Indole-3-carbinol^a^

Detection System | Column | Solvent System
System A
Photodiode array Ultraviolet (220 to 360 nm) light | Prodigy™ C18 ODS(3), 250 mm × 4.6 mm, 5 µm (Phenomenex, Torrance, CA) | 80:20 Methanol:1% aqueous acetic acid solution, isocratic; flow rate 0.8 mL/minute
System B
Ultraviolet (280 nm) light | Prodigy™ C18, 250 mm × 4.6 mm, 5 µm (Phenomenex) | 80:20 Methanol:1.5% aqueous acetic acid solution, isocratic; flow rate 0.8 mL/minute

^a^ The high-performance liquid chromatographs were manufactured by Waters, Inc. (Milford, MA) (System A), or Spectra Physics (San Jose, CA) (System B).

Table I-2 Preparation and Storage of Dose Formulations in the Gavage Studies of Indole-3--carbinol

Three-month Studies | Two-year Studies
Preparation
Prior to the preparation of dose formulations, portions of frozen indole-3-carbinol were milled for approximately 15 seconds in an IKA Works M20 Universal mill, then passed through a 40-mesh sieve, and placed in high density polyethylene wide-mouth containers, sealed with Teflon^®^-lined lids, rolled and shaken for approximately 15 minutes. To prepare the dose formulations, containers of milled indole-3-carbinol were allowed to warm to room temperature. For each dose formulation, the appropriate amount of milled indole-3-carbinol was weighed into a weigh boat or beaker and transferred to a mortar; corn oil was added in increments and the mixture was ground with a pestle into a paste-like mixture, transferred to an Erlenmeyer flask with corn oil rinses, diluted to final volume and sonicated for approximately 10 minutes, and cooled by an ice water bath. A stir bar was added and the mixture was stirred for at least 2 hours to ensure homogeneity. Formulations were prepared seven times during the 3-month studies. | Same as 3-month studies except that dose formulations were prepared approximately every 4 weeks.
Chemical Lot Number
CHP801001 | CHP801001
Maximum Storage Time
41 days | 41 days
Storage Conditions
The dose formulations were stored in amber glass vials sealed with Teflon^®^-lined lids at 5°C. | The dose formulations were stored in amber glass vials sealed with Teflon^®^-lined lids at 5°C.
Study Laboratory
Southern Research Institute (Birmingham, AL) | Battelle Columbus Operations (Columbus, OH)

Table I-3 Results of Analyses of Dose Formulations Administered to F344/N Rats and Mice in the Three-month Gavage Studies of Indole-3-carbinol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
August 23, 2004 | August 24–25, 2004 | 3.75 | 3.52 ± 0.061 | −6
| | 7.50 | 7.25 ± 0.33 | −3
| | 15 | 13.6 ± 0.14 | −9
| | 30 | 29.1 ± 0.10 | −3
| | 60 | 63.0 ± 0.41 | +5
| September 13–14, 2004^b^ | 3.75 | 3.60 ± 0.090 | −4
| | 7.50 | 7.33 ± 0.019 | −2
| | 15 | 14.9 ± 0.0085 | −1
| | 30 | 30.0 ± 0.37 | 0
| | 60 | 60.8 ± 0.38 | +1
October 5, 2004 | October 6–7, 2004 | 3.75 | 3.68 ± 0.089 | −2
| | 7.50 | 7.30 ± 0.20 | −3
| | 15 | 15.0 ± 0.024 | 0
| | 30 | 29.8 ± 0.19 | −1
| | 60 | 59.2 ± 0.25 | −1
| October 26–27, 2004^b^ | 3.75 | 3.60 ± 0.060 | −4
| | 7.50 | 7.22 ± 0.39 | −4
| | 15 | 15.0 ± 0.62 | 0
| | 30 | 29.4 ± 0.25 | −2
| | 60 | 56.0 ± 0.27 | −7
November 15, 2004 | November 16–17, 2004 | 3.75 | 3.54 ± 0.074 | −6
| | 7.50 | 7.03 ± 0.068 | −6
| | 15 | 14.7 ± 0.42 | −2
| | 30 | 29.6 ± 0.34 | −1
| | 60 | 56.8 ± 0.83 | −5
| December 8–9, 2004^b^ | 3.75 | 3.44 ± 0.025 | −8
| | 7.50 | 6.91 ± 0.038 | −8
| | 15 | 14.4 ± 0.30 | −4
| | 30 | 29.9 ± 0.047 | 0
| | 60 | 58.7 ± 3.2 | −2
Mice
August 23, 2004 | August 24–25, 2004 | 1.56 | 1.52 ± 0.0080 | −3
| | 3.13 | 3.03 ± 0.082 | −3
| | 6.25 | 6.21 ± 0.081 | −1
| | 12.5 | 12.1 ± 0.021 | −3
| | 25 | 23.7 ± 0.46 | −5
| September 13–14, 2004^b^ | 1.56 | 1.55 ± 0.00026 | −1
| | 3.13 | 2.83 ± 0.039 | −10
| | 6.25 | 5.86 ± 0.12 | −6
| | 12.5 | 11.5 ± 0.032 | −8
| | 25 | 24.2 ± 0.13 | −3
October 5, 2004 | October 6–7, 2004 | 1.56 | 1.55 ± 0.0013 | −1
| | 3.13 | 2.86 ± 0.033 | −9
| | 6.25 | 5.89 ± 0.022 | −6
| | 12.5 | 11.9 ± 0.0074 | −5
| | 25 | 25.1 ± 0.12 | 0
| October 26–27, 2004^b^ | 1.56 | 1.52 ± 0.0059 | −3
| | 3.13 | 2.84 ± 0.019 | −9
| | 6.25 | 5.92 ± 0.092 | −5
| | 12.5 | 11.8 ± 0.63 | −6
| | 25 | 25.2 ± 0.090 | +1
November 15, 2004 | November 16–17, 2004 | 1.56 | 1.57 ± 0.031 | +1
| | 3.13 | 2.97 ± 0.0038 | −5
| | 6.25 | 6.26 ± 0.017 | 0
| | 12.5 | 12.4 ± 0.080 | −1
| | 25 | 25.1 ± 0.98 | 0
| December 8–9, 2004^b^ | 1.56 | 1.58 ± 0.012 | +1
| | 3.13 | 3.00 ± 0.051 | −4
| | 6.25 | 6.25 ± 0.080 | 0
| | 12.5 | 12.1 ± 0.083 | −3
| | 25 | 25.2 ± 0.20 | +1

^a^ Results of duplicate analyses. For rats, dosing volume = 5 mL/kg; 3.75 mg/mL = 18.75 mg/kg, 7.50 mg/mL = 37.5 mg/kg, 15 mg/mL = 75 mg/kg, 30 mg/mL = 150 mg/kg, 60 mg/mL = 300 mg/kg. For mice, dosing volume = 10 mL/kg; 1.56 mg/mL = 15.6 mg/kg, 3.13 mg/mL = 31.25 mg/kg, 6.25 mg/mL = 62.5 mg/kg, 12.5 mg/mL = 125 mg/kg, 25 mg/mL = 250 mg/kg.

^b^ Animal room samples.

Table I-4 Results of Analyses of Dose Formulations Administered to Sprague Dawley Rats and Mice in the Two-year Gavage Studies of Indole-3-carbinol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
March 5, 2007 | March 8, 2007 | 15 | 15.1 ± 0.2 | +1
| | 15 | 15.0 ± 0.0 | 0
| | 30 | 30.2 ± 0.2 | +1
| | 30 | 30.6 ± 0.2 | +2
| | 60 | 61.9 ± 0.3 | +3
| | 60 | 61.6 ± 0.1 | +3
| April 12, 2007^b^ | 15 | 15.5 ± 0.1 | +3
| | 15 | 15.4 ± 0.2 | +3
| | 30 | 30.6 ± 0.1 | +2
| | 30 | 30.5 ± 0.1 | +2
| | 60 | 62.0 ± 0.1 | +3
| | 60 | 60.7 ± 0.2 | +1
May 2, 2007 | May 2, 2007 | 15 | 15.5 ± 0.1 | +3
| | 15 | 15.4 ± 0.1 | +3
| | 30 | 31.3 ± 0.1 | +4
| | 30 | 31.4 ± 0.3 | +5
| | 60 | 64.3 ± 0.2 | +7
| | 60 | 63.1 ± 0.1 | +5
July 23, 2007 | July 24, 2007 | 15 | 15.8 ± 0.1 | +5
| | 15 | 15.8 ± 0.1 | +5
| | 30 | 31.3 ± 0.2 | +4
| | 30 | 31.8 ± 0.1 | +6
| | 60 | 63.4 ± 0.4 | +6
| | 60 | 63.6 ± 0.1 | +6
September 17, 2007 | September 19, 2007 | 15 | 15.5 ± 0.1 | +3
| | 15 | 15.5 ± 0.2 | +3
| | 30 | 31.3 ± 0.1 | +4
| | 30 | 30.9 ± 0.2 | +3
| | 60 | 63.5 ± 0.2 | +6
| | 60 | 63.4 ± 0.4 | +6
| October 25, 2007^b^ | 15 | 15.4 ± 0.1 | +3
| | 15 | 15.6 ± 0.1 | +4
| | 30 | 29.9 ± 0.3 | 0
| | 30 | 31.2 ± 0.4 | +4
| | 60 | 63.5 ± 0.1 | +6
| | 60 | 62.2 ± 0.7 | +4
November 12, 2007 | November 14, 2007 | 15 | 15.4^c^ | +3
| | 15 | 15.6 ± 0.2 | +4
| | 30 | 30.9 ± 0.2 | +3
| | 30 | 30.9 ± 0.2 | +3
| | 60 | 62.9 ± 0.5 | +5
| | 60 | 62.3 ± 0.4 | +4
January 8, 2008 | January 9, 2008 | 15 | 15.4 ± 0.1 | +3
| | 15 | 15.5 ± 0.0 | +3
| | 30 | 31.1 ± 0.1 | +4
| | 30 | 31.1 ± 0.2 | +4
| | 60 | 62.9 ± 0.1 | +5
| | 60 | 63.2 ± 0.4 | +5
March 31, 2008 | April 2, 2008 | 15 | 15.5 ± 0.1 | +3
| | 15 | 15.5 ± 0.3 | +3
| | 30 | 31.7 ± 0.4 | +6
| | 30 | 31.2 ± 0.2 | +4
| | 60 | 63.0 ± 0.2 | +5
| | 60 | 63.2 ± 0.5 | +5
| May 13, 2008^b^ | 15 | 14.5 ± 0.6 | −3
| | 15 | 15.2 ± 0.1 | +1
| | 30 | 30.1 ± 0.4 | 0
| | 30 | 30.8 ± 0.6 | +3
| | 60 | 62.8 ± 1.3 | +5
| | 60 | 62.1 ± 0.3 | +4
June 23, 2008 | June 24, 2008 | 15 | 15.3 ± 0.1 | +2
| | 15 | 15.6 ± 0.0 | +4
| | 30 | 31.1 ± 0.2 | +4
| | 30 | 30.7 ± 0.2 | +2
| | 60 | 60.5 ± 0.1 | +1
| | 60 | 62.1 ± 0.0 | +4
August 15, 2008 | August 20, 2008 | 15 | 15.2 ± 0.1 | +1
| | 15 | 15.5 ± 0.1 | +3
| | 30 | 30.8 ± 0.3 | +3
| | 30 | 30.7 ± 0.0 | +2
| | 60 | 62.6 ± 0.3 | +4
| | 60 | 61.3 ± 0.6 | +2
October 13, 2008 | October 14, 2008 | 15 | 15.3 ± 0.1 | +2
| | 15 | 15.7 ± 0.1 | +5
| | 30 | 31.2 ± 0.3 | +4
| | 30 | 31.1 ± 0.1 | +4
| | 60 | 61.4 ± 0.1 | +2
| | 60 | 63.0 ± 0.3 | +5
| November 26, 2008^b^ | 15 | 15.2 ± 0.1 | +1
| | 15 | 15.7 ± 0.2 | +5
| | 30 | 31.8 ± 0.7 | +6
| | 30 | 31.0 ± 0.3 | +3
| | 60 | 63.7 ± 1.2 | +6
| | 60 | 62.4 ± 0.7 | +4
December 8, 2008 | December 9, 2008 | 15 | 15.1 ± 0.6 | +1
| | 15 | 15.1 ± 0.5 | +1
| | 30 | 30.1 ± 2.1 | 0
| | 30 | 30.6 ± 0.6 | +2
| | 60 | 60.7 ± 1.5 | +1
| | 60 | 61.6 ± 1.3 | +3
February 2, 2009 | February 5, 2009 | 15 | 15.2 ± 0.1 | +1
| | 15 | 15.4 ± 0.1 | +3
| | 30 | 30.9 ± 0.2 | +3
| | 30 | 30.6 ± 0.3 | +2
| | 60 | 62.5 ± 0.4 | +4
| | 60 | 61.6 ± 0.3 | +3
Mice
March 5, 2007 | March 8, 2007 | 6.25 | 6.24 ± 0.51 | 0
| | 12.5 | 12.7 ± 0.1 | +2
| | 25 | 25.1 ± 0.2 | 0
| April 12, 2007^b^ | 6.25 | 6.64 ± 0.09 | +6
| | 12.5 | 13.0 ± 0.0 | +4
| | 25 | 25.7 ± 2.9 | +3
May 2, 2007 | May 2, 2007 | 6.25 | 6.50 ± 0.06 | +4
| | 12.5 | 12.9 ± 0.1 | +3
| | 25 | 25.7 ± 0.3 | +3
July 23, 2007 | July 24, 2007 | 6.25 | 6.27 ± 0.01 | 0
| | 12.5 | 13.0 ± 0.1 | +4
| | 25 | 26.2 ± 0.2 | +5
September 17, 2007 | September 19, 2007 | 6.25 | 6.40 ± 0.02 | +2
| | 12.5 | 12.7 ± 0.1 | +2
| | 25 | 25.8 ± 0.1 | +3
| October 25, 2007^b^ | 6.25 | 6.43 ± 0.01 | +3
| | 12.5 | 12.3 ± 0.1 | −2
| | 25 | 25.2 ± 1.3 | +1
November 12, 2007 | November 14, 2007 | 6.25 | 6.30 ± 0.03 | +1
| | 12.5 | 12.6 ± 0.0 | +1
| | 25 | 25.8 ± 0.2 | +3
January 8, 2008 | January 9, 2008 | 6.25 | 6.46 ± 0.01 | +3
| | 12.5 | 12.6 ± 0.2 | +1
| | 25 | 25.7 ± 0.1 | +3
March 31, 2008 | April 2, 2008 | 6.25 | 6.36 ± 0.10 | +2
| | 12.5 | 12.6 ± 0.1 | +1
| | 25 | 26.1 ± 0.2 | +4
| May 13, 2008^b^ | 6.25 | 6.55 ± 0.04 | +5
| | 12.5 | 13.0 ± 0.1 | +4
| | 25 | 25.7 ± 0.0 | +3
June 23, 2008 | June 24, 2008 | 6.25 | 6.50 ± 0.03 | +4
| | 12.5 | 12.8 ± 0.0 | +2
| | 25 | 26.1 ± 0.1 | +4
August 15, 2008 | August 20, 2008 | 6.25 | 6.57 ± 0.01 | +5
| | 12.5 | 12.7 ± 0.0 | +2
| | 25 | 26.2 ± 0.1 | +5
October 13, 2008 | October 14, 2008 | 6.25 | 6.61 ± 0.05 | +6
| | 12.5 | 13.1 ± 0.1 | +5
| | 25 | 26.2 ± 0.2 | +5
| November 26, 2008^b^ | 6.25 | 6.45 ± 0.07 | +3
| | 12.5 | 12.5 ± 0.2 | 0
| | 25 | 26.3 ± 0.2 | +5
December 8, 2008 | December 9, 2008 | 6.25 | 6.20 ± 0.15 | −1
| | 12.5 | 12.1 ± 0.2 | −3
| | 25 | 26.1 ± 0.5 | +4
February 2, 2009 | February 5, 2009 | 6.25 | 6.27 ± 0.03 | 0
| | 12.5 | 12.9 ± 0.1 | +3
| | 25 | 25.9 ± 0.2 | +4

^a^ Results of duplicate analyses. For rats, dosing volume = 5 mL/kg; 15 mg/mL = 75 mg/kg, 30 mg/mL = 150 mg/kg, 60 mg/mL = 300 mg/kg. For mice, dosing volume = 10 mL/kg; 6.25 mg/mL = 62.5 mg/kg, 12.5 mg/mL = 125 mg/kg, 25 mg/mL = 250 mg/kg.

^b^ Animal room samples.

^c^ One value only.

Figure I-1

Infrared Absorption Spectrum of Indole-3-carbinol

Figure I-2

Proton Nuclear Magnetic Resonance Spectrum of Indole-3-carbinol