# Appendix H Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table H-1 Summary of Reproductive Tissue Evaluations for Male F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 309 ± 5 | 321 ± 8 | 309 ± 8 | 285 ± 6*
L. Cauda epididymis | 0.1657 ± 0.0055 | 0.1687 ± 0.0083 | 0.1588 ± 0.0067 | 0.1591 ± 0.0099
L. Epididymis | 0.4403 ± 0.0125 | 0.4414 ± 0.0145 | 0.4249 ± 0.0101 | 0.4074 ± 0.0148
L. Testis | 1.3959 ± 0.0246 | 1.4735 ± 0.0264 | 1.4580 ± 0.0235 | 1.4157 ± 0.0308
Spermatid measurements
Spermatid heads (10^6^/testis) | 160.4 ± 6.7 | 168.4 ± 7.8 | 149.3 ± 6.4 | 170.9 ± 12.6
Spermatid heads (10^6^/g testis) | 153.4 ± 6.0 | 160.6 ± 9.4 | 143.4 ± 5.4 | 164.1 ± 9.5
Epididymal spermatozoal measurements
Sperm motility (%) | 84.60 ± 1.62 | 83.66 ± 1.85 | 82.23 ± 1.66 | 82.52 ± 1.78
Sperm (10^6^/cauda epididymis) | 94.03 ± 2.43 | 83.90 ± 2.90 | 89.39 ± 4.30 | 92.04 ± 4.57
Sperm (10^6^/g cauda epididymis) | 571.6 ± 19.0 | 505.7 ± 26.3 | 571.8 ± 35.7 | 590.9 ± 31.4

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table H-2 Estrous Cycle Characterization for Female F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 189 ± 2 | 185 ± 3 | 183 ± 3 | 183 ± 3
Proportion of regular cycling females^b^ | 7/7 | 8/8 | 9/10 | 8/9
Estrous cycle length (days) | 5.00 ± 0.11^c^ | 5.13 ± 0.13^d^ | 5.25 ± 0.13 | 5.89 ± 0.31*^e^
Estrous stages^f^ (% of cycle)
Diestrus | 45.8 | 50.0 | 52.5 | 60.0
Proestrus | 15.0 | 13.3 | 16.7 | 9.2
Estrus | 20.8 | 19.2 | 19.2 | 20.0
Metestrus | 6.7 | 6.7 | 11.7 | 10.8
Uncertain diagnoses | 11.7 | 10.8 | 0.0 | 0.0

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated a significantly higher probability of extended diestrus in the 300 mg/kg group compared to the vehicle control group.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in three of 10 animals.

^d^ Estrous cycle was longer than 12 days or unclear in two of 10 animals.

^e^ Estrous cycle was longer than 12 days or unclear in one of 10 animals.

^f^ Evidence shows that 150 and 300 mg/kg females differ significantly (Wilkes’ Criterion, P ≤ 0.05) from the vehicle control females in the relative length of time spent in the estrous stages.

Table H-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female F344/N Rats Administered Indole-3-carbinol by Gavage for Three Months

Stage | Comparison^a^ | P Value | Trend^b^
Overall Tests | Overall | <0.001
Overall Tests | Low vs. Controls | 0.983 | –
Overall Tests | Mid vs. Controls | 0.89 | N
Overall Tests | High vs. Controls | <0.001 | –
Extended Estrus | Overall | 0.519
Extended Estrus | Low vs. Controls | 0.572 | –
Extended Estrus | Mid vs. Controls | 0.543 | N
Extended Estrus | High vs. Controls | 0.239 | –
Extended Diestrus | Overall | 0.001
Extended Diestrus | Low vs. Controls | 0.967 | N
Extended Diestrus | Mid vs. Controls | 0.861 | N
Extended Diestrus | High vs. Controls | <0.001 | –
Extended Metestrus | Overall | 1
Extended Metestrus | Low vs. Controls | 1 | –
Extended Metestrus | Mid vs. Controls | 1 | –
Extended Metestrus | High vs. Controls | 1 | –
Extended Proestrus | Overall | 0.985
Extended Proestrus | Low vs. Controls | 1 | –
Extended Proestrus | Mid vs. Controls | 0.604 | –
Extended Proestrus | High vs. Controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | Low vs. Controls | 1 | –
Skipped Estrus | Mid vs. Controls | 0.924 | –
Skipped Estrus | High vs. Controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | Low vs. Controls | 1 | –
Skipped Diestrus | Mid vs. Controls | 1 | –
Skipped Diestrus | High vs. Controls | 1 | –
Summary of Significant Groups
Overall Tests | High vs. Controls | <0.001 | –
Extended Diestrus | High vs. Controls | <0.001 | –

^a^ Controls = Vehicle Control, Low = 75 mg/kg, Mid = 150 mg/kg, High = 300 mg/kg.

^b^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Table H-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
n | 10 | 10 | 10 | 9
Weights (g)
Necropsy body wt | 40.4 ± 0.6 | 40.0 ± 1.1 | 42.2 ± 1.6 | 40.8 ± 1.0
L. Cauda epididymis | 0.0245 ± 0.0010 | 0.0255 ± 0.0013 | 0.0231 ± 0.0013 | 0.0232 ± 0.0010
L. Epididymis | 0.0583 ± 0.0019 | 0.0589 ± 0.0014 | 0.0555 ± 0.0030 | 0.0530 ± 0.0020
L. Testis | 0.1274 ± 0.0023 | 0.1244 ± 0.0026 | 0.1254 ± 0.0014 | 0.1202 ± 0.0028
Spermatid measurements
Spermatid heads (10^6^/testis) | 20.99 ± 1.28 | 22.56 ± 1.11 | 22.63 ± 1.60 | 24.81 ± 0.47
Spermatid heads (10^6^/g testis) | 378.9 ± 52.3 | 417.9 ± 28.0 | 478.1 ± 47.0 | 507.8 ± 76.5
Epididymal spermatozoal measurements
Sperm motility (%) | 83.71 ± 0.50 | 79.68 ± 1.09** | 79.12 ± 0.96** | 74.26 ± 0.80**
Sperm (10^6^/cauda epididymis) | 18.04 ± 0.58 | 18.97 ± 1.04 | 18.52 ± 0.90 | 18.73 ± 2.35
Sperm (10^6^/g cauda epididymis) | 742.9 ± 28.9 | 747.1 ± 30.7 | 820.0 ± 54.9 | 800.5 ± 94.9

** Significantly different (P ≤ 0.01) from the vehicle control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid measurements, sperm per cauda epididymis, and sperm per gram cauda epididymis).

Table H-5 Estrous Cycle Characterization for Female Mice in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 34.2 ± 1.0 | 33.7 ± 0.6 | 33.1 ± 0.7 | 31.4 ± 1.3
Proportion of regular cycling females^b^ | 8/10 | 8/10 | 7/10 | 5/9
Estrous cycle length (days) | 4.06 ± 0.13 | 4.65 ± 0.51 | 4.29 ± 0.17 | 4.17 ± 0.33^c^
Estrous stages (% of cycle)
Diestrus | 31.7 | 40.8 | 30.0 | 40.0
Proestrus | 0.0 | 1.7 | 1.7 | 3.3
Estrus | 46.7 | 38.3 | 46.7 | 37.5
Metestrus | 21.7 | 19.2 | 21.7 | 19.2

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated a significantly higher probability of extended diestrus in the 250 mg/kg group compared to the vehicle control group.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ One of 10 animals was excluded from mean due to cycle length longer than 9 days.

Table H-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice Administered Indole-3-carbinol by Gavage for Three Months

Stage | Comparison^a^ | P Value | Trend^b^
Overall Tests | Overall | 0.024
Overall Tests | Low vs. Controls | 0.437 | –
Overall Tests | Mid vs. Controls | 0.426 | –
Overall Tests | High vs. Controls | 0.004 | –
Extended Estrus | Overall | 0.793
Extended Estrus | Low vs. Controls | 0.77 | N
Extended Estrus | Mid vs. Controls | 0.351 | –
Extended Estrus | High vs. Controls | 0.775 | –
Extended Diestrus | Overall | 0.052
Extended Diestrus | Low vs. Controls | 0.065 | –
Extended Diestrus | Mid vs. Controls | 0.946 | N
Extended Diestrus | High vs. Controls | 0.031 | –
Extended Metestrus | Overall | 1
Extended Metestrus | Low vs. Controls | 1 | –
Extended Metestrus | Mid vs. Controls | 1 | –
Extended Metestrus | High vs. Controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | Low vs. Controls | 1 | –
Extended Proestrus | Mid vs. Controls | 1 | –
Extended Proestrus | High vs. Controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | Low vs. Controls | 1 | –
Skipped Estrus | Mid vs. Controls | 1 | –
Skipped Estrus | High vs. Controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | Low vs. Controls | 1 | –
Skipped Diestrus | Mid vs. Controls | 1 | –
Skipped Diestrus | High vs. Controls | 1 | –
Summary of Significant Groups
Overall Tests | High vs. Controls | 0.004 | –
Extended Diestrus | High vs. Controls | 0.031 | –

^a^ Controls = Vehicle Control, Low = 62.5 mg/kg, Mid = 125 mg/kg, High = 250 mg/kg.

^b^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Figure H-1

Vaginal Cytology Plots for Female F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol

IC = Insufficient number of cells to determine stage; D = diestrus, P = proestrus, E = estrus, M = metestrus

Figure H-2

Vaginal Cytology Plots for Female Mice in the Three-month Gavage Study of Indole-3-carbinol

D = diestrus, P = proestrus, E = estrus, M = metestrus