# Appendix G Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 18.75 mg/kg | 37.5 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 309 ± 5 | 320 ± 9 | 325 ± 7 | 321 ± 8 | 309 ± 8 | 285 ± 6
Heart
Absolute | 0.77 ± 0.02 | 0.82 ± 0.02 | 0.83 ± 0.02 | 0.82 ± 0.01 | 0.78 ± 0.02 | 0.75 ± 0.02
Relative | 2.483 ± 0.034 | 2.577 ± 0.035 | 2.561 ± 0.030 | 2.562 ± 0.023 | 2.528 ± 0.032 | 2.618 ± 0.038*
R. Kidney
Absolute | 0.86 ± 0.02 | 0.94 ± 0.02 | 0.93 ± 0.03 | 0.97 ± 0.03* | 0.92 ± 0.03 | 0.90 ± 0.02
Relative | 2.785 ± 0.038 | 2.940 ± 0.033 | 2.844 ± 0.054 | 3.012 ± 0.038** | 2.981 ± 0.048** | 3.152 ± 0.055**
Liver
Absolute | 9.98 ± 0.30 | 11.19 ± 0.40* | 11.20 ± 0.40* | 11.85 ± 0.36** | 12.07 ± 0.38** | 12.57 ± 0.33**
Relative | 32.205 ± 0.594 | 34.924 ± 0.481** | 34.382 ± 0.716** | 36.941 ± 0.435** | 39.050 ± 0.472** | 44.047 ± 0.729**
Lung
Absolute | 1.31 ± 0.06 | 1.43 ± 0.03 | 1.43 ± 0.06 | 1.36 ± 0.04 | 1.45 ± 0.08 | 1.28 ± 0.04
Relative | 4.229 ± 0.164 | 4.474 ± 0.113 | 4.399 ± 0.196 | 4.240 ± 0.075 | 4.676 ± 0.226 | 4.486 ± 0.131
R. Testis
Absolute | 1.299 ± 0.020 | 1.311 ± 0.020 | 1.449 ± 0.075* | 1.334 ± 0.025 | 1.355 ± 0.028 | 1.292 ± 0.029
Relative | 4.201 ± 0.055 | 4.113 ± 0.059 | 4.477 ± 0.265 | 4.178 ± 0.099 | 4.396 ± 0.064 | 4.531 ± 0.080
Thymus
Absolute | 0.185 ± 0.008 | 0.187 ± 0.008 | 0.207 ± 0.007 | 0.191 ± 0.006 | 0.182 ± 0.006 | 0.170 ± 0.007
Relative | 0.597 ± 0.021 | 0.590 ± 0.030 | 0.635 ± 0.019 | 0.597 ± 0.019 | 0.591 ± 0.019 | 0.596 ± 0.027
Female
Necropsy body wt | 189 ± 2 | 192 ± 3 | 195 ± 2 | 185 ± 3 | 183 ± 3 | 183 ± 3
Heart
Absolute | 0.53 ± 0.01 | 0.56 ± 0.01 | 0.54 ± 0.00 | 0.53 ± 0.01 | 0.54 ± 0.01 | 0.53 ± 0.01
Relative | 2.784 ± 0.036 | 2.911 ± 0.036 | 2.782 ± 0.030 | 2.844 ± 0.050 | 2.926 ± 0.045* | 2.913 ± 0.026
R. Kidney
Absolute | 0.57 ± 0.01 | 0.66 ± 0.01** | 0.63 ± 0.01* | 0.61 ± 0.01 | 0.62 ± 0.01 | 0.63 ± 0.02*
Relative | 3.034 ± 0.056 | 3.447 ± 0.053** | 3.233 ± 0.075** | 3.277 ± 0.046** | 3.375 ± 0.064** | 3.436 ± 0.063**
Liver
Absolute | 5.08 ± 0.11 | 5.94 ± 0.11** | 5.98 ± 0.07** | 5.92 ± 0.13** | 6.34 ± 0.14** | 6.92 ± 0.11**
Relative | 26.804 ± 0.441 | 30.985 ± 0.566** | 30.790 ± 0.547** | 32.061 ± 0.548** | 34.660 ± 0.614** | 37.857 ± 0.319**
Lung
Absolute | 0.92 ± 0.03 | 0.99 ± 0.03 | 0.93 ± 0.02 | 0.92 ± 0.03 | 0.94 ± 0.03 | 0.98 ± 0.02
Relative | 4.874 ± 0.151 | 5.144 ± 0.149 | 4.781 ± 0.139 | 4.982 ± 0.182 | 5.121 ± 0.170 | 5.386 ± 0.176
Thymus
Absolute | 0.178 ± 0.005 | 0.173 ± 0.005 | 0.162 ± 0.007 | 0.149 ± 0.008** | 0.151 ± 0.007** | 0.145 ± 0.006**
Relative | 0.943 ± 0.027 | 0.901 ± 0.022 | 0.836 ± 0.042* | 0.805 ± 0.036** | 0.825 ± 0.029** | 0.792 ± 0.031**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 15.6 mg/kg | 31.25 mg/kg | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 40.4 ± 0.6 | 40.5 ± 1.1 | 41.5 ± 0.9 | 40.0 ± 1.1 | 42.2 ± 1.6 | 41.0 ± 0.9
Heart
Absolute | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.15 ± 0.00 | 0.14 ± 0.00
Relative | 3.496 ± 0.073 | 3.418 ± 0.066 | 3.453 ± 0.100 | 3.413 ± 0.085 | 3.476 ± 0.135 | 3.330 ± 0.088
R. Kidney
Absolute | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.28 ± 0.01
Relative | 7.009 ± 0.152 | 6.908 ± 0.212 | 7.063 ± 0.204 | 7.137 ± 0.195 | 6.928 ± 0.321 | 6.891 ± 0.166
Liver
Absolute | 1.50 ± 0.06 | 1.46 ± 0.07 | 1.54 ± 0.05 | 1.54 ± 0.05 | 1.77 ± 0.13* | 1.82 ± 0.06**
Relative | 37.329 ± 1.896 | 35.868 ± 0.799 | 37.166 ± 0.702 | 38.520 ± 0.632 | 41.960 ± 2.146* | 44.333 ± 0.817**
Lung
Absolute | 0.24 ± 0.02 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.24 ± 0.01 | 0.23 ± 0.02
Relative | 5.916 ± 0.421 | 5.532 ± 0.321 | 5.411 ± 0.341 | 5.406 ± 0.307 | 5.751 ± 0.384 | 5.665 ± 0.348
R. Testis
Absolute | 0.120 ± 0.002 | 0.121 ± 0.004 | 0.117 ± 0.003^b^ | 0.116 ± 0.003 | 0.118 ± 0.002 | 0.109 ± 0.006
Relative | 2.985 ± 0.068 | 3.008 ± 0.122 | 2.828 ± 0.077^b^ | 2.920 ± 0.121 | 2.830 ± 0.135 | 2.656 ± 0.143
Thymus
Absolute | 0.032 ± 0.002 | 0.029 ± 0.002 | 0.031 ± 0.001 | 0.031 ± 0.003 | 0.031 ± 0.004 | 0.035 ± 0.002
Relative | 0.779 ± 0.047 | 0.728 ± 0.049 | 0.738 ± 0.038 | 0.784 ± 0.066 | 0.743 ± 0.094 | 0.846 ± 0.048
Female
Necropsy body wt | 34.2 ± 1.0 | 33.5 ± 1.0 | 33.8 ± 1.6 | 33.7 ± 0.6 | 33.1 ± 0.7 | 31.4 ± 1.3
Heart
Absolute | 0.12 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.00
Relative | 3.505 ± 0.117 | 3.860 ± 0.158 | 3.606 ± 0.153 | 3.577 ± 0.104 | 3.578 ± 0.061 | 3.699 ± 0.130
R. Kidney
Absolute | 0.17 ± 0.00 | 0.18 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.01 | 0.17 ± 0.00 | 0.17 ± 0.01
Relative | 4.995 ± 0.117 | 5.303 ± 0.119 | 5.069 ± 0.187 | 5.094 ± 0.172 | 5.128 ± 0.135 | 5.351 ± 0.178
Liver
Absolute | 1.04 ± 0.01 | 1.21 ± 0.05* | 1.11 ± 0.04* | 1.16 ± 0.03* | 1.22 ± 0.03** | 1.21 ± 0.04**
Relative | 30.559 ± 0.696 | 36.190 ± 1.253** | 32.906 ± 0.651** | 34.449 ± 0.693** | 36.878 ± 0.867** | 38.687 ± 0.778**
Lung
Absolute | 0.23 ± 0.01 | 0.22 ± 0.01 | 0.20 ± 0.01* | 0.21 ± 0.01 | 0.23 ± 0.01 | 0.23 ± 0.01
Relative | 6.764 ± 0.244 | 6.673 ± 0.348 | 5.863 ± 0.199 | 6.243 ± 0.217 | 7.055 ± 0.265 | 7.408 ± 0.352
Thymus
Absolute | 0.041 ± 0.001 | 0.036 ± 0.001 | 0.038 ± 0.002 | 0.041 ± 0.002 | 0.042 ± 0.002 | 0.031 ± 0.002**
Relative | 1.204 ± 0.039 | 1.087 ± 0.045 | 1.158 ± 0.104 | 1.218 ± 0.063 | 1.285 ± 0.068 | 1.019 ± 0.087

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 9.