# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for F344/N Rats in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 18.75 mg/kg | 37.5 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
Male
Hematology
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 25 | 9 | 10 | 9 | 10 | 9 | 9
Week 14 | 10 | 10 | 10 | 10 | 9 | 10
Hematocrit (auto) (%)
Day 4 | 45.0 ± 0.8 | 45.4 ± 0.6 | 44.5 ± 0.4 | 45.1 ± 0.5 | 44.3 ± 0.4 | 47.3 ± 1.5
Day 25 | 45.9 ± 0.4 | 46.5 ± 0.5 | 44.6 ± 0.6 | 46.0 ± 0.7 | 45.4 ± 0.5 | 45.0 ± 0.2
Week 14 | 48.5 ± 0.3 | 47.8 ± 0.4 | 48.8 ± 0.3 | 48.7 ± 0.4 | 48.4 ± 0.5 | 48.5 ± 0.6
Hematocrit (spun) (%)
Day 4 | 44.3 ± 0.6 | 44.7 ± 0.6 | 43.9 ± 0.3 | 44.3 ± 0.4 | 44.0 ± 0.5 | 46.3 ± 1.4
Day 25 | 46.2 ± 0.3 | 46.2 ± 0.5 | 45.0 ± 0.5 | 46.1 ± 0.5 | 45.6 ± 0.6 | 44.9 ± 0.3
Week 14 | 47.5 ± 0.3 | 46.8 ± 0.4 | 47.7 ± 0.3 | 47.8 ± 0.5 | 47.2 ± 0.4 | 47.3 ± 0.4
Hemoglobin (g/dL)
Day 4 | 14.9 ± 0.3 | 14.9 ± 0.2 | 14.7 ± 0.1 | 14.9 ± 0.2 | 14.7 ± 0.1 | 15.5 ± 0.5
Day 25 | 15.7 ± 0.2 | 15.8 ± 0.2 | 15.2 ± 0.3 | 15.8 ± 0.2 | 15.4 ± 0.2 | 15.4 ± 0.1
Week 14 | 15.9 ± 0.1 | 15.7 ± 0.1 | 16.1 ± 0.1 | 16.1 ± 0.1 | 15.9 ± 0.2 | 15.8 ± 0.2
Erythrocytes (10^6^/μL)
Day 4 | 7.39 ± 0.12 | 7.43 ± 0.11 | 7.30 ± 0.07 | 7.43 ± 0.07 | 7.36 ± 0.05 | 7.86 ± 0.25
Day 25 | 8.30 ± 0.09 | 8.38 ± 0.10 | 8.09 ± 0.09 | 8.31 ± 0.13 | 8.16 ± 0.09 | 8.25 ± 0.06
Week 14 | 8.49 ± 0.05 | 8.38 ± 0.08 | 8.67 ± 0.06 | 8.64 ± 0.07 | 8.63 ± 0.08 | 8.71 ± 0.12
Reticulocytes (10^5^/μL)
Day 4 | 5.49 ± 0.37 | 5.83 ± 0.35 | 5.66 ± 0.39 | 5.59 ± 0.33 | 5.13 ± 0.19 | 4.49 ± 0.22*
Day 25 | 2.87 ± 0.14 | 3.05 ± 0.08 | 2.93 ± 0.12 | 2.82 ± 0.14 | 2.78 ± 0.19 | 2.47 ± 0.17
Week 14 | 2.14 ± 0.04 | 2.03 ± 0.05 | 1.96 ± 0.04 | 1.98 ± 0.05 | 2.04 ± 0.09 | 1.93 ± 0.10
Reticulocytes (%)
Day 4 | 7.48 ± 0.57 | 7.90 ± 0.55 | 7.77 ± 0.54 | 7.52 ± 0.46 | 6.97 ± 0.28 | 5.81 ± 0.41*
Day 25 | 3.48 ± 0.18 | 3.64 ± 0.12 | 3.63 ± 0.16 | 3.43 ± 0.20 | 3.44 ± 0.26 | 2.99 ± 0.22
Week 14 | 2.52 ± 0.05 | 2.43 ± 0.06 | 2.27 ± 0.06 | 2.29 ± 0.07 | 2.36 ± 0.10 | 2.24 ± 0.12
Nucleated erythrocytes/100 leukocytes
Day 4 | 0.5 ± 0.2 | 0.9 ± 0.3 | 0.2 ± 0.1 | 0.7 ± 0.2 | 0.7 ± 0.2 | 0.6 ± 0.3
Day 25 | 0.1 ± 0.1 | 0.1 ± 0.1 | 0.2 ± 0.1 | 0.2 ± 0.1 | 0.2 ± 0.2 | 0.3 ± 0.2
Week 14 | 0.2 ± 0.2 | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Mean cell volume (fL)
Day 4 | 60.8 ± 0.3 | 61.2 ± 0.5 | 61.0 ± 0.2 | 60.7 ± 0.3 | 60.2 ± 0.3 | 60.2 ± 0.3
Day 25 | 55.4 ± 0.3 | 55.5 ± 0.3 | 55.2 ± 0.2 | 55.3 ± 0.3 | 55.6 ± 0.3 | 54.6 ± 0.4
Week 14 | 57.1 ± 0.2 | 57.0 ± 0.2 | 56.4 ± 0.3 | 56.4 ± 0.2* | 56.1 ± 0.2** | 55.6 ± 0.2**
Mean cell hemoglobin (pg)
Day 4 | 20.1 ± 0.1 | 20.1 ± 0.2 | 20.1 ± 0.1 | 20.0 ± 0.2 | 20.0 ± 0.1 | 19.8 ± 0.1
Day 25 | 18.9 ± 0.1 | 18.9 ± 0.1 | 18.7 ± 0.2 | 19.0 ± 0.1 | 18.9 ± 0.1 | 18.6 ± 0.1
Week 14 | 18.7 ± 0.1 | 18.7 ± 0.1 | 18.6 ± 0.1 | 18.6 ± 0.1 | 18.4 ± 0.1** | 18.1 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 4 | 33.1 ± 0.2 | 32.9 ± 0.2 | 33.0 ± 0.2 | 32.9 ± 0.2 | 33.1 ± 0.1 | 32.8 ± 0.2
Day 25 | 34.2 ± 0.2 | 34.1 ± 0.2 | 34.0 ± 0.3 | 34.3 ± 0.2 | 34.0 ± 0.1 | 34.1 ± 0.2
Week 14 | 32.7 ± 0.1 | 32.8 ± 0.1 | 33.0 ± 0.2 | 33.0 ± 0.1 | 32.8 ± 0.1 | 32.6 ± 0.1
Platelets (10^3^/μL)
Day 4 | 972.3 ± 40.4 | 1,004.3 ± 20.3 | 934.5 ± 23.8 | 1,090.1 ± 47.6 | 1,015.7 ± 34.4 | 1,117.9 ± 48.0
Day 25 | 752.3 ± 20.6 | 795.3 ± 24.7 | 815.1 ± 47.0 | 775.5 ± 29.3 | 803.2 ± 30.0 | 805.4 ± 26.6
Week 14 | 588.3 ± 18.8 | 600.7 ± 11.3 | 604.1 ± 8.3 | 602.8 ± 8.1 | 618.3 ± 12.9 | 658.5 ± 15.7**
Leukocytes (10^3^/μL)
Day 4 | 8.87 ± 0.27 | 9.03 ± 0.22 | 8.42 ± 0.45 | 9.65 ± 0.36 | 8.91 ± 0.19 | 8.00 ± 0.75
Day 25 | 9.63 ± 0.46 | 9.36 ± 0.83 | 9.79 ± 0.61 | 9.67 ± 0.31 | 9.11 ± 0.84 | 9.97 ± 0.91
Week 14 | 7.78 ± 0.56 | 7.76 ± 0.47 | 7.94 ± 0.50 | 8.06 ± 0.46 | 8.20 ± 0.78 | 7.76 ± 0.70
Segmented neutrophils (10^3^/μL)
Day 4 | 1.08 ± 0.04 | 1.15 ± 0.07 | 1.10 ± 0.06 | 1.22 ± 0.07 | 1.08 ± 0.06 | 1.18 ± 0.07
Day 25 | 0.82 ± 0.04 | 0.78 ± 0.07 | 0.89 ± 0.06 | 0.85 ± 0.04 | 0.81 ± 0.06 | 0.99 ± 0.06
Week 14 | 1.13 ± 0.04 | 1.15 ± 0.06 | 1.11 ± 0.04 | 1.01 ± 0.04 | 1.12 ± 0.05 | 1.16 ± 0.05
Lymphocytes (10^3^/μL)
Day 4 | 7.38 ± 0.24 | 7.51 ± 0.19 | 6.96 ± 0.40 | 7.96 ± 0.31 | 7.42 ± 0.16 | 6.39 ± 0.67
Day 25 | 8.38 ± 0.44 | 8.15 ± 0.73 | 8.42 ± 0.53 | 8.46 ± 0.30 | 7.91 ± 0.74 | 8.50 ± 0.82
Week 14 | 6.32 ± 0.55 | 6.30 ± 0.42 | 6.53 ± 0.49 | 6.74 ± 0.45 | 6.74 ± 0.72 | 6.33 ± 0.65
Monocytes (10^3^/μL)
Day 4 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.24 ± 0.02 | 0.21 ± 0.01 | 0.22 ± 0.03
Day 25 | 0.15 ± 0.01 | 0.15 ± 0.01 | 0.14 ± 0.02 | 0.12 ± 0.02 | 0.14 ± 0.02 | 0.19 ± 0.03
Week 14 | 0.12 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.10 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01
Basophils (10^3^/μL)
Day 4 | 0.033 ± 0.005 | 0.037 ± 0.004 | 0.028 ± 0.005 | 0.032 ± 0.003 | 0.039 ± 0.007 | 0.036 ± 0.008
Day 25 | 0.069 ± 0.010 | 0.066 ± 0.013 | 0.069 ± 0.013 | 0.063 ± 0.010 | 0.052 ± 0.012 | 0.066 ± 0.013
Week 14 | 0.059 ± 0.007 | 0.049 ± 0.008 | 0.045 ± 0.009 | 0.066 ± 0.005 | 0.066 ± 0.010 | 0.043 ± 0.008
Eosinophils (10^3^/μL)
Day 4 | 0.04 ± 0.00 | 0.03 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.03 ± 0.00 | 0.02 ± 0.00*
Day 25 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01
Week 14 | 0.08 ± 0.01 | 0.07 ± 0.00* | 0.07 ± 0.00* | 0.06 ± 0.00** | 0.07 ± 0.01* | 0.04 ± 0.01**
Large unstained cells (10^3^/μL)
Day 4 | 0.142 ± 0.011 | 0.109 ± 0.010 | 0.115 ± 0.012 | 0.150 ± 0.008 | 0.137 ± 0.012 | 0.145 ± 0.023
Day 25 | 0.150 ± 0.037 | 0.167 ± 0.034 | 0.224 ± 0.052 | 0.137 ± 0.018 | 0.162 ± 0.051 | 0.178 ± 0.026
Week 14 | 0.081 ± 0.009 | 0.080 ± 0.008 | 0.074 ± 0.008 | 0.091 ± 0.005 | 0.091 ± 0.012 | 0.081 ± 0.011
Clinical Chemistry
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 25 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 11.7 ± 0.5 | 13.1 ± 0.6 | 13.6 ± 0.6 | 13.4 ± 0.5 | 14.1 ± 0.7* | 13.4 ± 0.5
Day 25 | 15.4 ± 0.5 | 14.2 ± 0.5 | 15.2 ± 0.5 | 14.4 ± 0.5 | 13.3 ± 0.5** | 13.4 ± 0.3**
Week 14 | 12.2 ± 0.4 | 12.8 ± 0.4 | 13.4 ± 0.4 | 15.1 ± 1.1 | 11.9 ± 0.5 | 13.3 ± 0.5
Creatinine (mg/dL)
Day 4 | 0.12 ± 0.01 | 0.10 ± 0.00 | 0.11 ± 0.01 | 0.12 ± 0.01 | 0.11 ± 0.01 | 0.12 ± 0.01
Day 25 | 0.21 ± 0.02 | 0.23 ± 0.02 | 0.20 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.20 ± 0.00
Week 14 | 0.29 ± 0.01 | 0.28 ± 0.01 | 0.32 ± 0.01 | 0.30 ± 0.00 | 0.29 ± 0.01 | 0.31 ± 0.02
Glucose (mg/dL)
Day 4 | 126 ± 3 | 123 ± 2 | 123 ± 1 | 121 ± 2 | 125 ± 2 | 116 ± 3
Day 25 | 127 ± 2 | 126 ± 4 | 123 ± 2 | 122 ± 2 | 126 ± 2 | 128 ± 3
Week 14 | 131 ± 3 | 134 ± 3 | 138 ± 3 | 135 ± 3 | 136 ± 3 | 130 ± 3
Total protein (g/dL)
Day 4 | 5.6 ± 0.1 | 5.7 ± 0.1 | 5.8 ± 0.0 | 5.7 ± 0.1 | 5.6 ± 0.1 | 5.6 ± 0.1
Day 25 | 6.5 ± 0.1 | 6.7 ± 0.1 | 6.6 ± 0.1 | 6.7 ± 0.1 | 6.7 ± 0.1 | 6.4 ± 0.1
Week 14 | 6.7 ± 0.1 | 6.7 ± 0.1 | 6.9 ± 0.0 | 6.8 ± 0.1 | 6.8 ± 0.1 | 6.4 ± 0.1
Albumin (g/dL)
Day 4 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.2 ± 0.0 | 4.2 ± 0.1
Day 25 | 4.6 ± 0.0 | 4.7 ± 0.1 | 4.6 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.0 | 4.6 ± 0.0
Week 14 | 4.8 ± 0.1 | 4.7 ± 0.0 | 4.9 ± 0.0 | 4.9 ± 0.0 | 4.9 ± 0.0 | 4.6 ± 0.1
Alanine aminotransferase (IU/L)
Day 4 | 77 ± 3 | 79 ± 3 | 80 ± 2 | 77 ± 2 | 79 ± 3 | 95 ± 3**
Day 25 | 64 ± 2 | 61 ± 2 | 61 ± 2 | 65 ± 2 | 58 ± 1 | 71 ± 1
Week 14 | 61 ± 3 | 55 ± 2 | 53 ± 2 | 59 ± 4 | 49 ± 1** | 66 ± 4
Alkaline phosphatase (IU/L)
Day 4 | 633 ± 14 | 631 ± 18 | 617 ± 12 | 656 ± 18 | 691 ± 17* | 738 ± 26**
Day 25 | 445 ± 8 | 459 ± 11 | 437 ± 9 | 416 ± 13 | 380 ± 30** | 377 ± 15**
Week 14 | 223 ± 3 | 232 ± 6 | 224 ± 6 | 206 ± 7 | 198 ± 4** | 178 ± 4**
Creatine kinase (IU/L)
Day 4 | 628 ± 61 | 591 ± 53 | 587 ± 46 | 622 ± 68 | 545 ± 42 | 540 ± 45
Day 25 | 520 ± 70 | 464 ± 67 | 368 ± 35 | 376 ± 41 | 340 ± 35 | 430 ± 37
Week 14 | 242 ± 33 | 256 ± 27 | 243 ± 34 | 230 ± 17 | 267 ± 38 | 284 ± 34
Sorbitol dehydrogenase (IU/L)
Day 4 | 6 ± 1^b^ | 9 ± 1^b^ | 8 ± 2^c^ | 8 ± 1*^b^ | 9 ± 1* | 13 ± 2**
Day 25 | 9 ± 2^b^ | 10 ± 2 | 10 ± 1^b^ | 10 ± 2^d^ | 11 ± 1^b^ | 12 ± 2
Week 14 | 18 ± 1 | 17 ± 1 | 15 ± 1 | 17 ± 1 | 13 ± 2 | 17 ± 2
Bile acids (µmol/L)
Day 4 | 18.8 ± 1.8 | 20.1 ± 2.0 | 21.7 ± 1.8 | 24.7 ± 1.1** | 28.2 ± 2.0** | 29.6 ± 1.4**
Day 25 | 17.8 ± 0.9 | 16.5 ± 1.8 | 14.9 ± 0.9 | 22.5 ± 1.8 | 23.4 ± 1.7 | 21.3 ± 1.3
Week 14 | 19.5 ± 2.4 | 20.0 ± 2.6 | 18.6 ± 2.6 | 18.0 ± 1.5 | 19.1 ± 1.0 | 21.3 ± 1.3
Female
Hematology
n
Day 4 | 9 | 10 | 9 | 10 | 10 | 9
Day 25 | 8 | 10 | 10 | 8 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
Day 4 | 48.8 ± 0.7 | 48.7 ± 0.7 | 50.4 ± 0.8 | 49.8 ± 1.0 | 48.8 ± 1.2 | 50.1 ± 1.0
Day 25 | 47.3 ± 0.7 | 46.7 ± 0.8 | 47.0 ± 0.5 | 46.8 ± 0.6 | 47.8 ± 0.6 | 47.3 ± 0.3
Week 14 | 47.8 ± 0.4 | 46.8 ± 0.3 | 46.2 ± 0.3* | 47.0 ± 0.5 | 46.0 ± 0.3* | 46.7 ± 0.4
Hematocrit (spun) (%)
Day 4 | 48.5 ± 0.8 | 47.9 ± 0.6 | 50.0 ± 0.6 | 49.4 ± 0.9 | 48.6 ± 1.0 | 50.3 ± 0.9
Day 25 | 46.6 ± 0.5 | 45.9 ± 0.7 | 46.5 ± 0.5 | 46.4 ± 0.5 | 47.3 ± 0.5 | 47.2 ± 0.4
Week 14 | 47.3 ± 0.4 | 46.7 ± 0.3 | 46.5 ± 0.3 | 46.8 ± 0.4 | 45.8 ± 0.2* | 46.6 ± 0.4
Hemoglobin (g/dL)
Day 4 | 15.8 ± 0.3 | 15.8 ± 0.2 | 16.2 ± 0.3 | 16.4 ± 0.4 | 15.9 ± 0.4 | 16.4 ± 0.3
Day 25 | 15.5 ± 0.2 | 15.5 ± 0.2 | 15.7 ± 0.1 | 15.5 ± 0.2 | 15.8 ± 0.1 | 15.6 ± 0.1
Week 14 | 15.6 ± 0.1 | 15.4 ± 0.1 | 15.2 ± 0.1** | 15.4 ± 0.1* | 15.1 ± 0.1** | 15.2 ± 0.1**
Erythrocytes (10^6^/μL)
Day 4 | 8.02 ± 0.10 | 7.99 ± 0.13 | 8.20 ± 0.12 | 8.17 ± 0.16 | 7.96 ± 0.19 | 8.35 ± 0.15
Day 25 | 8.56 ± 0.08 | 8.37 ± 0.15 | 8.49 ± 0.08 | 8.47 ± 0.12 | 8.63 ± 0.08 | 8.63 ± 0.07
Week 14 | 8.22 ± 0.06 | 8.11 ± 0.05 | 8.02 ± 0.07 | 8.24 ± 0.07 | 8.16 ± 0.05 | 8.41 ± 0.07
Reticulocytes (10^5^/μL)
Day 4 | 4.10 ± 0.36 | 4.29 ± 0.38 | 4.48 ± 0.43 | 3.82 ± 0.34 | 3.90 ± 0.30 | 3.10 ± 0.26*
Day 25 | 1.76 ± 0.11 | 2.07 ± 0.14 | 1.89 ± 0.09 | 1.96 ± 0.07 | 1.90 ± 0.09 | 1.78 ± 0.08
Week 14 | 1.76 ± 0.04 | 1.91 ± 0.08 | 1.88 ± 0.09 | 1.80 ± 0.08 | 1.83 ± 0.04 | 1.91 ± 0.06
Reticulocytes (%)
Day 4 | 5.13 ± 0.48 | 5.38 ± 0.49 | 5.49 ± 0.53 | 4.75 ± 0.52 | 4.97 ± 0.48 | 3.74 ± 0.34*
Day 25 | 2.05 ± 0.14 | 2.49 ± 0.19 | 2.21 ± 0.10 | 2.30 ± 0.12 | 2.21 ± 0.12 | 2.07 ± 0.09
Week 14 | 2.14 ± 0.05 | 2.36 ± 0.12 | 2.36 ± 0.12 | 2.20 ± 0.09 | 2.23 ± 0.05 | 2.27 ± 0.07
Nucleated erythrocytes/100 leukocytes
Day 4 | 0.7 ± 0.3 | 0.3 ± 0.2 | 0.8 ± 0.4 | 1.0 ± 0.3 | 0.9 ± 0.3 | 0.7 ± 0.4
Day 25 | 0.1 ± 0.1 | 0.2 ± 0.1 | 0.2 ± 0.1 | 0.3 ± 0.3 | 0.2 ± 0.1 | 0.1 ± 0.1
Week 14 | 0.2 ± 0.2 | 0.4 ± 0.2 | 0.2 ± 0.1 | 0.2 ± 0.1 | 0.1 ± 0.1 | 0.2 ± 0.1
Mean cell volume (fL)
Day 4 | 60.9 ± 0.3 | 61.0 ± 0.2 | 61.5 ± 0.3 | 61.0 ± 0.2 | 61.2 ± 0.4 | 60.0 ± 0.3
Day 25 | 55.3 ± 0.4 | 55.8 ± 0.3 | 55.4 ± 0.3 | 55.3 ± 0.3 | 55.5 ± 0.5 | 54.8 ± 0.4
Week 14 | 58.1 ± 0.1 | 57.7 ± 0.1** | 57.6 ± 0.2** | 57.0 ± 0.1** | 56.4 ± 0.2** | 55.5 ± 0.1**
Mean cell hemoglobin (pg)
Day 4 | 19.8 ± 0.1 | 19.8 ± 0.2 | 19.8 ± 0.1 | 20.0 ± 0.1 | 20.0 ± 0.1 | 19.7 ± 0.2
Day 25 | 18.1 ± 0.1 | 18.5 ± 0.1 | 18.5 ± 0.1 | 18.3 ± 0.1 | 18.3 ± 0.1 | 18.0 ± 0.1
Week 14 | 19.0 ± 0.1 | 19.0 ± 0.0 | 18.9 ± 0.1* | 18.7 ± 0.0** | 18.5 ± 0.1** | 18.0 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 4 | 32.4 ± 0.3 | 32.4 ± 0.2 | 32.2 ± 0.3 | 32.8 ± 0.2 | 32.6 ± 0.2 | 32.8 ± 0.2
Day 25 | 32.8 ± 0.2 | 33.1 ± 0.2 | 33.4 ± 0.2 | 33.1 ± 0.2 | 33.0 ± 0.2 | 32.9 ± 0.1
Week 14 | 32.8 ± 0.1 | 32.8 ± 0.1 | 32.9 ± 0.2 | 32.7 ± 0.1 | 32.8 ± 0.2 | 32.5 ± 0.1
Platelets (10^3^/μL)
Day 4 | 955.8 ± 39.5 | 983.1 ± 46.2 | 979.3 ± 58.0 | 962.5 ± 23.3 | 926.6 ± 46.6 | 1,077.2 ± 50.4
Day 25 | 755.6 ± 29.7 | 729.4 ± 20.9 | 729.0 ± 20.5 | 721.0 ± 27.4 | 787.4 ± 34.2 | 711.4 ± 33.7
Week 14 | 573.2 ± 19.6 | 588.1 ± 12.9 | 554.1 ± 18.9 | 621.4 ± 13.6 | 590.1 ± 15.0 | 610.7 ± 21.6
Leukocytes (10^3^/μL)
Day 4 | 10.37 ± 0.34 | 9.82 ± 0.21 | 9.00 ± 0.25* | 10.32 ± 0.42 | 10.08 ± 0.35 | 10.75 ± 0.35
Day 25 | 9.64 ± 0.55 | 9.54 ± 0.36 | 9.22 ± 0.68 | 9.56 ± 0.81 | 9.93 ± 0.64 | 10.37 ± 0.51
Week 14 | 6.40 ± 0.36 | 6.50 ± 0.30 | 6.40 ± 0.44 | 6.49 ± 0.38 | 6.58 ± 0.36 | 7.20 ± 0.38
Segmented neutrophils (10^3^/μL)
Day 4 | 1.03 ± 0.04 | 1.05 ± 0.05 | 1.04 ± 0.06 | 1.08 ± 0.06 | 1.15 ± 0.08 | 1.30 ± 0.07**
Day 25 | 0.84 ± 0.06 | 0.98 ± 0.08 | 0.92 ± 0.10 | 0.96 ± 0.10 | 0.83 ± 0.07 | 1.08 ± 0.06
Week 14 | 1.08 ± 0.07 | 1.19 ± 0.07 | 1.23 ± 0.08 | 1.28 ± 0.07 | 1.03 ± 0.05 | 1.14 ± 0.04
Lymphocytes (10^3^/μL)
Day 4 | 8.89 ± 0.28 | 8.38 ± 0.22 | 7.62 ± 0.21* | 8.80 ± 0.37 | 8.53 ± 0.30 | 8.96 ± 0.31
Day 25 | 8.40 ± 0.49 | 8.13 ± 0.35 | 7.90 ± 0.56 | 8.19 ± 0.70 | 8.63 ± 0.53 | 8.76 ± 0.52
Week 14 | 5.05 ± 0.30 | 5.02 ± 0.26 | 4.88 ± 0.40 | 4.94 ± 0.34 | 5.27 ± 0.33 | 5.78 ± 0.31
Monocytes (10^3^/μL)
Day 4 | 0.23 ± 0.02 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.23 ± 0.02 | 0.22 ± 0.02 | 0.27 ± 0.02
Day 25 | 0.16 ± 0.02 | 0.15 ± 0.01 | 0.13 ± 0.02 | 0.15 ± 0.02 | 0.17 ± 0.02 | 0.19 ± 0.02
Week 14 | 0.09 ± 0.01 | 0.10 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01
Basophils (10^3^/μL)
Day 4 | 0.037 ± 0.004 | 0.031 ± 0.004 | 0.026 ± 0.002 | 0.034 ± 0.004 | 0.031 ± 0.004 | 0.037 ± 0.003
Day 25 | 0.050 ± 0.008 | 0.064 ± 0.011 | 0.061 ± 0.011 | 0.074 ± 0.010 | 0.070 ± 0.013 | 0.082 ± 0.010
Week 14 | 0.045 ± 0.008 | 0.061 ± 0.011 | 0.047 ± 0.008 | 0.050 ± 0.006 | 0.050 ± 0.008 | 0.053 ± 0.008
Eosinophils (10^3^/μL)
Day 4 | 0.04 ± 0.01 | 0.03 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.03 ± 0.00 | 0.04 ± 0.01
Day 25 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.04 ± 0.00** | 0.05 ± 0.01*
Week 14 | 0.08 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.00* | 0.06 ± 0.01* | 0.04 ± 0.00**
Large unstained cells (10^3^/μL)
Day 4 | 0.143 ± 0.018 | 0.116 ± 0.005 | 0.097 ± 0.008* | 0.130 ± 0.012 | 0.120 ± 0.011 | 0.174 ± 0.019
Day 25 | 0.136 ± 0.014 | 0.155 ± 0.032 | 0.151 ± 0.024 | 0.141 ± 0.019 | 0.188 ± 0.061 | 0.217 ± 0.044
Week 14 | 0.054 ± 0.008 | 0.077 ± 0.020 | 0.079 ± 0.016 | 0.067 ± 0.007 | 0.077 ± 0.011 | 0.087 ± 0.023
Clinical Chemistry
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 9
Day 25 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 11.7 ± 0.6 | 12.6 ± 0.6 | 11.8 ± 0.6 | 13.2 ± 0.6 | 13.6 ± 0.5 | 12.6 ± 0.6
Day 25 | 16.4 ± 0.5 | 14.8 ± 0.3 | 16.4 ± 0.5 | 15.2 ± 0.5 | 15.0 ± 0.5 | 14.1 ± 0.4*
Week 14 | 12.6 ± 0.4 | 13.9 ± 0.3 | 12.8 ± 0.4 | 13.1 ± 0.4 | 12.2 ± 0.7 | 12.3 ± 0.5
Creatinine (mg/dL)
Day 4 | 0.17 ± 0.02 | 0.14 ± 0.02 | 0.17 ± 0.02 | 0.18 ± 0.01 | 0.17 ± 0.02 | 0.19 ± 0.01
Day 25 | 0.25 ± 0.02 | 0.19 ± 0.02 | 0.26 ± 0.02 | 0.24 ± 0.02 | 0.22 ± 0.01 | 0.22 ± 0.01
Week 14 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.27 ± 0.02 | 0.30 ± 0.00 | 0.27 ± 0.02 | 0.29 ± 0.01
Glucose (mg/dL)
Day 4 | 133 ± 3 | 135 ± 4 | 135 ± 7 | 133 ± 3 | 124 ± 2 | 124 ± 4
Day 25 | 125 ± 8 | 120 ± 4 | 128 ± 4 | 137 ± 6 | 116 ± 3^b^ | 117 ± 4
Week 14 | 130 ± 2 | 130 ± 3 | 131 ± 2 | 136 ± 4 | 128 ± 2 | 127 ± 2
Total protein (g/dL)
Day 4 | 5.9 ± 0.1 | 6.0 ± 0.1 | 6.0 ± 0.1 | 6.0 ± 0.1 | 6.1 ± 0.1 | 6.0 ± 0.1
Day 25 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.4 ± 0.1 | 6.4 ± 0.0 | 6.6 ± 0.1 | 6.4 ± 0.1
Week 14 | 6.6 ± 0.1 | 6.9 ± 0.1 | 6.6 ± 0.1 | 6.8 ± 0.1 | 6.7 ± 0.1 | 6.3 ± 0.1
Albumin (g/dL)
Day 4 | 4.4 ± 0.1 | 4.5 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.1 | 4.4 ± 0.1
Day 25 | 4.7 ± 0.1 | 4.8 ± 0.1 | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.8 ± 0.1 | 4.7 ± 0.1
Week 14 | 4.9 ± 0.1 | 5.1 ± 0.1 | 4.9 ± 0.0 | 5.0 ± 0.1 | 5.0 ± 0.1 | 4.7 ± 0.0
Alanine aminotransferase (IU/L)
Day 4 | 65 ± 2 | 66 ± 2 | 67 ± 3 | 65 ± 3 | 69 ± 2 | 80 ± 2**
Day 25 | 52 ± 1 | 48 ± 2 | 52 ± 1 | 49 ± 2 | 47 ± 2 | 58 ± 2
Week 14 | 62 ± 4 | 42 ± 2** | 45 ± 2** | 36 ± 1** | 35 ± 1** | 47 ± 1**
Alkaline phosphatase (IU/L)
Day 4 | 553 ± 11 | 583 ± 15 | 585 ± 19 | 571 ± 13 | 576 ± 12 | 610 ± 18
Day 25 | 381 ± 8 | 382 ± 9 | 371 ± 11 | 348 ± 8* | 327 ± 13** | 328 ± 11**
Week 14 | 205 ± 4 | 180 ± 5** | 189 ± 9* | 190 ± 6* | 164 ± 5** | 155 ± 6**
Creatine kinase (IU/L)
Day 4 | 447 ± 52 | 445 ± 46 | 463 ± 35 | 462 ± 39 | 395 ± 26^b^ | 415 ± 37
Day 25 | 453 ± 77 | 468 ± 51 | 438 ± 58 | 534 ± 91 | 424 ± 40 | 426 ± 25
Week 14 | 187 ± 17 | 229 ± 30 | 238 ± 20 | 189 ± 22 | 152 ± 19 | 187 ± 21
Sorbitol dehydrogenase (IU/L)
Day 4 | 7 ± 1^b^ | 7 ± 1^b^ | 3 ± 1^b^ | 5 ± 1^b^ | 7 ± 1 | 8 ± 2
Day 25 | 10 ± 3^e^ | 10 ± 2 | 12 ± 2^d^ | 8 ± 2^d^ | 11 ± 2 | 10 ± 1
Week 14 | 15 ± 1 | 14 ± 1 | 16 ± 1 | 15 ± 2 | 12 ± 1 | 14 ± 1
Bile acids (µmol/L)
Day 4 | 17.2 ± 3.3 | 16.7 ± 1.6 | 13.9 ± 0.7 | 18.2 ± 1.1 | 19.8 ± 2.1 | 20.2 ± 1.5*
Day 25 | 17.7 ± 2.3 | 16.0 ± 0.9 | 19.9 ± 2.6 | 20.2 ± 1.7 | 24.5 ± 2.7* | 23.0 ± 1.9*
Week 14 | 15.8 ± 1.9 | 18.4 ± 3.1 | 16.8 ± 1.5 | 14.4 ± 1.2 | 17.2 ± 1.6 | 20.0 ± 2.1

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 7.

^d^ n = 8.

^e^ n = 6.

Table F-2 Hematology Data for Mice in the Three-month Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 15.6 mg/kg | 31.25 mg/kg | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematocrit (auto) (%) | 51.0 ± 0.6 | 50.9 ± 0.3 | 51.2 ± 0.3 | 50.5 ± 0.7 | 52.6 ± 0.6 | 53.0 ± 0.5*
Hematocrit (spun) (%) | 50.0 ± 0.5 | 50.0 ± 0.3 | 49.8 ± 0.3 | 49.6 ± 0.6 | 51.8 ± 0.6* | 52.3 ± 0.5**
Hemoglobin (g/dL) | 17.1 ± 0.2 | 17.0 ± 0.1 | 17.2 ± 0.1 | 16.9 ± 0.2 | 17.5 ± 0.2* | 17.8 ± 0.2**
Erythrocytes (10^6^/µL) | 10.19 ± 0.14 | 10.27 ± 0.05 | 10.25 ± 0.07 | 10.14 ± 0.13 | 10.58 ± 0.14* | 10.73 ± 0.11**
Reticulocytes (10^5^/µL) | 3.23 ± 0.10 | 3.13 ± 0.05 | 3.01 ± 0.04 | 3.15 ± 0.09 | 3.11 ± 0.08 | 3.09 ± 0.06
Reticulocytes (%) | 3.19 ± 0.10 | 3.04 ± 0.05 | 2.96 ± 0.05 | 3.11 ± 0.11 | 2.93 ± 0.08* | 2.88 ± 0.06*
Nucleated erythrocytes/ 100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 50.1 ± 0.3 | 49.6 ± 0.2 | 49.9 ± 0.3 | 49.8 ± 0.2 | 49.7 ± 0.2 | 49.4 ± 0.3*
Mean cell hemoglobin (pg) | 16.8 ± 0.1 | 16.6 ± 0.1 | 16.8 ± 0.1 | 16.7 ± 0.1 | 16.6 ± 0.1 | 16.6 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.5 ± 0.1 | 33.5 ± 0.1 | 33.6 ± 0.1 | 33.5 ± 0.1 | 33.4 ± 0.2 | 33.5 ± 0.1
Platelets (10^3^/µL) | 853.0 ± 22.2 | 906.4 ± 40.5 | 866.3 ± 36.4 | 900.1 ± 34.4 | 838.8 ± 35.2 | 900.2 ± 28.9
Leukocytes (10^3^/µL) | 4.26 ± 0.33 | 4.55 ± 0.22 | 4.64 ± 0.23 | 4.48 ± 0.35 | 4.74 ± 0.28 | 4.89 ± 0.39
Segmented neutrophils (10^3^/µL) | 0.55 ± 0.04 | 0.53 ± 0.04 | 0.52 ± 0.02 | 0.55 ± 0.05 | 0.58 ± 0.04 | 0.58 ± 0.03
Lymphocytes (10^3^/µL) | 3.36 ± 0.28 | 3.66 ± 0.18 | 3.82 ± 0.23 | 3.58 ± 0.30 | 3.80 ± 0.24 | 4.00 ± 0.35
Monocytes (10^3^/µL) | 0.05 ± 0.01 | 0.05 ± 0.00 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.05 ± 0.01
Basophils (10^3^/µL) | 0.007 ± 0.002 | 0.006 ± 0.002 | 0.011 ± 0.002 | 0.008 ± 0.002 | 0.009 ± 0.003 | 0.007 ± 0.002
Eosinophils (10^3^/µL) | 0.27 ± 0.03 | 0.28 ± 0.03 | 0.21 ± 0.02 | 0.27 ± 0.02 | 0.26 ± 0.04 | 0.23 ± 0.04
Large unstained cells (10^3^/μL) | 0.017 ± 0.004 | 0.015 ± 0.002 | 0.022 ± 0.002 | 0.017 ± 0.003 | 0.020 ± 0.004 | 0.022 ± 0.004
Female
Hematocrit (auto) (%) | 51.5 ± 0.4 | 50.3 ± 1.4 | 53.0 ± 0.4 | 51.5 ± 0.5 | 51.1 ± 0.6 | 52.1 ± 0.7
Hematocrit (spun) (%) | 50.3 ± 0.5 | 49.5 ± 1.2 | 51.9 ± 0.3 | 50.8 ± 0.4 | 50.5 ± 0.6 | 51.0 ± 0.6
Hemoglobin (g/dL) | 17.1 ± 0.2 | 16.6 ± 0.4 | 17.5 ± 0.1 | 17.2 ± 0.1 | 17.0 ± 0.2 | 17.3 ± 0.2
Erythrocytes (10^6^/µL) | 10.30 ± 0.11 | 9.99 ± 0.25 | 10.57 ± 0.10 | 10.31 ± 0.08 | 10.25 ± 0.13 | 10.50 ± 0.12
Reticulocytes (10^5^/µL) | 2.98 ± 0.16 | 2.64 ± 0.22 | 3.48 ± 0.27 | 2.86 ± 0.18 | 2.71 ± 0.10 | 2.64 ± 0.21
Reticulocytes (%) | 2.89 ± 0.16 | 2.66 ± 0.22 | 3.31 ± 0.26 | 2.77 ± 0.17 | 2.64 ± 0.13 | 2.54 ± 0.20
Nucleated erythrocytes/ 100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 50.1 ± 0.2 | 50.4 ± 0.4 | 50.2 ± 0.2 | 50.0 ± 0.2 | 49.9 ± 0.2 | 49.6 ± 0.2
Mean cell hemoglobin (pg) | 16.6 ± 0.1 | 16.7 ± 0.1 | 16.6 ± 0.1 | 16.7 ± 0.1 | 16.6 ± 0.1 | 16.4 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.1 ± 0.1 | 33.0 ± 0.2 | 33.1 ± 0.1 | 33.5 ± 0.2 | 33.3 ± 0.1 | 33.2 ± 0.1
Platelets (10^3^/µL) | 643.3 ± 36.7 | 750.3 ± 49.4 | 734.3 ± 52.7 | 744.1 ± 20.8 | 647.2 ± 36.2 | 658.5 ± 21.1
Leukocytes (10^3^/µL) | 2.63 ± 0.22 | 3.78 ± 0.60 | 2.84 ± 0.17 | 3.27 ± 0.15 | 2.97 ± 0.18 | 2.83 ± 0.18
Segmented neutrophils (10^3^/µL) | 0.28 ± 0.05 | 0.77 ± 0.44 | 0.34 ± 0.05 | 0.43 ± 0.04 | 0.31 ± 0.03 | 0.29 ± 0.04
Lymphocytes (10^3^/µL) | 2.11 ± 0.18 | 2.77 ± 0.22 | 2.29 ± 0.16 | 2.65 ± 0.13 | 2.44 ± 0.16 | 2.30 ± 0.13
Monocytes (10^3^/µL) | 0.02 ± 0.00 | 0.03 ± 0.01 | 0.03 ± 0.00 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01
Basophils (10^3^/µL) | 0.006 ± 0.002 | 0.006 ± 0.002 | 0.007 ± 0.002 | 0.007 ± 0.002 | 0.006 ± 0.002 | 0.006 ± 0.002
Eosinophils (10^3^/µL) | 0.21 ± 0.02 | 0.19 ± 0.03 | 0.17 ± 0.03 | 0.14 ± 0.04 | 0.17 ± 0.03 | 0.19 ± 0.03
Large unstained cells (10^3^/μL) | 0.009 ± 0.002 | 0.017 ± 0.003 | 0.010 ± 0.001 | 0.014 ± 0.002 | 0.012 ± 0.001 | 0.010 ± 0.001

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.