# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Testing procedures used in the first two studies, conducted at BioReliance Corporation (Rockville, MD) followed protocols reported by Zeiger et al.^135^; in the study conducted by SITEK Research Laboratories (Rockville, MD) using the same chemical lot (CHP801001) that was used in the 3-month and 2-year bioassays, a slightly modified procedure was used, and that is described in detail below. Indole-3-carbinol was tested as a coded sample. In the studies conducted at BioReliance Corporation, indole-3-carbinol was incubated with the Salmonella typhimurium tester strains TA97, TA98, TA100, TA102, TA104, TA1535, and TA1537 either in buffer or 10% or 30% S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

The modified protocol used at SITEK Research Laboratories used only 10% rat liver S9 for exogenous metabolic activation and employed tryptophan-dependent Escherichia coli strain WP2 uvrA/pKM101 as a bacterial tester strain in addition to S. typhimurium strains TA98 and TA100. Incubation of bacterial strains with indole-3-carbinol and subsequent plating were carried out as described above for the traditional protocol with the addition of tryptophan-deficient medium for the E. coli tester strain.

In both studies, each trial consisted of triplicate plates of concurrent positive and negative controls and at least five doses of indole-3-carbinol. At both laboratories, the highest concentration tested was limited by toxicity. All trials were repeated except TA1537 without S9.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine- or tryptophan-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Rat Bone Marrow Micronucleus Test Protocol

Indole-3-carbinol (500, 1,000, or 2,000 mg/kg per day) was administered to male F344/N rats, five per treatment group, once daily for 3 days by gavage, a protocol similar to that presented by Shelby et al.^119^. The positive control was 25 mg/kg cyclophosphamide and the vehicle control was corn oil. The rats were euthanized 24 hours after the third dosing, and blood smears were prepared from bone marrow cells obtained from the femurs. Air-dried smears were fixed and stained with acridine orange; 2,000 polychromatic erythrocytes (PCEs; reticulocytes) were scored for frequency of micronucleated cells in three to five rats per dose group. In addition, the percentage of PCEs among 200 erythrocytes in the bone marrow was determined for each animal as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among PCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## E.3 Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^136^. At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were shipped to the genetic toxicity testing laboratory (ILS, Inc., Research Triangle Park, NC) where they were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronucleated cells in 2,000 normochromatic erythrocytes (NCEs) in each of five mice per dose group. In addition, the percentage of PCEs in a population of 1,000 erythrocytes was determined as a measure of bone marrow toxicity.

The peripheral blood results were tabulated as described for PCEs in the rat bone marrow micronucleus test. Results of the 3-month studies were accepted without repeat tests, because additional test data could not be obtained.

## E.4 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.5 Results

Indole-3-carbinol was tested in three independent bacterial mutagenicity studies, and results were varied. The first study, which employed S. typhimurium strains TA97, TA98, TA100, TA1535, and TA1537 and used a concentration range of 3.3 to 3,333 μg indole-3-carbinol/plate with and without 10% or 30% rat or hamster liver S9, yielded results that were judged to be equivocal in TA97 in the absence of S9 (Table E-1). A second study, using strains TA97, TA98, TA100, TA102, TA104, TA1535, and TA1537, and concentrations ranging from 33 to 10,000 μg/plate, yielded weak positive responses in strain TA100 without and with 30% hamster liver S9 (no mutagenicity was seen in this strain in the presence of other concentrations or species of S9) (Table E-1). Results of the third study were judged to be equivocal in S. typhimurium strain TA100 (concentration range 500 to 5,000 μg/plate) in the presence of 10% rat liver S9 and in E. coli strain WP2 uvrA/pKM101 (concentration range of 500 to 7,500 μg/plate) in the absence of S9 activation; no mutagenic activity was seen in this assay in S. typhimurium strain TA98, with or without S9, tested up to 5,000 μg/plate (Table E-2).

In vivo, no increase in the frequency of micronucleated PCEs was seen in the bone marrow of male F344/N rats given three doses of indole-3-carbinol (500 to 2,000 mg/kg per day) via gavage; however, a significant decrease in the percent PCEs was seen in the bone marrow of treated rats, indicating that indole-3-carbinol was toxic to the bone marrow (Table E-3). In addition to the rat study, micronucleus frequencies in NCEs of male and female B6C3F1/N mice were assessed in peripheral blood following 3 months of daily gavage treatment with indole-3-carbinol (15.6 to 250 mg/kg per day) in corn oil; no significant increases in micronucleated NCEs were seen in either sex, and no significant changes in percent PCEs occurred over the dose range tested (Table E-4).

Table E-1 Mutagenicity of Indole-3-carbinol in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9 | With 10% Rat S9
Study 1
TA100 | 0 | 98 ± 4 | 122 ± 10 | 122 ± 6 | 87 ± 3 | 117 ± 14 | 158 ± 9
| 3.3 | | 118 ± 7
| 33 | 92 ± 6 | 109 ± 6 | 121 ± 9 | 85 ± 5 | 138 ± 8
| 100 | 111 ± 10 | 127 ± 2 | 122 ± 5 | 90 ± 1 | 141 ± 3 | 163 ± 11
| 333 | 107 ± 9 | 151 ± 9 | 147 ± 4 | 80 ± 7 | 177 ± 4 | 172 ± 3
| 1,000 | 98 ± 12 | 163 ± 12 | 122 ± 17 | 80 ± 8 | 206 ± 17 | 162 ± 20
| 1,500 | | | | | | 139 ± 19
| 2,000 | 34 ± 4^b^ | | 86 ± 13^b^ | | 148 ± 5 | 74 ± 7
| 3,333 | | | | 63 ± 8^b^
Trial summary | | Negative | Negative | Negative | Negative | Equivocal | Negative
Positive control | | 218 ± 12 | 327 ± 9 | 813 ± 96 | 231 ± 46 | 854 ± 30 | 635 ± 34
| Dose (μg/plate) | With 30% Rat S9
TA100 (continued) | 0 | 84 ± 3
| 33 | 81 ± 7
| 100 | 76 ± 9
| 333 | 76 ± 4
| 1,000 | 80 ± 6^b^
| 3,333 | 38 ± 4^b^
Trial summary | | Negative
Positive control | | 208 ± 10
| Dose (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 30% Hamster S9
TA97 | 0 | 197 ± 10 | 94 ± 11 | 134 ± 9 | 164 ± 6 | 123 ± 4 | 130 ± 20
| 3.3 | | | 109 ± 14
| 33 | 187 ± 13 | 92 ± 1 | 118 ± 4 | 177 ± 12 | | 109 ± 4
| 100 | 203 ± 10 | 99 ± 5 | 108 ± 5 | 98 ± 13 | 119 ± 7 | 109 ± 5
| 333 | 249 ± 1 | 106 ± 2 | 155 ± 1 | 147 ± 7 | 103 ± 6 | 99 ± 15
| 667 | | 119 ± 10
| 1,000 | 203 ± 6 | 101 ± 11 | 159 ± 4 | 185 ± 14 | 109 ± 14 | 109 ± 8
| 2,000 | 0^d^ | | | 202 ± 14 | 58 ± 10 | 123 ± 10
| 2,500 | | | | | 0^b^
Trial summary | | Equivocal | Equivocal | Negative | Equivocal | Negative | Negative
Positive control | | 740 ± 78 | 214 ± 24 | 328 ± 6 | 958 ± 82 | 1,265 ± 30 | 536 ± 40
| Dose (μg/plate) | With 10% Rat S9 | With 10% Rat S9 | With 30% Rat S9
TA97 (continued) | 0 | 158 ± 10 | 125 ± 9 | 160 ± 11
| 33 | 116 ± 10 | | 156 ± 8
| 100 | 166 ± 7 | 116 ± 4 | 160 ± 8
| 333 | 170 ± 21 | 111 ± 7 | 145 ± 8
| 1,000 | 193 ± 1 | 101 ± 11 | 96 ± 7
| 1,500 | | 94 ± 7
| 2,000 | 122 ± 15 | 68 ± 5 | 115 ± 6
Trial summary | | Equivocal | Negative | Negative
Positive control | | 1,443 ± 199 | 1,135 ± 37 | 324 ± 35
| Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9 | With 30% Rat S9
TA98 | 0 | 26 ± 1 | 15 ± 1 | 24 ± 3 | 19 ± 2 | 21 ± 3 | 24 ± 2
| 3.3 | | 18 ± 0
| 33 | 21 ± 3 | 20 ± 3 | 28 ± 2 | 22 ± 1 | 23 ± 3 | 22 ± 2
| 100 | 21 ± 2 | 17 ± 3 | 25 ± 4 | 17 ± 3 | 25 ± 2 | 24 ± 4
| 333 | 24 ± 3 | 19 ± 0 | 24 ± 4 | 21 ± 2 | 30 ± 3 | 21 ± 2
| 1,000 | 14 ± 2 | 18 ± 2 | 24 ± 3 | 21 ± 4 | 26 ± 1 | 25 ± 3
| 2,000 | 13 ± 2 | | 16 ± 2^b^ | | 12 ± 1^b^
| 3,333 | | | | 14 ± 2^b^ | | 14 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 68 ± 5 | 90 ± 5 | 751 ± 22 | 55 ± 2 | 457 ± 66 | 82 ± 13
TA1535 | 0 | 15 ± 1 | 15 ± 3 | 16 ± 2 | 18 ± 1 | 13 ± 0 | 19 ± 1
| 3.3 | | 19 ± 1
| 33 | 19 ± 3 | 17 ± 2 | 11 ± 2 | 19 ± 3 | 18 ± 0 | 20 ± 3
| 100 | 23 ± 4 | 20 ± 4 | 14 ± 3 | 17 ± 2 | 12 ± 2 | 12 ± 3
| 333 | 18 ± 2 | 19 ± 2 | 13 ± 3 | 10 ± 3 | 12 ± 1 | 12 ± 2
| 1,000 | 19 ± 3 | 18 ± 0 | 12 ± 4 | 13 ± 1 | 14 ± 4 | 10 ± 2
| 2,000 | Toxic | | 10 ± 1 | | 9 ± 1
| 3,333 | | | | 4 ± 2^e^ | | 0^e^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 531 ± 92 | 364 ± 34 | 80 ± 13 | 210 ± 11 | 355 ± 60 | 79 ± 5
| Dose (μg/plate) | Without S9
TA1537 | 0 | 5 ± 0
| 33 | 8 ± 3
| 100 | 5 ± 2
| 333 | 4 ± 1
| 1,000 | 7 ± 1
| 1,500 | 3 ± 2^b^
Trial summary | | Negative
Positive control | | 13 ± 1
| Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9
Study 2
TA102 | 0 | 277 ± 27 | 366 ± 5 | 347 ± 22 | 358 ± 9 | 281 ± 11 | 348 ± 11
| 33 | 270 ± 28 | 378 ± 6 | 429 ± 22 | 357 ± 10 | | 436 ± 24
| 100 | 262 ± 8 | 362 ± 6 | 421 ± 14 | 397 ± 31 | 291 ± 21 | 405 ± 33
| 333 | 280 ± 25 | 345 ± 14 | 394 ± 11 | 389 ± 23 | 295 ± 13 | 416 ± 49
| 1,000 | 185 ± 10 | 255 ± 50 | 333 ± 7 | 434 ± 25 | 220 ± 12 | 320 ± 18
| 1,500 | | | | | 217 ± 11
| 3,333 | 30 ± 3^d^ | 84 ± 5^d^ | 82 ± 30^d^ | 167 ± 32^e^ | 96 ± 9^e^ | 40 ± 7^d^
Trial summary | | Negative | Negative | Negative | Equivocal | Negative | Negative
Positive control | | 875 ± 17 | 1,435 ± 32 | 1,849 ± 123 | 1,383 ± 22 | 1,503 ± 46 | 1,714 ± 98
| Dose (μg/plate) | With 30% Rat S9 | With 30% Rat S9
TA102 (continued) | 0 | 340 ± 21 | 233 ± 14
| 33 | 370 ± 22
| 100 | 408 ± 11 | 203 ± 6
| 333 | 388 ± 8 | 224 ± 4
| 1,000 | 422 ± 19 | 148 ± 12
| 1,500 | | 115 ± 6
| 3,333 | 163 ± 30^e^ | 102 ± 8^e^
Trial summary | | Equivocal | Negative
Positive control | | 1,107 ± 66 | 1,529 ± 46
| Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9 | With 30% Rat S9
TA104 | 0 | 222 ± 11 | 207 ± 2 | 249 ± 18 | 225 ± 8 | 206 ± 13 | 221 ± 7
| 33 | 205 ± 9 | 122 ± 18 | 187 ± 7 | 180 ± 21 | 184 ± 7 | 219 ± 13
| 100 | 213 ± 6 | 163 ± 11 | 216 ± 19 | 181 ± 10 | 204 ± 17 | 244 ± 17
| 333 | 180 ± 19 | 147 ± 14 | 175 ± 19 | 183 ± 19 | 204 ± 15 | 207 ± 3
| 1,000 | 185 ± 14 | 89 ± 3 | 208 ± 23 | 213 ± 2 | 181 ± 9 | 237 ± 22
| 3,333 | 0^d^ | 47 ± 11^d^ | 205 ± 5^d^ | 38 ± 1^d^ | 207 ± 26^d^ | 46 ± 3^d^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 705 ± 14 | 624 ± 6 | 1,080 ± 34 | 1,112 ± 36 | 1,173 ± 17 | 744 ± 61
| Dose (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 30% Hamster S9
TA100 | 0 | 90 ± 0 | 104 ± 8 | 149 ± 7 | 174 ± 7 | 139 ± 9 | 97 ± 10
| 33 | 76 ± 10 | 120 ± 5 | 141 ± 11 | 180 ± 16 | 146 ± 7 | 89 ± 4
| 100 | 114 ± 5 | 122 ± 7 | 161 ± 7 | 185 ± 4 | 138 ± 10 | 105 ± 6
| 333 | 123 ± 7 | 144 ± 4 | 196 ± 23 | 213 ± 4 | 170 ± 5 | 144 ± 10
| 1,000 | 133 ± 19 | 199 ± 7 | 166 ± 3 | 229 ± 20 | 183 ± 6 | 156 ± 5
| 1,200 | | 183 ± 9
| 1,500 | 46 ± 44^b^ | | | | 130 ± 9^e^ | 149 ± 18
| 3,333 | | | 0^d^ | 0^d^
Trial summary | | Weakly Positive | Weakly Positive | Negative | Negative | Negative | Weakly Positive
Positive control | | 225 ± 20 | 432 ± 47 | 594 ± 33 | 1,428 ± 58 | 845 ± 79 | 296 ± 25
| Dose (μg/plate) | With 30% Hamster S9 | With 10% Rat S9 | With 10% Rat S9 | With 30% Rat S9
TA100 (continued) | 0 | 102 ± 2 | 163 ± 2 | 121 ± 16 | 101 ± 6
| 33 | 104 ± 2 | 200 ± 6 | 141 ± 16 | 105 ± 3
| 100 | 106 ± 2 | 181 ± 6 | 120 ± 7 | 94 ± 11
| 333 | 132 ± 11 | 217 ± 14 | 178 ± 15 | 107 ± 11
| 1,000 | 157 ± 16 | 239 ± 26 | 158 ± 16 | 124 ± 10
| 1,200 | 191 ± 8
| 1,500 | | | 132 ± 9^e^ | 79 ± 4^e^
| 3,333 | | 0^d^
Trial summary | | Weakly Positive | Equivocal | Negative | Negative
Positive control | | 956 ± 35 | 1,259 ± 205 | 595 ± 37 | 357 ± 27
| Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9
TA97 | 0 | 114 ± 2 | 156 ± 15 | 186 ± 29 | 151 ± 11 | 132 ± 6 | 201 ± 12
| 33 | 110 ± 9 | 148 ± 9 | 203 ± 13 | 149 ± 6 | | 184 ± 19
| 100 | 107 ± 8 | 167 ± 9 | 211 ± 5 | 157 ± 8 | 159 ± 8 | 168 ± 2
| 333 | 126 ± 4 | 151 ± 6 | 229 ± 32 | 148 ± 12 | 160 ± 9 | 160 ± 4
| 1,000 | 133 ± 4 | 168 ± 10 | 208 ± 17 | 162 ± 9 | 185 ± 6 | 211 ± 10
| 1,500 | 108 ± 12^e^ | | | 210 ± 6^e^ | 194 ± 12
| 2,000 | | | | | 124 ± 13
| 3,333 | | 0^d^ | 0^d^ | | | 0^d^
Trial summary | | Negative | Negative | Negative | Equivocal | Equivocal | Negative
Positive control | | 394 ± 2 | 476 ± 32 | 1,320 ± 31 | 1,680 ± 75 | 1,458 ± 59 | 1,671 ± 307
| Dose (μg/plate) | With 30% Rat S9 | With 30% Rat S9
TA97 (continued) | 0 | 151 ± 3 | 145 ± 8
| 33 | 143 ± 2
| 100 | 142 ± 8 | 132 ± 2
| 333 | 146 ± 6 | 164 ± 11
| 1,000 | 177 ± 5 | 167 ± 8
| 1,500 | 193 ± 12^e^ | 175 ± 20
| 2,000 | | 95 ± 11
Trial summary | | Equivocal | Equivocal
Positive control | | 553 ± 16 | 463 ± 15
| Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9 | With 30% Rat S9
TA98 | 0 | 15 ± 2 | 18 ± 3 | 18 ± 5 | 17 ± 1 | 21 ± 3 | 19 ± 2
| 33 | 13 ± 3 | 15 ± 1 | 21 ± 4 | 11 ± 1 | 18 ± 2 | 11 ± 1
| 100 | 13 ± 1 | 16 ± 2 | 21 ± 5 | 17 ± 4 | 21 ± 2 | 13 ± 1
| 333 | 13 ± 1 | 14 ± 3 | 21 ± 6 | 12 ± 1 | 27 ± 4 | 19 ± 1
| 1,000 | 10 ± 2 | 9 ± 2 | 18 ± 3 | 13 ± 2 | 20 ± 1 | 17 ± 5
| 1,500 | 0^b^ | | | 6 ± 1 | | 9 ± 2^b^
| 3,333 | | 0^d^ | 0^d^ | | 0^d^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 115 ± 2 | 100 ± 7 | 1,536 ± 136 | 246 ± 8 | 629 ± 141 | 129 ± 18
| Dose (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 30% Hamster S9
TA1535 | 0 | 14 ± 2 | 14 ± 1 | 18 ± 2 | 14 ± 1 | 10 ± 1 | 13 ± 1
| 33 | 13 ± 2 | | 18 ± 3 | 13 ± 1 | 13 ± 0
| 100 | 14 ± 1 | | 19 ± 3 | 14 ± 1 | 10 ± 1
| 333 | 13 ± 1 | 15 ± 2 | 20 ± 1 | 13 ± 1 | 13 ± 1 | 12 ± 2
| 1,000 | 15 ± 1 | 10 ± 1 | 18 ± 2 | 13 ± 1 | 13 ± 1 | 12 ± 1
| 1,200 | 12 ± 1 | | | | 14 ± 3
| 1,500 | | 8 ± 0 | | | | 9 ± 1
| 3,333 | | 0^d^ | 0^d^ | 0^d^ | | 2^d^
| 10,000 | | 0^d^ | | | | 0^d^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 130 ± 5 | 166 ± 4 | 256 ± 39 | 287 ± 24 | 66 ± 3 | 155 ± 23
| Dose (μg/plate) | With 10% Rat S9 | With 30% Rat S9
TA1535 (continued) | 0 | 15 ± 0 | 13 ± 3
| 33 | 14 ± 2 | 12 ± 1
| 100 | 17 ± 3 | 10^f^
| 333 | 15 ± 1 | 18 ± 2
| 1,000 | 12 ± 2 | 12 ± 1
| 1,500 | | 8 ± 2^e^
| 3,333 | 0^d^
Trial summary | | Negative | Negative
Positive control | | 422 ± 19 | 95 ± 6
| Dose (μg/plate) | With 30% Hamster S9 | With 30% Rat S9
TA1537 | 0 | 9 ± 2 | 9 ± 2
| 100 | 8 ± 1 | 7 ± 1
| 333 | 8 ± 1 | 10 ± 1
| 1,000 | 9 ± 2 | 8 ± 1
| 1,500 | 5 ± 1 | 5 ± 1
| 2,000 | 4 ± 1^e^ | 5 ± 1^e^
Trial summary | | Negative | Negative
Positive control | | 530 ± 58 | 143 ± 22

^a^ Studies were performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^135^. 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97 and TA1537), 4-nitro-o-phenylenediamine (TA98), mitomycin-C (TA102), and methyl methanesulfonate (TA104). The positive control for metabolic activation with all strains was 2-aminoanthracene, except 2-aminoanthracene or sterigmatocystin was used for TA102.

^d^ Slight toxicity and precipitate on plate.

^e^ Precipitate on plate.

^f^ Contamination.

Table E-2 Mutagenicity of Indole-3-carbinol in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9 | With 10% Rat S9
TA100 | 0 | 44 ± 3 | 103 ± 7 | 81 ± 4 | 80 ± 2 | 61 ± 3 | 94 ± 2
| 100 | | 109 ± 4 | 90 ± 0
| 500 | 63 ± 2 | 124 ± 6 | 129 ± 1 | 109 ± 4 | 84 ± 2 | 126 ± 5
| 1,500 | 47 ± 1 | 60 ± 8 | 75 ± 3 | 142 ± 13 | 84 ± 3 | 174 ± 4
| 2,500 | 32 ± 1 | 20 ± 1^b^ | 26 ± 2 | 74 ± 1 | 84 ± 6 | 123 ± 5
| 3,500 | 9 ± 1^b^ | Toxic | 12 ± 3^b^ | 45 ± 5 | 44 ± 8^c^ | 23 ± 3^b^
| 5,000 | Toxic | | | 6 ± 3^b^ | 26 ± 8^c^ | 5^c^
Trial summary | | Negative | Negative | Negative | Equivocal | Negative | Equivocal
Positive control^d^ | | 420 ± 24 | 844 ± 95 | 737 ± 40 | 1,108 ± 18 | 831 ± 93 | 1,086 ± 2
TA98 | 0 | 24 ± 1 | 21 ± 1 | 16 ± 2 | 30 ± 2 | 34 ± 2 | 25 ± 4
| 100 | 21 ± 4 | | 24 ± 1
| 500 | 17 ± 2 | 24 ± 1 | 20 ± 1 | 30 ± 1 | 37 ± 1 | 27 ± 4
| 1,500 | 11 ± 2 | 23 ± 1 | 9 ± 1 | 30 ± 2 | 27 ± 2 | 19 ± 3
| 2,500 | 4 ± 1^b^ | 15 ± 1 | 6 ± 1^b^ | 27 ± 2 | 17 ± 4 | 9 ± 2
| 3,500 | Toxic | Toxic | Toxic | 11 ± 1^b^ | 11 ± 0 | 3 ± 1^b^
| 5,000 | | Toxic | | 7 ± 1^b^ | 3 ± 1^c^ | Toxic
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 441 ± 43 | 654 ± 17 | 411 ± 41 | 1,533 ± 29 | 787 ± 4 | 787 ± 91
Escherichia coli WP2 uvrA/pKM101 (Analogous to TA102)
| 0 | 136 ± 5 | 164 ± 20 | 188 ± 4 | 185 ± 4 | 188 ± 6 | 225 ± 15
| 500 | 193 ± 5 | 204 ± 7 | 241 ± 5
| 1,500 | 218 ± 8 | 212 ± 5 | 279 ± 11 | 238 ± 9 | 261 ± 3 | 248 ± 10
| 2,500 | 194 ± 10 | 199 ± 9 | 234 ± 11 | 217 ± 1 | 235 ± 9 | 355 ± 2
| 3,500 | 139 ± 9 | 111 ± 2 | 173 ± 9 | 194 ± 6 | 178 ± 9 | 342 ± 2
| 5,000 | 87 ± 8 | 59 ± 4^b^ | 128 ± 9^c^ | 184 ± 6 | 115 ± 5 | 98 ± 3^b^
| 7,500 | Toxic | Toxic | | 104 ± 9 | 63 ± 5^b^ | 242 ± 1^c^
| 10,000 | | | | 65 ± 12^b^ | Toxic
Trial summary | | Equivocal | Negative | Equivocal | Negative | Negative | Equivocal
Positive control | | 1,992 ± 81 | 2,139 ± 53 | 1,810 ± 66 | 1,144 ± 12 | 1,080 ± 17 | 1,298 ± 51

^a^ Study was performed at SITEK Research Laboratories using the same lot of indole-3-carbinol (CHP801001) used in the 3-month and 2-year bioassays and a modification of the protocol presented by Zeiger et al.^135^. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ Precipitate on plate.

^d^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-3 Induction of Micronuclei in Bone Marrow Polychromatic Erythrocytes of Male F344/N Rats Following Treatment with Indole-3-carbinol by Gavage for Three Days^a^

| Dose (mg/kg) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | PCEs^b^ (%)
Corn oil^d^ | 0 | 5 | 1.00 ± 0.22 | | 51.100 ± 3.98
Indole-3-carbinol | 500 | 5 | 1.22 ± 0.33 | 0.3227 | 27.560 ± 8.24
| 1,000 | 3 | 1.33 ± 0.17 | 0.2713 | 41.500 ± 2.50
| 2,000 | 4 | 0.83 ± 0.38 | 0.6306 | 27.375 ± 8.30
| | | P = 0.611^e^
Cyclophosphamide^f^ | 25 | 4 | 26.17 ± 5.17 | 0.0000 | 7.075 ± 2.21

^a^ Study was performed at ILS, Inc., using a protocol similar to that presented by Shelby et al.^119^; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.008; positive control values are significant at P ≤ 0.05.

^d^ Vehicle control.

^e^ Significance of micronucleated PCEs/1,000 PCEs tested by the one-tailed trend test; significant at P ≤ 0.025.

^f^ Positive control.

Table E-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with Indole-3-carbinol by Gavage for Three Months^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Corn oil^d^ | 0 | 5 | 2.10 ± 0.19 | | 3.62 ± 0.31
Indole-3-carbinol | 15.6 | 5 | 1.50 ± 0.27 | 0.8416 | 3.68 ± 0.16
| 31.25 | 5 | 1.80 ± 0.25 | 0.6847 | 3.74 ± 0.29
| 62.5 | 5 | 2.00 ± 0.35 | 0.5621 | 3.84 ± 0.29
| 125 | 5 | 1.90 ± 0.29 | 0.6242 | 3.84 ± 0.28
| 250 | 5 | 1.60 ± 0.33 | 0.7947 | 3.52 ± 0.34
| | | P = 0.663^e^
Female
Corn oil | 0 | 5 | 1.10 ± 0.37 | | 3.18 ± 0.23
Indole-3-carbinol | 15.6 | 5 | 1.40 ± 0.19 | 0.2741 | 2.60 ± 0.49
| 31.25 | 5 | 1.60 ± 0.29 | 0.1678 | 3.78 ± 0.52
| 62.5 | 5 | 1.60 ± 0.33 | 0.1678 | 3.24 ± 0.41
| 125 | 5 | 1.80 ± 0.34 | 0.0967 | 3.40 ± 0.29
| 250 | 5 | 1.90 ± 0.33 | 0.0719 | 3.12 ± 0.19
| | | P = 0.087

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^136^; NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.005.

^d^ Vehicle control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.