# Appendix D Summary of Lesions in Female Mice in the Two-year Gavage Study of Indole-3-carbinol

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | 1 | – | – | –
Moribund | 10 | 6 | 15 | 3
Natural deaths | 6 | 4 | 9 | 2
Survivors
Died last week of study | – | – | 1 | –
Terminal euthanasia | 33 | 40 | 25 | 45
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Squamous cell carcinoma | – | – | 1 (2%) | –
Gallbladder | (49) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, intestine small, jejunum | 1 (2%) | – | – | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Leiomyosarcoma | 1 (2%) | – | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Leiomyosarcoma | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Hemangiosarcoma, multiple | – | – | 1 (2%) | –
Hepatoblastoma | – | – | 1 (2%) | 1 (2%)
Hepatocellular adenoma | 7 (14%) | 11 (22%) | 6 (12%) | 7 (14%)
Hepatocellular adenoma, multiple | – | 3 (6%) | 2 (4%) | 4 (8%)
Hepatocellular carcinoma | 6 (12%) | 6 (12%) | 8 (16%) | 4 (8%)
Hepatocellular carcinoma, multiple | – | 2 (4%) | 1 (2%) | –
Mesentery | (3) | (7) | (7) | (6)
Carcinoma, metastatic, kidney | – | 1 (14%) | – | –
Hemangioma | – | – | 1 (14%) | –
Pancreas | (50) | (50) | (50) | (50)
Salivary glands | (50) | (49) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | 1 (2%) | – | – | –
Stomach, glandular | (48) | (50) | (49) | (50)
Tongue | (0) | (0) | (0) | (1)
Squamous cell papilloma | – | – | – | 1 (100%)
Tooth | (6) | (9) | (9) | (11)
Cardiovascular System
Blood vessel | (48) | (50) | (50) | (50)
Hemangioma | 1 (2%) | – | – | –
Heart | (50) | (50) | (50) | (50)
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Subcapsular, adenoma | 1 (2%) | – | – | –
Adrenal medulla | (49) | (50) | (50) | (50)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Carcinoma | – | – | 1 (2%) | –
Parathyroid gland | (43) | (48) | (49) | (46)
Pituitary gland | (49) | (50) | (50) | (49)
Pars distalis, adenoma | 3 (6%) | 4 (8%) | – | 1 (2%)
Pars intermedia, adenoma | 1 (2%) | – | – | –
Thyroid gland | (50) | (50) | (49) | (50)
C-cell, carcinoma | 1 (2%) | – | – | –
Follicular cell, adenoma | 1 (2%) | – | – | 1 (2%)
General Body System
Tissue NOS | (0) | (0) | (1) | (0)
Genital System
Clitoral gland | (49) | (50) | (50) | (50)
Ovary | (50) | (50) | (50) | (50)
Cystadenoma | 1 (2%) | 4 (8%) | 1 (2%) | 4 (8%)
Hemangioma | – | – | – | 1 (2%)
Bilateral, tubulostromal adenoma | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Carcinoma | – | 1 (2%) | – | –
Polyp stromal | – | – | – | 4 (8%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (9) | (5) | (6) | (1)
Lymph node, mandibular | (50) | (49) | (50) | (50)
Lymph node, mesenteric | (49) | (49) | (49) | (49)
Hemangiosarcoma | – | – | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Thymus | (49) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Squamous cell carcinoma | – | – | 1 (2%) | –
Subcutaneous tissue, fibrosarcoma | – | – | 2 (4%) | –
Subcutaneous tissue, hemangioma | – | – | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma, multiple | – | – | 1 (2%) | –
Subcutaneous tissue, sarcoma | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (0) | (1) | (2) | (0)
Fibrosarcoma | – | – | 1 (50%) | –
Rhabdomyosarcoma | – | – | 1 (50%) | –
Schwannoma malignant | – | 1 (100%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Meningioma benign | – | 1 (2%) | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 1 (2%) | 1 (2%) | 3 (6%) | 2 (4%)
Alveolar/bronchiolar carcinoma | 2 (4%) | 2 (4%) | 3 (6%) | –
Alveolar/bronchiolar carcinoma, multiple | – | 1 (2%) | – | –
Carcinoma, metastatic, harderian gland | – | 1 (2%) | – | –
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | 2 (4%) | 2 (4%) | 2 (4%) | –
Squamous cell carcinoma, metastatic, skin | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (2) | (0) | (0) | (0)
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | 3 (6%) | 7 (14%) | 7 (14%) | –
Carcinoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Bilateral, renal tubule, carcinoma | – | 1 (2%) | – | –
Renal tubule, carcinoma, multiple | – | – | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | – | – | 1 (2%)
Lymphoma malignant | 6 (12%) | 9 (18%) | 6 (12%) | 3 (6%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 30 | 32 | 36 | 26
Total primary neoplasms | 42 | 56 | 50 | 37
Total animals with benign neoplasms | 17 | 21 | 17 | 20
Total benign neoplasms | 22 | 32 | 20 | 26
Total animals with malignant neoplasms | 19 | 19 | 26 | 9
Total malignant neoplasms | 20 | 24 | 30 | 11
Total animals with metastatic neoplasms | 4 | 4 | 4 | –
Total metastatic neoplasms | 4 | 4 | 4 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Harderian Gland: Adenoma
Overall rate^a^ | 3/50 (6%) | 7/50 (14%) | 7/50 (14%) | 0/50 (0%)
Adjusted rate^b^ | 6.6% | 15.0% | 16.6% | 0.0%
Terminal rate^c^ | 3/33 (9%) | 5/40 (13%) | 5/26 (19%) | 0/45 (0%)
First incidence (days) | 729 (T) | 681 | 381 | –^e^
Poly-3 test^d^ | P = 0.072N | P = 0.170 | P = 0.128 | P = 0.111N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 8/50 (16%) | 8/50 (16%) | 1/50 (2%)
Adjusted rate | 6.6% | 17.1% | 19.0% | 2.1%
Terminal rate | 3/33 (9%) | 6/40 (15%) | 6/26 (23%) | 0/45 (0%)
First incidence (days) | 729 (T) | 681 | 381 | 603
Poly-3 test | P = 0.134N | P = 0.108 | P = 0.076 | P = 0.286N
Liver: Hepatocellular Adenoma
Overall rate | 7/50 (14%) | 14/50 (28%) | 8/50 (16%) | 11/50 (22%)
Adjusted rate | 15.2% | 30.0% | 19.5% | 22.9%
Terminal rate | 5/33 (15%) | 13/40 (33%) | 7/26 (27%) | 10/45 (22%)
First incidence (days) | 568 | 687 | 621 | 603
Poly-3 test | P = 0.390 | P = 0.071 | P = 0.405 | P = 0.247
Liver: Hepatocellular Carcinoma
Overall rate | 6/50 (12%) | 8/50 (16%) | 9/50 (18%) | 4/50 (8%)
Adjusted rate | 13.2% | 17.1% | 21.5% | 8.4%
Terminal rate | 5/33 (15%) | 7/40 (18%) | 5/26 (19%) | 4/45 (9%)
First incidence (days) | 709 | 650 | 606 | 729 (T)
Poly-3 test | P = 0.246N | P = 0.409 | P = 0.228 | P = 0.341N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 12/50 (24%) | 19/50 (38%) | 16/50 (32%) | 14/50 (28%)
Adjusted rate | 26.1% | 40.5% | 37.9% | 29.2%
Terminal rate | 10/33 (30%) | 17/40 (43%) | 11/26 (42%) | 13/45 (29%)
First incidence (days) | 568 | 650 | 606 | 603
Poly-3 test | P = 0.503N | P = 0.103 | P = 0.165 | P = 0.460
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 6/50 (12%) | 8/50 (16%) | 10/50 (20%) | 4/50 (8%)
Adjusted rate | 13.2% | 17.1% | 23.9% | 8.4%
Terminal rate | 5/33 (15%) | 7/40 (18%) | 6/26 (23%) | 4/45 (9%)
First incidence (days) | 709 | 650 | 606 | 729 (T)
Poly-3 test | P = 0.257N | P = 0.409 | P = 0.154 | P = 0.341N
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 12/50 (24%) | 19/50 (38%) | 17/50 (34%) | 14/50 (28%)
Adjusted rate | 26.1% | 40.5% | 40.3% | 29.2%
Terminal rate | 10/33 (30%) | 17/40 (43%) | 12/26 (46%) | 13/45 (29%)
First incidence (days) | 568 | 650 | 606 | 603
Poly-3 test | P = 0.511N | P = 0.103 | P = 0.113 | P = 0.460
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 2.2% | 2.2% | 7.3% | 4.2%
Terminal rate | 0/33 (0%) | 1/40 (3%) | 2/26 (8%) | 2/45 (4%)
First incidence (days) | 634 | 729 (T) | 639 | 729 (T)
Poly-3 test | P = 0.343 | P = 0.757N | P = 0.267 | P = 0.514
Lung: Alveolar/Bronchiolar Carcinoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 4.4% | 6.5% | 7.2% | 0.0%
Terminal rate | 2/33 (6%) | 3/40 (8%) | 0/26 (0%) | 0/45 (0%)
First incidence (days) | 729 (T) | 729 (T) | 526 | –
Poly-3 test | P = 0.151N | P = 0.511 | P = 0.463 | P = 0.227N
Lung: Alveolar/Bronchiolar Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 6/50 (12%) | 2/50 (4%)
Adjusted rate | 6.6% | 8.6% | 14.2% | 4.2%
Terminal rate | 2/33 (6%) | 4/40 (10%) | 2/26 (8%) | 2/45 (4%)
First incidence (days) | 634 | 729 (T) | 526 | 729 (T)
Poly-3 test | P = 0.385N | P = 0.509 | P = 0.203 | P = 0.482N
Ovary: Cystadenoma
Overall rate | 1/50 (2%) | 4/50 (8%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 2.2% | 8.6% | 2.4% | 8.4%
Terminal rate | 0/33 (0%) | 4/40 (10%) | 0/26 (0%) | 4/45 (9%)
First incidence (days) | 695 | 729 (T) | 638 | 729 (T)
Poly-3 test | P = 0.232 | P = 0.185 | P = 0.737 | P = 0.193
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 3/49 (6%) | 4/50 (8%) | 0/50 (0%) | 1/49 (2%)
Adjusted rate | 6.8% | 8.6% | 0.0% | 2.2%
Terminal rate | 3/32 (9%) | 4/40 (10%) | 0/26 (0%) | 1/44 (2%)
First incidence (days) | 729 (T) | 729 (T) | – | 729 (T)
Poly-3 test | P = 0.108N | P = 0.525 | P = 0.135N | P = 0.288N
Uterus: Stromal Polyp
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 8.4%
Terminal rate | 0/33 (0%) | 0/40 (0%) | 0/26 (0%) | 4/45 (9%)
First incidence (days) | – | – | – | 729 (T)
Poly-3 test | P = 0.003 | –^f^ | – | P = 0.067
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 2.2% | 0.0% | 7.2% | 4.2%
Terminal rate | 0/33 (0%) | 0/40 (0%) | 0/26 (0%) | 2/45 (4%)
First incidence (days) | 709 | – | 621 | 729 (T)
Poly-3 test | P = 0.258 | P = 0.496N | P = 0.274 | P = 0.516
All Organs: Malignant Lymphoma
Overall rate | 6/50 (12%) | 9/50 (18%) | 6/50 (12%) | 3/50 (6%)
Adjusted rate | 12.9% | 18.9% | 14.4% | 6.3%
Terminal rate | 0/33 (0%) | 6/40 (15%) | 3/26 (12%) | 3/45 (7%)
First incidence (days) | 634 | 558 | 597 | 729 (T)
Poly-3 test | P = 0.116N | P = 0.301 | P = 0.540 | P = 0.233N
All Organs: Benign Neoplasms
Overall rate | 17/50 (34%) | 21/50 (42%) | 17/50 (34%) | 20/50 (40%)
Adjusted rate | 36.5% | 44.8% | 39.1% | 41.7%
Terminal rate | 12/33 (36%) | 18/40 (45%) | 11/26 (42%) | 19/45 (42%)
First incidence (days) | 568 | 681 | 381 | 603
Poly-3 test | P = 0.427 | P = 0.274 | P = 0.485 | P = 0.382
All Organs: Malignant Neoplasms
Overall rate | 19/50 (38%) | 19/50 (38%) | 26/50 (52%) | 9/50 (18%)
Adjusted rate | 39.4% | 39.6% | 56.5% | 18.3%
Terminal rate | 8/33 (24%) | 14/40 (35%) | 10/26 (39%) | 6/45 (13%)
First incidence (days) | 569 | 558 | 526 | 491
Poly-3 test | P = 0.015N | P = 0.576 | P = 0.070 | P = 0.017N
All Organs: Benign or Malignant Neoplasms
Overall rate | 30/50 (60%) | 32/50 (64%) | 36/50 (72%) | 26/50 (52%)
Adjusted rate | 61.5% | 66.2% | 75.2% | 52.8%
Terminal rate | 18/33 (55%) | 25/40 (63%) | 17/26 (65%) | 23/45 (51%)
First incidence (days) | 568 | 558 | 381 | 491
Poly-3 test | P = 0.182N | P = 0.393 | P = 0.105 | P = 0.252N

(T) Terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table D-3 Historical Incidence of Liver Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatoblastoma
Historical Incidence: Corn Oil Gavage Studies
Ginkgo biloba extract (March 2005) | 17/50 | 9/50 | 1/50
Indole-3-carbinol (April 2007) | 7/50 | 6/50 | 0/50
Kava kava extract (August 2004) | 8/50 | 3/50 | 0/50
N,N-Dimethyl-p-toluidine (October 2004) | 17/50 | 6/50 | 0/50
Tetrabromobisphenol A (August 2007) | 13/50 | 2/50 | 0/50
Total (%) | 62/250 (24.8%) | 26/250 (10.4%) | 1/250 (0.4%)
Mean ± standard deviation | 24.8% ± 9.6% | 10.4% ± 5.6% | 0.4% ± 0.9%
Range | 14%–34% | 4%–18% | 0%–2%
Overall Historical Incidence: All Routes
Total (%) | 378/948 (39.9%) | 152/948 (16.0%) | 4/948 (0.4%)
Mean ± standard deviation | 39.9% ± 18.7% | 16.0% ± 10.6% | 0.4% ± 0.8%
Range | 14%–78% | 4%–46% | 0%–2%

^a^ Data as of June 2013.

Table D-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | 1 | – | – | –
Moribund | 10 | 6 | 15 | 3
Natural deaths | 6 | 4 | 9 | 2
Survivors
Died last week of study | – | – | 1 | –
Terminal euthanasia | 33 | 40 | 25 | 45
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (49) | (50) | (50) | (50)
Cyst | – | 1 (2%) | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Ulcer | 1 (2%) | – | – | –
Epithelium, hyperplasia | 1 (2%) | – | – | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Ulcer | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Basophilic focus | 4 (8%) | 6 (12%) | 7 (14%) | 5 (10%)
Clear cell focus | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Eosinophilic focus | 16 (32%) | 26 (52%) | 26 (52%) | 21 (42%)
Fatty change | 36 (72%) | 39 (78%) | 35 (70%) | 40 (80%)
Hematopoietic cell proliferation | 2 (4%) | – | – | –
Hemorrhage | – | 2 (4%) | – | –
Hepatodiaphragmatic nodule | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Inflammation, chronic | – | 1 (2%) | – | –
Mixed cell focus | 2 (4%) | 4 (8%) | 5 (10%) | 1 (2%)
Necrosis | 1 (2%) | 1 (2%) | 1 (2%) | –
Bile duct, cyst | – | 1 (2%) | – | –
Centrilobular, necrosis | – | – | 1 (2%) | –
Mesentery | (3) | (7) | (7) | (6)
Fat, necrosis | 3 (100%) | 6 (86%) | 7 (100%) | 5 (83%)
Pancreas | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Inflammation, chronic | 1 (2%) | 1 (2%) | – | –
Acinus, atrophy | – | – | – | 1 (2%)
Acinus, hyperplasia | 1 (2%) | 2 (4%) | 1 (2%) | –
Duct, cyst | 1 (2%) | – | – | –
Salivary glands | (50) | (49) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | –
Duct, cyst | – | – | – | 1 (2%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation, chronic | 1 (2%) | – | – | –
Ulcer | 9 (18%) | 4 (8%) | 8 (16%) | 3 (6%)
Epithelium, hyperplasia | – | – | 1 (2%) | –
Stomach, glandular | (48) | (50) | (49) | (50)
Erosion | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Inflammation, chronic | – | 15 (30%) | 29 (59%) | 47 (94%)
Mineralization | 2 (4%) | – | 3 (6%) | –
Pigmentation | – | 15 (30%) | 31 (63%) | 49 (98%)
Epithelium, hyperplasia | 1 (2%) | 7 (14%) | 10 (20%) | 35 (70%)
Tongue | (0) | (0) | (0) | (1)
Tooth | (6) | (9) | (9) | (11)
Dysplasia | 6 (100%) | 9 (100%) | 9 (100%) | 10 (91%)
Cardiovascular System
Blood vessel | (48) | (50) | (50) | (50)
Mineralization | – | – | 1 (2%) | –
Aorta, inflammation, chronic | – | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 4 (8%) | 3 (6%) | 1 (2%) | 2 (4%)
Inflammation, chronic | – | 1 (2%) | – | –
Artery, inflammation, chronic | – | – | 1 (2%) | 1 (2%)
Myocardium, mineralization | 2 (4%) | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (49) | (50) | (50) | (50)
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | 1 (2%) | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Necrosis | – | 1 (2%) | – | 1 (2%)
Vacuolization cytoplasmic | 1 (2%) | 1 (2%) | 1 (2%) | –
Adrenal medulla | (49) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | 3 (6%) | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 5 (10%) | 1 (2%) | 4 (8%) | 1 (2%)
Parathyroid gland | (43) | (48) | (49) | (46)
Pituitary gland | (49) | (50) | (50) | (49)
Cyst | – | 2 (4%) | – | –
Pars distalis, hyperplasia | 5 (10%) | 18 (36%) | 6 (12%) | 4 (8%)
Pars distalis, vacuolization cytoplasmic | – | – | – | 1 (2%)
Pars intermedia, hyperplasia | 1 (2%) | – | – | –
Thyroid gland | (50) | (50) | (49) | (50)
Inflammation, chronic | – | – | 1 (2%) | –
Follicle, hyperplasia | | – | – | 1 (2%)
General Body System
Tissue NOS | (0) | (0) | (1) | (0)
Inflammation, chronic | – | – | 1 (100%) | –
Genital System
Clitoral gland | (49) | (50) | (50) | (50)
Ovary | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | 1 (2%)
Cyst | 16 (32%) | 15 (30%) | 9 (18%) | 8 (16%)
Inflammation, chronic | 1 (2%) | – | 1 (2%) | –
Mineralization | – | – | 1 (2%) | –
Thrombosis | 2 (4%) | – | 2 (4%) | 2 (4%)
Uterus | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | 1 (2%) | – | –
Inflammation, chronic | – | 4 (8%) | – | –
Metaplasia, squamous | – | – | 1 (2%) | –
Necrosis | 1 (2%) | – | – | –
Endometrium, hyperplasia, cystic | 36 (72%) | 32 (64%) | 30 (60%) | 34 (68%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (9) | (5) | (6) | (1)
Lumbar, ectasia | 1 (11%) | – | – | –
Lumbar, hemorrhage | – | – | 1 (17%) | –
Renal, ectasia | 2 (22%) | 1 (20%) | 2 (33%) | –
Lymph node, mandibular | (50) | (49) | (50) | (50)
Lymph node, mesenteric | (49) | (49) | (49) | (49)
Spleen | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Hematopoietic cell proliferation | 30 (60%) | 30 (60%) | 27 (54%) | 23 (46%)
Hyperplasia, granulocytic | – | – | 1 (2%) | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Hyperplasia, mast cell | – | – | – | 1 (2%)
Pigmentation, hemosiderin | 1 (2%) | – | – | –
Lymphoid follicle, atrophy | – | 1 (2%) | – | –
Lymphoid follicle, hyperplasia | 2 (4%) | – | – | –
Thymus | (49) | (50) | (50) | (50)
Atrophy | 42 (86%) | 40 (80%) | 40 (80%) | 41 (82%)
Hyperplasia | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Inflammation, chronic | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Ulcer | 1 (2%) | – | 1 (2%) | –
Subcutaneous tissue, fibrosis | 1 (2%) | – | – | –
Subcutaneous tissue, hemorrhage | – | – | – | 1 (2%)
Subcutaneous tissue, inflammation, chronic | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 9 (18%) | 13 (26%) | 11 (22%) | 17 (34%)
Fracture | 1 (2%) | – | – | –
Skeletal muscle | (0) | (1) | (2) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Hemorrhage | 1 (2%) | – | – | –
Inflammation, granulomatous | – | – | – | 1 (2%)
Hypothalamus, compression | 2 (4%) | – | – | –
Meninges, inflammation, chronic | – | 1 (2%) | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Hemorrhage | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Inflammation, chronic | – | 1 (2%) | – | –
Metaplasia, osseous | – | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | –
Alveolar epithelium, hyperplasia | 1 (2%) | 2 (4%) | 1 (2%) | 2 (4%)
Alveolus, infiltration cellular, histiocyte | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Mediastinum, inflammation, chronic | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Foreign body | – | – | 1 (2%) | 2 (4%)
Inflammation | 4 (8%) | 1 (2%) | 8 (16%) | 39 (78%)
Nerve, atrophy | – | – | 1 (2%) | 50 (100%)
Nerve, olfactory epithelium, atrophy | 1 (2%) | 1 (2%) | – | –
Olfactory epithelium, accumulation, hyaline droplet | 18 (36%) | 27 (54%) | 21 (42%) | 44 (88%)
Olfactory epithelium, atrophy | 1 (2%) | 2 (4%) | 3 (6%) | 45 (90%)
Olfactory epithelium, degeneration | – | – | 2 (4%) | 3 (6%)
Olfactory epithelium, necrosis | – | – | 2 (4%) | –
Olfactory epithelium, respiratory metaplasia | 7 (14%) | 8 (16%) | 16 (32%) | 49 (98%)
Respiratory epithelium, accumulation, hyaline droplet | 47 (94%) | 38 (76%) | 42 (84%) | 50 (100%)
Respiratory epithelium, hyperplasia | 32 (64%) | 31 (62%) | 38 (76%) | 50 (100%)
Respiratory epithelium, metaplasia, squamous | 1 (2%) | – | – | –
Respiratory epithelium, necrosis | 2 (4%) | – | 1 (2%) | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (2) | (0) | (0) | (0)
Eye | (50) | (50) | (50) | (50)
Cornea, inflammation, chronic | 1 (2%) | – | 1 (2%) | 1 (2%)
Lens, cataract | – | 1 (2%) | 1 (2%) | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Dilatation | – | – | – | 6 (12%)
Hyperplasia | 2 (4%) | 3 (6%) | 5 (10%) | 9 (18%)
Infiltration cellular, mononuclear cell | 24 (48%) | 18 (36%) | 8 (16%) | 22 (44%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Infarct | 3 (6%) | – | 1 (2%) | –
Metaplasia, osseous | – | – | – | 1 (2%)
Mineralization | 4 (8%) | 3 (6%) | 4 (8%) | –
Nephropathy | 24 (48%) | 25 (50%) | 19 (38%) | 20 (40%)
Artery, inflammation, chronic | – | – | – | 1 (2%)
Renal tubule, accumulation, hyaline droplet | – | – | – | 1 (2%)
Renal tubule, cyst | – | – | 1 (2%) | 1 (2%)
Renal tubule, pigmentation | 1 (2%) | – | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Infiltration cellular, mononuclear cell | 3 (6%) | – | – | –
Transitional epithelium, hyperplasia | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.