# Appendix C Summary of Lesions in Male Mice in the Two-year Gavage Study of Indole-3-carbinol

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | – | – | 1 | 1
Moribund | 17 | 12 | 11 | 9
Natural deaths | 6 | 7 | 6 | 8
Survivors
Died last week of study | 1 | – | – | –
Terminal euthanasia | 26 | 31 | 32 | 32
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (50) | (50) | (49) | (48)
Carcinoma, metastatic, pancreas | – | – | 1 (2%) | –
Squamous cell carcinoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | – | – | 1 (2%)
Carcinoma | – | – | – | 2 (4%)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (49) | (50)
Adenoma | 1 (2%) | – | 1 (2%) | –
Liver | (50) | (50) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Carcinoma, metastatic, intestine small, duodenum | – | – | – | 1 (2%)
Fibrous histiocytoma | – | 1 (2%) | – | –
Hemangioma | – | – | – | 1 (2%)
Hemangiosarcoma | 3 (6%) | 2 (4%) | 1 (2%) | 2 (4%)
Hemangiosarcoma, multiple | 1 (2%) | 2 (4%) | – | 1 (2%)
Hepatoblastoma | 3 (6%) | 3 (6%) | 1 (2%) | 7 (14%)
Hepatoblastoma, multiple | – | 1 (2%) | 3 (6%) | 7 (14%)
Hepatocellular adenoma | 11 (22%) | 7 (14%) | 15 (31%) | 8 (16%)
Hepatocellular adenoma, multiple | 15 (30%) | 25 (50%) | 16 (33%) | 33 (66%)
Hepatocellular carcinoma | 7 (14%) | 8 (16%) | 11 (22%) | 6 (12%)
Hepatocellular carcinoma, multiple | 5 (10%) | 3 (6%) | 18 (37%) | 8 (16%)
Hepatocholangiocarcinoma | – | 3 (6%) | 1 (2%) | –
Hepatocholangioma | – | – | – | 1 (2%)
Squamous cell carcinoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Mesentery | (7) | (3) | (2) | (2)
Fibrosarcoma | – | 1 (33%) | – | –
Hepatoblastoma, metastatic, liver | – | 1 (33%) | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (14%) | – | – | –
Leiomyosarcoma, metastatic, stomach, forestomach | – | 1 (33%) | – | –
Squamous cell carcinoma, metastatic, stomach, forestomach | 1 (14%) | – | – | –
Oral mucosa | (0) | (1) | (0) | (2)
Pancreas | (50) | (50) | (50) | (50)
Carcinoma | – | – | 1 (2%) | –
Hemangioma | – | 1 (2%) | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Leiomyosarcoma, metastatic, stomach, glandular | – | 1 (2%) | – | –
Squamous cell carcinoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Hemangiosarcoma | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell carcinoma | 1 (2%) | – | – | –
Squamous cell papilloma | 1 (2%) | 1 (2%) | 1 (2%) | –
Squamous cell papilloma, multiple | – | 1 (2%) | – | –
Stomach, glandular | (50) | (47) | (47) | (49)
Carcinoma | – | – | 1 (2%) | –
Carcinoma, metastatic, intestine small, duodenum | – | – | – | 1 (2%)
Carcinoma, metastatic, pancreas | – | – | 1 (2%) | –
Leiomyosarcoma | | 1 (2%) | – | –
Tooth | (30) | (37) | (32) | (32)
Cardiovascular System
Blood vessel | (49) | (50) | (49) | (49)
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Hemangiosarcoma | – | 1 (2%) | – | –
Endocrine system
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | – | – | 2 (4%) | –
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | 1 (2%)
Parathyroid gland | (48) | (44) | (48) | (44)
Pituitary gland | (50) | (50) | (50) | (50)
Pars intermedia, adenoma | – | 1 (2%) | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, adenoma | – | 1 (2%) | – | 1 (2%)
Follicular cell, adenoma | – | – | 1 (2%) | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Coagulating gland | (1) | (0) | (0) | (0)
Epididymis | (50) | (50) | (50) | (50)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Leiomyosarcoma, metastatic, stomach, glandular | – | 1 (2%) | – | –
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Squamous cell carcinoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50)
Bilateral, interstitial cell, adenoma | – | – | – | 1 (2%)
Interstitial cell, adenoma | – | 1 (2%) | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | 1 (2%) | 1 (2%) | –
Lymph node | (2) | (2) | (0) | (4)
Lymph node, mandibular | (50) | (50) | (50) | (50)
Lymph node, mesenteric | (48) | (48) | (49) | (50)
Hemangiosarcoma | – | 1 (2%) | – | –
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Thymus | (49) | (47) | (46) | (45)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (2%) | –
Squamous cell carcinoma, metastatic, stomach, forestomach | 1 (2%) | – | – | –
Thymoma benign | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (2) | (0) | (0) | (0)
Skin | (50) | (50) | (50) | (50)
Epidermis, keratoacanthoma | – | – | 1 (2%) | –
Subcutaneous tissue, fibrosarcoma | 1 (2%) | 1 (2%) | – | –
Subcutaneous tissue, hemangiosarcoma | – | 2 (4%) | 1 (2%) | –
Subcutaneous tissue, lipoma | – | – | – | 1 (2%)
Subcutaneous tissue, neural crest tumor | – | – | 1 (2%) | –
Subcutaneous tissue, schwannoma malignant | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (0) | (0) | (2) | (0)
Hemangiosarcoma | – | – | 2 (100%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Granular cell tumor benign | 1 (2%) | – | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 4 (8%) | 6 (12%) | 6 (12%) | 8 (16%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | 2 (4%) | –
Alveolar/bronchiolar carcinoma | 3 (6%) | 7 (14%) | 5 (10%) | 4 (8%)
Alveolar/bronchiolar carcinoma, multiple | 1 (2%) | – | – | 1 (2%)
Carcinoma, metastatic, harderian gland | – | – | – | 1 (2%)
Hepatoblastoma, metastatic, liver | – | 1 (2%) | 1 (2%) | 2 (4%)
Hepatocellular carcinoma, metastatic, liver | 6 (12%) | 3 (6%) | 10 (20%) | 4 (8%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | 6 (12%) | 6 (12%) | 7 (14%) | 3 (6%)
Carcinoma | 1 (2%) | 1 (2%) | – | 1 (2%)
Bilateral, adenoma | – | 1 (2%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Urethra | (0) | (1) | (0) | (0)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 2 (4%) | 1 (2%) | – | 1 (2%)
Lymphoma malignant | 3 (6%) | 1 (2%) | 1 (2%) | 5 (10%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 48 | 45 | 48 | 48
Total primary neoplasms | 78 | 95 | 103 | 107
Total animals with benign neoplasms | 33 | 40 | 39 | 42
Total benign neoplasms | 44 | 53 | 53 | 61
Total animals with malignant neoplasms | 27 | 26 | 36 | 35
Total malignant neoplasms | 34 | 42 | 49 | 46
Total animals with metastatic neoplasms | 7 | 7 | 10 | 9
Total metastatic neoplasms | 16 | 13 | 14 | 11
Total animals with uncertain neoplasms— benign or malignant | – | – | 1 | –
Total uncertain neoplasms | – | – | 1 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Harderian Gland: Adenoma
Overall rate^a^ | 6/50 (12%) | 7/50 (14%) | 7/50 (14%) | 3/50 (6%)
Adjusted rate^b^ | 14.5% | 15.4% | 15.6% | 6.7%
Terminal rate^c^ | 2/26 (8%) | 5/31 (16%) | 4/32 (13%) | 1/32 (3%)
First incidence (days) | 463 | 616 | 437 | 437
Poly-3 test^d^ | P = 0.144N | P = 0.571 | P = 0.564 | P = 0.205N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 8/50 (16%) | 7/50 (14%) | 4/50 (8%)
Adjusted rate | 16.7% | 17.6% | 15.6% | 9.0%
Terminal rate | 2/26 (8%) | 5/31 (16%) | 4/32 (13%) | 2/32 (6%)
First incidence (days) | 463 | 616 | 437 | 437
Poly-3 test | P = 0.152N | P = 0.568 | P = 0.560N | P = 0.226N
Liver: Hemangiosarcoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 1/49 (2%) | 3/50 (6%)
Adjusted rate | 10.0% | 8.8% | 2.3% | 6.8%
Terminal rate | 2/26 (8%) | 1/31 (3%) | 0/32 (0%) | 0/32 (0%)
First incidence (days) | 626 | 630 | 596 | 495
Poly-3 test | P = 0.321N | P = 0.571N | P = 0.155N | P = 0.445N
Liver: Hepatocellular Adenoma
Overall rate | 26/50 (52%) | 32/50 (64%) | 31/49 (63%) | 41/50 (82%)
Adjusted rate | 62.1% | 66.5% | 67.9% | 85.4%
Terminal rate | 19/26 (73%) | 21/31 (68%) | 23/32 (72%) | 28/32 (88%)
First incidence (days) | 463 | 381 | 437 | 385
Poly-3 test | P = 0.005 | P = 0.411 | P = 0.360 | P = 0.006
Liver: Hepatocellular Carcinoma
Overall rate | 12/50 (24%) | 11/50 (22%) | 29/49 (59%) | 14/50 (28%)
Adjusted rate | 27.7% | 24.2% | 63.4% | 30.9%
Terminal rate | 3/26 (12%) | 8/31 (26%) | 18/32 (56%) | 8/32 (25%)
First incidence (days) | 465 | 682 | 567 | 385
Poly-3 test | P = 0.217 | P = 0.449N | P < 0.001 | P = 0.461
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 35/50 (70%) | 36/50 (72%) | 43/49 (88%) | 44/50 (88%)
Adjusted rate | 77.6% | 74.6% | 90.6% | 91.1%
Terminal rate | 21/26 (81%) | 24/31 (77%) | 29/32 (91%) | 30/32 (94%)
First incidence (days) | 463 | 381 | 437 | 385
Poly-3 test | P = 0.012 | P = 0.459N | P = 0.062 | P = 0.049
Liver: Hepatoblastoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 4/49 (8%) | 14/50 (28%)
Adjusted rate | 7.6% | 8.9% | 9.3% | 31.6%
Terminal rate | 3/26 (12%) | 4/31 (13%) | 3/32 (9%) | 10/32 (31%)
First incidence (days) | 730 (T) | 730 (T) | 702 | 617
Poly-3 test | P < 0.001 | P = 0.567 | P = 0.543 | P = 0.005
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 15/50 (30%) | 13/50 (26%) | 30/49 (61%) | 25/50 (50%)
Adjusted rate | 34.6% | 28.7% | 65.6% | 54.5%
Terminal rate | 6/26 (23%) | 10/31 (32%) | 19/32 (59%) | 17/32 (53%)
First incidence (days) | 465 | 682 | 567 | 385
Poly-3 test | P = 0.005 | P = 0.353N | P = 0.002 | P = 0.042
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 36/50 (72%) | 36/50 (72%) | 44/49 (90%) | 45/50 (90%)
Adjusted rate | 79.8% | 74.6% | 92.7% | 92.8%
Terminal rate | 22/26 (85%) | 24/31 (77%) | 30/32 (94%) | 30/32 (94%)
First incidence (days) | 463 | 381 | 437 | 385
Poly-3 test | P = 0.007 | P = 0.354N | P = 0.050 | P = 0.044
Liver: Hepatocholangiocarcinoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 1/49 (2%) | 0/50 (0%)
Adjusted rate | 0.0% | 6.6% | 2.3% | 0.0%
Terminal rate | 0/26 (0%) | 0/31 (0%) | 1/32 (3%) | 0/32 (0%)
First incidence (days) | –^e^ | 630 | 730 (T) | –
Poly-3 test | P = 0.319N | P = 0.146 | P = 0.515 | –^f^
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 4/50 (8%) | 7/50 (14%) | 8/50 (16%) | 8/50 (16%)
Adjusted rate | 10.1% | 15.4% | 17.8% | 17.9%
Terminal rate | 4/26 (15%) | 5/31 (16%) | 4/32 (13%) | 5/32 (16%)
First incidence (days) | 730 (T) | 631 | 437 | 495
Poly-3 test | P = 0.230 | P = 0.342 | P = 0.241 | P = 0.238
Lung: Alveolar/Bronchiolar Carcinoma
Overall rate | 4/50 (8%) | 7/50 (14%) | 5/50 (10%) | 5/50 (10%)
Adjusted rate | 10.0% | 15.4% | 11.4% | 11.4%
Terminal rate | 3/26 (12%) | 4/31 (13%) | 3/32 (9%) | 4/32 (13%)
First incidence (days) | 680 | 682 | 655 | 586
Poly-3 test | P = 0.523N | P = 0.337 | P = 0.561 | P = 0.560
Lung: Alveolar/Bronchiolar Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 12/50 (24%) | 13/50 (26%) | 11/50 (22%)
Adjusted rate | 20.0% | 26.2% | 28.6% | 24.6%
Terminal rate | 7/26 (27%) | 7/31 (23%) | 7/32 (22%) | 8/32 (25%)
First incidence (days) | 680 | 631 | 437 | 495
Poly-3 test | P = 0.420 | P = 0.338 | P = 0.252 | P = 0.405
Small Intestine (Site Unspecified): Adenoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 7.5% | 0.0% | 2.3% | 2.3%
Terminal rate | 2/26 (8%) | 0/31 (0%) | 1/32 (3%) | 1/32 (3%)
First incidence (days) | 728 | – | 730 (T) | 730 (T)
Poly-3 test | P = 0.308N | P = 0.098N | P = 0.273N | P = 0.274N
Small Intestine (Site Unspecified): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 7.5% | 0.0% | 2.3% | 6.9%
Terminal rate | 2/26 (8%) | 0/31 (0%) | 1/32 (3%) | 3/32 (9%)
First incidence (days) | 728 | – | 730 (T) | 730 (T)
Poly-3 test | P = 0.415 | P = 0.098N | P = 0.273N | P = 0.621N
All Organs: Hemangiosarcoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 5/50 (10%) | 3/50 (6%)
Adjusted rate | 10.0% | 10.9% | 11.1% | 6.8%
Terminal rate | 2/26 (8%) | 1/31 (3%) | 1/32 (3%) | 0/32 (0%)
First incidence (days) | 626 | 630 | 596 | 495
Poly-3 test | P = 0.337N | P = 0.581 | P = 0.570 | P = 0.445N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 4/50 (8%) | 6/50 (12%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate | 10.0% | 13.1% | 11.1% | 9.0%
Terminal rate | 2/26 (8%) | 2/31 (7%) | 1/32 (3%) | 1/32 (3%)
First incidence (days) | 626 | 630 | 596 | 495
Poly-3 test | P = 0.430N | P = 0.454 | P = 0.570 | P = 0.588N
All Organs: Malignant Lymphoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 5/50 (10%)
Adjusted rate | 7.5% | 2.2% | 2.3% | 11.3%
Terminal rate | 1/26 (4%) | 0/31 (0%) | 1/32 (3%) | 3/32 (9%)
First incidence (days) | 711 | 673 | 730 (T) | 631
Poly-3 test | P = 0.164 | P = 0.262N | P = 0.273N | P = 0.413
All Organs: Benign Neoplasms
Overall rate | 33/50 (66%) | 40/50 (80%) | 39/50 (78%) | 42/50 (84%)
Adjusted rate | 77.2% | 81.8% | 82.8% | 86.1%
Terminal rate | 23/26 (89%) | 26/31 (84%) | 28/32 (88%) | 28/32 (88%)
First incidence (days) | 463 | 381 | 437 | 385
Poly-3 test | P = 0.166 | P = 0.381 | P = 0.331 | P = 0.182
All Organs: Malignant Neoplasms
Overall rate | 27/50 (54%) | 26/50 (52%) | 36/50 (72%) | 35/50 (70%)
Adjusted rate | 58.2% | 54.5% | 75.4% | 73.8%
Terminal rate | 10/26 (39%) | 13/31 (42%) | 21/32 (66%) | 23/32 (72%)
First incidence (days) | 465 | 381 | 567 | 385
Poly-3 test | P = 0.022 | P = 0.437N | P = 0.055 | P = 0.078
All Organs: Benign or Malignant Neoplasms
Overall rate | 48/50 (96%) | 45/50 (90%) | 48/50 (96%) | 48/50 (96%)
Adjusted rate | 98.5% | 90.9% | 98.0% | 96.8%
Terminal rate | 26/26 (100%) | 28/31 (90%) | 31/32 (97%) | 31/32 (97%)
First incidence (days) | 463 | 381 | 437 | 385
Poly-3 test | P = 0.509 | P = 0.098N | P = 0.735N | P = 0.552N

(T) Terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table C-3 Historical Incidence of Liver Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatocellular Adenoma or Hepatocellular Carcinoma | Hepatoblastoma
Historical Incidence: Corn Oil Gavage Studies
Ginkgo biloba extract (March 2005) | 31/50 | 22/50 | 39/50 | 3/50
Indole-3-carbinol (April 2007) | 26/50 | 12/50 | 35/50 | 3/50
Kava kava extract (August 2004) | 27/50 | 20/50 | 38/50 | 0/50
N,N-Dimethyl-p-toluidine (October 2004) | 29/50 | 22/50 | 38/50 | 1/50
Tetrabromobisphenol A (August 2007) | 32/50 | 11/50 | 39/50 | 2/50
Total (%) | 145/250 (58.0%) | 87/250 (34.8%) | 189/250 (75.6%) | 9/250 (3.6%)
Mean ± standard deviation | 58.0% ± 5.1% | 34.8% ± 10.9% | 75.6% ± 3.3% | 3.6% ± 2.6%
Range | 52%–64% | 22%–44% | 70%–78% | 0%–6%
Overall Historical Incidence: All Routes
Total (%) | 594/949 (62.6%) | 348/949 (36.7%) | 742/949 (78.2%) | 40/949 (4.2%)
Mean ± standard deviation | 62.6% ± 9.1% | 36.7% ± 11.4% | 78.2% ± 7.2% | 4.2% ± 3.5%
Range | 48%–78% | 22%–56% | 64%–90% | 0%–12%
| | Hepatocellular Carcinoma or Hepatoblastoma | Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma | Hepatocholangio-carcinoma
Historical Incidence: Corn Oil Gavage Studies
Ginkgo biloba extract (March 2005) | | 24/50 | 39/50 | 0/50
Indole-3-carbinol (April 2007) | | 15/50 | 36/50 | 0/50
Kava kava extract (August 2004) | | 20/50 | 38/50 | 4/50
N,N-Dimethyl-p-toluidine (October 2004) | | 22/50 | 38/50 | 0/50
Tetrabromobisphenol A (August 2007) | | 12/50 | 39/50 | 0/50
Total (%) | | 93/250 (37.2%) | 190/250 (76.0%) | 4/250 (1.6%)
Mean ± standard deviation | | 37.2% ± 10.0% | 76.0% ± 2.5% | 1.6% ± 3.6%
Range | | 24%–48% | 72%–78% | 0%–8%
Overall Historical Incidence: All Routes
Total (%) | | 371/949 (39.1%) | 746/949 (78.6%) | 10/949 (1.1%)
Mean ± standard deviation | | 39.1% ± 11.6% | 78.6% ± 7.2% | 1.1% ± 2.2%
Range | | 22%–58% | 64%–90% | 0%–8%

^a^ Data as of June 2013.

Table C-4 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | – | – | 1 | 1
Moribund | 17 | 12 | 11 | 9
Natural deaths | 6 | 7 | 6 | 8
Survivors
Died last week of study | 1 | – | – | –
Terminal euthanasia | 26 | 31 | 32 | 32
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Mineralization | – | – | 1 (2%) | –
Gallbladder | (50) | (50) | (49) | (48)
Atrophy | – | – | – | 1 (2%)
Inflammation, suppurative | – | – | – | 1 (2%)
Intestine large, cecum | (50) | (50) | (50) | (50)
Ulcer | – | 1 (2%) | – | 1 (2%)
Intestine large, colon | (50) | (50) | (50) | (50)
Inflammation, chronic | – | – | – | 1 (2%)
Intestine large, rectum | (50) | (50) | (50) | (50)
Inflammation, chronic | – | 1 (2%) | – | –
Intestine small, duodenum | (50) | (50) | (50) | (50)
Ulcer | – | – | – | 1 (2%)
Epithelium, atrophy | – | – | – | 1 (2%)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (49) | (50)
Atrophy | 1 (2%) | – | – | –
Inflammation, suppurative | 1 (2%) | – | – | –
Lymphangiectasis | 1 (2%) | – | – | –
Peyer’s patch, hyperplasia | – | 1 (2%) | 1 (2%) | 1 (2%)
Liver | (50) | (50) | (49) | (50)
Basophilic focus | 2 (4%) | 4 (8%) | 2 (4%) | 5 (10%)
Clear cell focus | 7 (14%) | 17 (34%) | 22 (45%) | 20 (40%)
Eosinophilic focus | 29 (58%) | 35 (70%) | 35 (71%) | 33 (66%)
Fatty change | 29 (58%) | 27 (54%) | 28 (57%) | 37 (74%)
Hepatodiaphragmatic nodule | – | 1 (2%) | – | 1 (2%)
Inflammation, chronic | – | – | – | 1 (2%)
Mixed cell focus | 1 (2%) | 6 (12%) | 6 (12%) | 5 (10%)
Necrosis | 3 (6%) | 2 (4%) | 2 (4%) | 2 (4%)
Necrosis, multifocal | 1 (2%) | – | – | –
Artery, thrombosis | – | – | – | 1 (2%)
Bile duct, hyperplasia | – | – | – | 1 (2%)
Oval cell, hyperplasia | – | – | – | 1 (2%)
Periportal, fibrosis | – | – | – | 1 (2%)
Mesentery | (7) | (3) | (2) | (2)
Fat, necrosis | 4 (57%) | – | 2 (100%) | 2 (100%)
Oral mucosa | (0) | (1) | (0) | (2)
Pancreas | (50) | (50) | (50) | (50)
Inflammation, chronic | – | – | – | 2 (4%)
Acinus, atrophy | 1 (2%) | – | 1 (2%) | –
Duct, cyst | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Infiltration cellular, mononuclear cell | 23 (46%) | 30 (60%) | 27 (54%) | 22 (44%)
Duct, sublingual gland, hyperplasia | – | – | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation, chronic | – | 1 (2%) | 4 (8%) | 1 (2%)
Ulcer | 6 (12%) | 5 (10%) | 7 (14%) | 1 (2%)
Epithelium, hyperplasia | 2 (4%) | 2 (4%) | 4 (8%) | 2 (4%)
Stomach, glandular | (50) | (47) | (47) | (49)
Erosion | 1 (2%) | – | – | –
Inflammation, chronic | 1 (2%) | 1 (2%) | 18 (38%) | 45 (92%)
Mineralization | 5 (10%) | 2 (4%) | – | –
Pigmentation | – | 1 (2%) | 38 (81%) | 48 (98%)
Epithelium, atrophy | – | – | – | 1 (2%)
Epithelium, hyperplasia | – | 1 (2%) | 22 (47%) | 40 (82%)
Tooth | (30) | (37) | (32) | (32)
Dysplasia | 30 (100%) | 36 (97%) | 32 (100%) | 32 (100%)
Cardiovascular System
Blood vessel | (49) | (50) | (49) | (49)
Adventitia, pulmonary vein, infiltration cellular, polymorphonuclear | 1 (2%) | – | – | –
Aorta, mineralization | – | 1 (2%) | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 11 (22%) | 7 (14%) | 18 (36%) | 8 (16%)
Inflammation, chronic | 1 (2%) | – | – | –
Artery, inflammation, chronic | 1 (2%) | – | – | –
Artery, mineralization | – | 1 (2%) | – | –
Myocardium, mineralization | – | 3 (6%) | – | 1 (2%)
Valve, inflammation | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | 1 (2%)
Hypertrophy | – | 4 (8%) | 2 (4%) | –
Vacuolization cytoplasmic | – | 2 (4%) | – | –
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | – | 1 (2%) | 2 (4%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | 1 (2%) | –
Parathyroid gland | (48) | (44) | (48) | (44)
Pituitary gland | (50) | (50) | (50) | (50)
Cyst | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Pars intermedia, hyperplasia | – | 1 (2%) | – | –
Thyroid gland | (50) | (50) | (50) | (50)
Inflammation, chronic | – | – | – | 1 (2%)
Follicle, cyst | 1 (2%) | – | – | –
Follicle, degeneration | – | – | – | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Coagulating gland | (1) | (0) | (0) | (0)
Epididymis | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)
Granuloma sperm | – | – | – | 1 (2%)
Infiltration cellular, mononuclear cell | 1 (2%) | 6 (12%) | 3 (6%) | 5 (10%)
Inflammation, chronic | – | 2 (4%) | – | –
Preputial gland | (50) | (50) | (50) | (50)
Cyst | 14 (28%) | 10 (20%) | 6 (12%) | 6 (12%)
Inflammation, suppurative | 2 (4%) | – | – | –
Inflammation, granulomatous | – | 2 (4%) | – | 2 (4%)
Prostate | (50) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | – | 1 (2%) | 1 (2%)
Inflammation, suppurative | – | – | 1 (2%) | –
Inflammation, chronic | 1 (2%) | – | – | 1 (2%)
Seminal vesicle | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Testes | (50) | (50) | (50) | (50)
Inflammation, granulomatous | 1 (2%) | – | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Mineralization | 1 (2%) | – | – | –
Germinal epithelium, atrophy | 2 (4%) | – | 3 (6%) | 3 (6%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (2) | (2) | (0) | (4)
Mediastinal, hyperplasia | – | – | – | 1 (25%)
Pancreatic, inflammation | – | – | – | 1 (25%)
Pancreatic, necrosis | – | 1 (50%) | – | –
Renal, inflammation | – | – | – | 1 (25%)
Lymph node, mandibular | (50) | (50) | (50) | (50)
Hyperplasia, lymphoid | – | 1 (2%) | – | 1 (2%)
Lymph node, mesenteric | (48) | (48) | (49) | (50)
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hyperplasia, lymphoid | – | – | – | 2 (4%)
Inflammation | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Accessory spleen | – | – | 1 (2%) | –
Atrophy | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 16 (32%) | 16 (32%) | 24 (48%) | 20 (40%)
Necrosis | 1 (2%) | – | – | –
Lymphoid follicle, atrophy | 2 (4%) | – | – | –
Thymus | (49) | (47) | (46) | (45)
Atrophy | 44 (90%) | 44 (94%) | 45 (98%) | 39 (87%)
Ectopic parathyroid gland | – | 1 (2%) | – | 1 (2%)
Integumentary System
Mammary gland | (2) | (0) | (0) | (0)
Skin | (50) | (50) | (50) | (50)
Ulcer | 3 (6%) | 2 (4%) | 3 (6%) | 1 (2%)
Subcutaneous tissue, inflammation, acute | – | – | 1 (2%) | –
Subcutaneous tissue, inflammation, chronic | – | – | 2 (4%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hyperostosis | – | – | 1 (2%) | 1 (2%)
Skeletal muscle | (0) | (0) | (2) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Meninges, inflammation, chronic | – | 1 (2%) | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Infiltration cellular, histiocyte | – | 2 (4%) | – | 1 (2%)
Inflammation, chronic | – | 1 (2%) | 1 (2%) | 1 (2%)
Pigmentation, hemosiderin | – | 1 (2%) | – | –
Thrombosis | – | – | 1 (2%) | –
Alveolar epithelium, hyperplasia | 3 (6%) | 4 (8%) | 5 (10%) | –
Mediastinum, inflammation, granulomatous | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Foreign body | 3 (6%) | 1 (2%) | – | 3 (6%)
Inflammation | 15 (30%) | 11 (22%) | 12 (24%) | 16 (32%)
Polyp, inflammatory | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Respiratory metaplasia | – | – | 1 (2%) | –
Nerve, atrophy | – | – | – | 8 (16%)
Nerve, olfactory epithelium, atrophy | – | 1 (2%) | – | –
Olfactory epithelium, accumulation, hyaline droplet | 4 (8%) | 4 (8%) | 5 (10%) | 5 (10%)
Olfactory epithelium, atrophy | 3 (6%) | 5 (10%) | 11 (22%) | 17 (34%)
Olfactory epithelium, degeneration | 1 (2%) | 1 (2%) | 4 (8%) | 2 (4%)
Olfactory epithelium, metaplasia, squamous | – | – | – | 2 (4%)
Olfactory epithelium, necrosis | – | – | – | 6 (12%)
Olfactory epithelium, respiratory metaplasia | 14 (28%) | 14 (28%) | 20 (40%) | 27 (54%)
Respiratory epithelium, accumulation, hyaline droplet | 18 (36%) | 34 (68%) | 30 (60%) | 26 (52%)
Respiratory epithelium, hyperplasia | 35 (70%) | 40 (80%) | 41 (82%) | 45 (90%)
Respiratory epithelium, metaplasia, squamous | – | – | – | 1 (2%)
Respiratory epithelium, necrosis | – | – | – | 2 (4%)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Phthisis bulbi | 1 (2%) | 1 (2%) | – | –
Anterior chamber, inflammation, suppurative | – | 1 (2%) | – | 1 (2%)
Cornea, inflammation, suppurative | – | 1 (2%) | – | –
Cornea, inflammation, chronic | 2 (4%) | 3 (6%) | 2 (4%) | 1 (2%)
Optic nerve, infiltration cellular, mononuclear cell | – | – | – | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 4 (8%) | 5 (10%) | 3 (6%)
Inflammation, suppurative | 1 (2%) | 1 (2%) | – | –
Inflammation, chronic | – | 1 (2%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Infarct | 3 (6%) | 2 (4%) | – | –
Inflammation, acute | – | 2 (4%) | – | –
Inflammation, chronic | 1 (2%) | – | – | 1 (2%)
Metaplasia, osseous | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Mineralization | 4 (8%) | 8 (16%) | 1 (2%) | 2 (4%)
Nephropathy | 42 (84%) | 50 (100%) | 45 (90%) | 43 (86%)
Thrombosis | – | 1 (2%) | – | –
Papilla, necrosis | 1 (2%) | – | – | 1 (2%)
Pelvis, inflammation, suppurative | 2 (4%) | 2 (4%) | 1 (2%) | –
Renal tubule, cyst | 1 (2%) | 3 (6%) | 2 (4%) | 2 (4%)
Renal tubule, hyperplasia | – | – | 1 (2%) | –
Renal tubule, pigmentation | 1 (2%) | 1 (2%) | 1 (2%) | 5 (10%)
Renal tubule, vacuolization cytoplasmic | 1 (2%) | – | – | –
Urethra | (0) | (1) | (0) | (0)
Inflammation, acute | – | 1 (100%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Hemorrhage | – | 1 (2%) | – | –
Inflammation, chronic | 1 (2%) | 2 (4%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.