# Appendix B Summary of Lesions in Female Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

Table B-1 Summary of the Incidence of Neoplasms in Female Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | – | 1 | – | 1
Moribund | 24 | 22 | 23 | 11
Natural deaths | 5 | 8 | 7 | 8
Survivors
Died last week of study | – | 1 | 1 | –
Terminal euthanasia | 21 | 18 | 19 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (48)
Intestine large, colon | (50) | (50) | (50) | (48)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (48) | (47) | (48) | (47)
Intestine small, ileum | (47) | (47) | (48) | (47)
Intestine small, jejunum | (47) | (46) | (48) | (48)
Liver | (50) | (50) | (50) | (48)
Adenocarcinoma, metastatic, uterus | – | – | 2 (4%) | 1 (2%)
Hepatocellular adenoma | 2 (4%) | 1 (2%) | 4 (8%) | –
Hepatocellular carcinoma | – | 1 (2%) | – | –
Mesentery | (0) | (2) | (2) | (1)
Fat, adenocarcinoma, metastatic, uterus | – | 1 (50%) | 1 (50%) | 1 (100%)
Fat, squamous cell carcinoma, metastatic, uterus | – | – | 1 (50%) | –
Oral mucosa | (50) | (50) | (50) | (50)
Squamous cell carcinoma | – | – | – | 2 (4%)
Pancreas | (50) | (49) | (49) | (48)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | 1 (2%) | 1 (2%)
Sarcoma stromal, metastatic, uterus | 1 (2%) | – | – | –
Acinus, adenoma | – | 1 (2%) | – | 1 (2%)
Salivary glands | (50) | (49) | (48) | (50)
Stomach, forestomach | (50) | (50) | (50) | (49)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Sarcoma stromal, metastatic, uterus | 1 (2%) | – | – | –
Squamous cell carcinoma | 1 (2%) | – | – | 1 (2%)
Stomach, glandular | (50) | (49) | (50) | (49)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Carcinoma | – | 1 (2%) | – | –
Tongue | (1) | (1) | (0) | (1)
Tooth | (0) | (1) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, squamous cell carcinoma, metastatic, lung | – | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (49)
Hemangioma | – | – | 1 (2%) | –
Schwannoma malignant | – | 2 (4%) | – | –
Squamous cell carcinoma, metastatic, lung | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (48)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Adenoma | – | 1 (2%) | 1 (2%) | –
Sarcoma stromal, metastatic, uterus | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (48)
Pheochromocytoma benign | – | 2 (4%) | 2 (4%) | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Carcinoma | – | – | 1 (2%) | –
Parathyroid gland | (47) | (49) | (46) | (49)
Pituitary gland | (50) | (50) | (50) | (49)
Schwannoma malignant, metastatic, peripheral nerve | – | 1 (2%) | – | –
Pars distalis, adenoma | 18 (36%) | 18 (36%) | 19 (38%) | 8 (16%)
Thyroid gland | (49) | (49) | (48) | (47)
C-cell, adenoma | 11 (22%) | 9 (18%) | 5 (10%) | 10 (21%)
C-cell, carcinoma | – | 1 (2%) | – | 1 (2%)
Follicular cell, adenoma | – | – | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (50) | (50) | (50)
Ovary | (50) | (50) | (50) | (49)
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Granulosa cell tumor benign | – | – | 1 (2%) | –
Granulosa-theca tumor benign | 1 (2%) | – | – | –
Tubulostromal carcinoma | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Adenocarcinoma | – | 1 (2%) | 4 (8%) | 3 (6%)
Adenocarcinoma, multiple | – | – | – | 1 (2%)
Polyp stromal | 10 (20%) | 10 (20%) | 13 (26%) | 9 (18%)
Sarcoma stromal | 1 (2%) | – | 2 (4%) | 1 (2%)
Sarcoma stromal, multiple | 1 (2%) | – | – | –
Squamous cell carcinoma | – | – | 1 (2%) | –
Vagina | (2) | (1) | (0) | (2)
Polyp | 1 (50%) | – | – | –
Sarcoma stromal, metastatic, uterus | – | – | – | 1 (50%)
Schwannoma malignant | 1 (50%) | 1 (100%) | – | 1 (50%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (7) | (6) | (4) | (3)
Pancreatic, sarcoma stromal, metastatic, uterus | 1 (14%) | – | – | –
Renal, adenocarcinoma, metastatic, uterus | – | – | – | 1 (33%)
Lymph node, mandibular | (50) | (49) | (49) | (50)
Lymph node, mesenteric | (50) | (50) | (50) | (48)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Sarcoma stromal, metastatic, uterus | 1 (2%) | – | – | –
Spleen | (50) | (50) | (50) | (48)
Thymus | (47) | (50) | (49) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Squamous cell carcinoma, metastatic, lung | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | 3 (6%) | 1 (2%) | – | 2 (4%)
Carcinoma | 3 (6%) | 2 (4%) | 2 (4%) | –
Fibroadenoma | 18 (36%) | 23 (46%) | 20 (40%) | 17 (34%)
Fibroadenoma, multiple | 11 (22%) | 8 (16%) | 4 (8%) | 6 (12%)
Myoepithelioma | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Basal cell carcinoma | – | – | 1 (2%) | –
Fibrosarcoma | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | – | – | –
Schwannoma malignant | 1 (2%) | – | – | –
Subcutaneous tissue, fibroma | 1 (2%) | – | – | 4 (8%)
Subcutaneous tissue, fibrosarcoma | 1 (2%) | – | – | –
Subcutaneous tissue, sarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, schwannoma malignant | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Cranium, osteoma | – | – | – | 1 (2%)
Periosteum, sarcoma | – | – | – | 1 (2%)
Skeletal muscle | (1) | (0) | (1) | (1)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (100%)
Sarcoma | 1 (100%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma malignant | – | – | – | 1 (2%)
Granular cell tumor benign | 1 (2%) | – | – | –
Peripheral nerve | (0) | (2) | (0) | (0)
Trigeminal, schwannoma malignant | – | 1 (50%) | – | –
Spinal cord | (0) | (1) | (0) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (49)
Adenocarcinoma, metastatic, uterus | – | 1 (2%) | 1 (2%) | 1 (2%)
Alveolar/bronchiolar adenoma | 1 (2%) | – | 1 (2%) | –
Cystic keratinizing epithelioma | – | 1 (2%) | – | –
Squamous cell carcinoma, multiple | – | – | 1 (2%) | –
Mediastinum, sarcoma | 1 (2%) | – | – | –
Nose | (49) | (50) | (49) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, peripheral nerve | – | 1 (2%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (48)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Capsule, adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Renal tubule, adenoma | – | – | 1 (2%) | –
Renal tubule, adenoma, multiple | – | | 1 (2%) | –
Urinary bladder | (49) | (50) | (50) | (50)
Squamous cell carcinoma | – | – | 1 (2%) | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | – | – | –
Leukemia mononuclear | – | 2 (4%) | – | –
Lymphoma malignant | – | – | 1 (2%) | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 46 | 44 | 46 | 37
Total primary neoplasms | 93 | 88 | 89 | 73
Total animals with benign neoplasms | 40 | 40 | 41 | 35
Total benign neoplasms | 79 | 76 | 74 | 58
Total animals with malignant neoplasms | 14 | 11 | 15 | 15
Total malignant neoplasms | 14 | 12 | 15 | 15
Total animals with metastatic neoplasms | 1 | 2 | 4 | 3
Total metastatic neoplasms | 5 | 5 | 11 | 13

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Liver: Hepatocellular Adenoma
Overall rate^a^ | 2/50 (4%) | 1/50 (2%) | 4/50 (8%) | 0/48 (0%)
Adjusted rate^b^ | 5.5% | 2.7% | 11.0% | 0.0%
Terminal rate^c^ | 2/21 (10%) | 1/19 (5%) | 2/19 (11%) | 0/30 (0%)
First incidence (days) | 729 (T) | 729 (T) | 596 | –^e^
Poly-3 test^d^ | P = 0.227N | P = 0.498N | P = 0.335 | P = 0.216N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 4/50 (8%) | 0/48 (0%)
Adjusted rate | 5.5% | 5.4% | 11.0% | 0.0%
Terminal rate | 2/21 (10%) | 1/19 (5%) | 2/19 (11%) | 0/30 (0%)
First incidence (days) | 729 (T) | 616 | 596 | –
Poly-3 test | P = 0.184N | P = 0.689N | P = 0.335 | P = 0.216N
Mammary Gland: Fibroadenoma
Overall rate | 29/50 (58%) | 31/50 (62%) | 24/50 (48%) | 23/50 (46%)
Adjusted rate | 66.6% | 71.5% | 58.4% | 53.5%
Terminal rate | 11/21 (52%) | 11/19 (58%) | 10/19 (53%) | 14/30 (47%)
First incidence (days) | 288 | 420 | 329 | 356
Poly-3 test | P = 0.058N | P = 0.389 | P = 0.283N | P = 0.147N
Mammary Gland: Adenoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 8.2% | 2.7% | 0.0% | 5.0%
Terminal rate | 1/21 (5%) | 0/19 (0%) | 0/19 (0%) | 2/30 (7%)
First incidence (days) | 681 | 645 | – | 729 (T)
Poly-3 test | P = 0.436N | P = 0.301N | P = 0.122N | P = 0.459N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 30/50 (60%) | 31/50 (62%) | 24/50 (48%) | 25/50 (50%)
Adjusted rate | 68.6% | 71.5% | 58.4% | 58.2%
Terminal rate | 11/21 (52%) | 11/19 (58%) | 10/19 (53%) | 16/30 (53%)
First incidence (days) | 288 | 420 | 329 | 356
Poly-3 test | P = 0.106N | P = 0.471 | P = 0.217N | P = 0.210N
Mammary Gland: Carcinoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 7.8% | 5.4% | 5.6% | 0.0%
Terminal rate | 0/21 (0%) | 1/19 (5%) | 2/19 (11%) | 0/30 (0%)
First incidence (days) | 446 | 705 | 729 (T) | –
Poly-3 test | P = 0.077N | P = 0.522N | P = 0.536N | P = 0.111N
Mammary Gland: Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 3/50 (6%) | 2/50 (4%) | 2/50 (4%)
Adjusted rate | 15.5% | 8.1% | 5.6% | 5.0%
Terminal rate | 1/21 (5%) | 1/19 (5%) | 2/19 (11%) | 2/30 (7%)
First incidence (days) | 446 | 645 | 729 (T) | 729 (T)
Poly-3 test | P = 0.084N | P = 0.261N | P = 0.158N | P = 0.119N
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 32/50 (64%) | 31/50 (62%) | 25/50 (50%) | 25/50 (50%)
Adjusted rate | 70.8% | 71.5% | 60.8% | 58.2%
Terminal rate | 11/21 (52%) | 11/19 (58%) | 11/19 (58%) | 16/30 (53%)
First incidence (days) | 288 | 420 | 329 | 356
Poly-3 test | P = 0.076N | P = 0.566 | P = 0.216N | P = 0.146N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 18/50 (36%) | 18/50 (36%) | 19/50 (38%) | 8/49 (16%)
Adjusted rate | 45.6% | 45.1% | 49.0% | 19.8%
Terminal rate | 8/21 (38%) | 10/19 (53%) | 11/19 (58%) | 3/30 (10%)
First incidence (days) | 552 | 420 | 516 | 571
Poly-3 test | P = 0.006N | P = 0.574N | P = 0.469 | P = 0.011N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 1/50 (2%) | 0/50 (0%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 2.7% | 0.0% | 0.0% | 9.9%
Terminal rate | 1/21 (5%) | 0/19 (0%) | 0/19 (0%) | 3/30 (10%)
First incidence (days) | 729 (T) | – | – | 701
Poly-3 test | P = 0.029 | P = 0.499N | P = 0.504N | P = 0.209
Skin (Subcutaneous Tissue): Fibroma or Fibrosarcoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 0/50 (0%) | 5/50 (10%)
Adjusted rate | 5.4% | 0.0% | 0.0% | 12.4%
Terminal rate | 1/21 (5%) | 0/19 (0%) | 0/19 (0%) | 3/30 (10%)
First incidence (days) | 645 | – | – | 692
Poly-3 test | P = 0.040 | P = 0.237N | P = 0.243N | P = 0.254
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, or Sarcoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 0/50 (0%) | 6/50 (12%)
Adjusted rate | 5.4% | 0.0% | 0.0% | 14.9%
Terminal rate | 1/21 (5%) | 0/19 (0%) | 0/19 (0%) | 4/30 (13%)
First incidence (days) | 645 | – | – | 692
Poly-3 test | P = 0.013 | P = 0.237N | P = 0.243N | P = 0.163
Thyroid Gland (C-Cell): Adenoma
Overall rate | 11/49 (22%) | 9/49 (18%) | 5/48 (10%) | 10/47 (21%)
Adjusted rate | 29.8% | 23.9% | 13.9% | 25.0%
Terminal rate | 8/21 (38%) | 6/19 (32%) | 2/19 (11%) | 7/30 (23%)
First incidence (days) | 558 | 313 | 631 | 605
Poly-3 test | P = 0.385N | P = 0.375N | P = 0.082N | P = 0.413N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 11/49 (22%) | 10/49 (20%) | 5/48 (10%) | 11/47 (23%)
Adjusted rate | 29.8% | 26.6% | 13.9% | 27.4%
Terminal rate | 8/21 (38%) | 7/19 (37%) | 2/19 (11%) | 7/30 (23%)
First incidence (days) | 558 | 313 | 631 | 605
Poly-3 test | P = 0.457N | P = 0.478N | P = 0.082N | P = 0.508N
Uterus: Stromal Polyp (Standard Evaluation)
Overall rate | 10/50 (20%) | 10/50 (20%) | 13/50 (26%) | 9/50 (18%)
Adjusted rate | 26.6% | 26.2% | 34.7% | 22.1%
Terminal rate | 7/21 (33%) | 5/19 (26%) | 8/19 (42%) | 6/30 (20%)
First incidence (days) | 422 | 420 | 611 | 622
Poly-3 test | P = 0.379N | P = 0.589N | P = 0.300 | P = 0.420N
Uterus: Stromal Polyp or Stromal Sarcoma (Standard Evaluation)
Overall rate | 12/50 (24%) | 10/50 (20%) | 15/50 (30%) | 9/50 (18%)
Adjusted rate | 31.3% | 26.2% | 38.6% | 22.1%
Terminal rate | 7/21 (33%) | 5/19 (26%) | 8/19 (42%) | 6/30 (20%)
First incidence (days) | 422 | 420 | 393 | 622
Poly-3 test | P = 0.260N | P = 0.405N | P = 0.330 | P = 0.249N
Uterus: Adenocarcinoma (Standard Evaluation)
Overall rate | 0/50 (0%) | 1/50 (2%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 0.0% | 2.7% | 10.9% | 9.8%
Terminal rate | 0/21 (0%) | 0/19 (0%) | 1/19 (5%) | 2/30 (7%)
First incidence (days) | – | 645 | 608 | 645
Poly-3 test | P = 0.040 | P = 0.503 | P = 0.059 | P = 0.074
Uterus: Adenocarcinoma (Extended Evaluation)
Overall rate | 5/50 (10%) | 3/50 (6%) | 10/50 (20%) | 8/50 (16%)
Adjusted rate | 13.7% | 8.2% | 26.9% | 19.8%
Terminal rate | 3/21 (14%) | 2/19 (11%) | 5/19 (26%) | 7/30 (23%)
First incidence (days) | 719 | 719 | 615 | 674
Poly-3 test | P = 0.158 | P = 0.351N | P = 0.127 | P = 0.340
Uterus: Adenoma or Adenocarcinoma (Extended Evaluation)
Overall rate | 5/50 (10%) | 5/50 (10%) | 11/50 (22%) | 9/50 (18%)
Adjusted rate | 13.7% | 13.5% | 29.6% | 22.3%
Terminal rate | 3/21 (14%) | 3/19 (16%) | 6/19 (32%) | 8/30 (27%)
First incidence (days) | 719 | 645 | 615 | 674
Poly-3 test | P = 0.146 | P = 0.624N | P = 0.080 | P = 0.247
Uterus: Adenoma or Adenocarcinoma (Standard and Extended Evaluation)
Overall rate | 5/50 (10%) | 5/50 (10%) | 14/50 (28%) | 11/50 (22%)
Adjusted rate | 13.7% | 13.5% | 36.6% | 27.0%
Terminal rate | 3/21 (14%) | 3/19 (16%) | 6/19 (32%) | 9/30 (30%)
First incidence (days) | 719 | 645 | 608 | 645
Poly-3 test | P = 0.052 | P = 0.624N | P = 0.018 | P = 0.119
Uterus: Adenocarcinoma or Adenosquamous Carcinoma (Standard and Extended Evaluations)
Overall rate | 5/50 (10%) | 4/50 (8%) | 13/50 (26%) | 10/50 (20%)
Adjusted rate | 13.7% | 10.8% | 34.0% | 24.6%
Terminal rate | 3/21 (14%) | 2/19 (11%) | 5/19 (26%) | 8/30 (27%)
First incidence (days) | 719 | 645 | 608 | 645
Poly-3 test | P = 0.071 | P = 0.491N | P = 0.033 | P = 0.177
All Organs: Benign Neoplasms
Overall rate | 40/50 (80%) | 40/50 (80%) | 41/50 (82%) | 35/50 (70%)
Adjusted rate | 89.5% | 88.9% | 91.7% | 79.1%
Terminal rate | 19/21 (91%) | 18/19 (95%) | 18/19 (95%) | 22/30 (73%)
First incidence (days) | 288 | 313 | 307 | 356
Poly-3 test | P = 0.067N | P = 0.609N | P = 0.508 | P = 0.127N
All Organs: Malignant Neoplasms
Overall rate | 14/50 (28%) | 11/50 (22%) | 15/50 (30%) | 15/50 (30%)
Adjusted rate | 33.4% | 27.7% | 36.7% | 35.8%
Terminal rate | 3/21 (14%) | 4/19 (21%) | 6/19 (32%) | 8/30 (27%)
First incidence (days) | 425 | 187 | 160 | 605
Poly-3 test | P = 0.356 | P = 0.374N | P = 0.464 | P = 0.498
All Organs: Benign or Malignant Neoplasms
Overall rate | 46/50 (92%) | 44/50 (88%) | 46/50 (92%) | 37/50 (74%)
Adjusted rate | 95.3% | 92.6% | 96.6% | 83.6%
Terminal rate | 19/21 (91%) | 18/19 (95%) | 18/19 (95%) | 24/30 (80%)
First incidence (days) | 288 | 187 | 160 | 356
Poly-3 test | P = 0.029N | P = 0.445N | P = 0.577 | P = 0.057N

(T) Terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table B-3 Historical Incidence of Carcinoma of the Uterus in Control Female Sprague Dawley Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Corn Oil Gavage Studies^b^
Indole-3-carbinol (March 2007) | 0/50
PCB 118 (March 2004) | 2/52
Total | 2/102 (2.0%)
Mean ± standard deviation | 1.9% ± 2.7%
Range | 0%–4%

^a^ Data as of June 2013.

^b^ Same data for overall historical incidence for all routes.

Table B-4 Historical Incidence of Skin Neoplasms in Control Female Sprague Dawley Rats^a^

Study (Study Start) | Fibroma | Fibrosarcoma | Fibroma or Fibrosarcoma
Historical Incidence: Corn Oil Gavage Studies^b^
Indole-3-carbinol (March 2007) | 1/50 | 1/50 | 2/50
PCB 118 (March 2004) | 2/52 | 0/52 | 2/52
Total (%) | 3/102 (2.9%) | 1/102 (1.0%) | 4/102 (3.9%)
Mean ± standard deviation | 2.9% ± 1.3% | 1.0% ± 1.4% | 3.9% ± 0.1%
Range | 2%–4% | 0%–2% | 4%

^a^ Data as of June 2013.

^b^ Same data for overall historical incidence for all routes.

Table B-5 Summary of the Incidence of Nonneoplastic Lesions in Female Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | – | 1 | – | 1
Moribund | 24 | 22 | 23 | 11
Natural deaths | 5 | 8 | 7 | 8
Survivors
Died last week of study | – | 1 | 1 | –
Terminal euthanasia | 21 | 18 | 19 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation | – | 2 (4%) | – | –
Perforation | – | – | – | 1 (2%)
Intestine large, cecum | (50) | (50) | (50) | (48)
Intestine large, colon | (50) | (50) | (50) | (48)
Intestine large, rectum | (50) | (50) | (50) | (50)
Metaplasia | – | – | 1 (2%) | –
Intestine small, duodenum | (48) | (47) | (48) | (47)
Lymphatic, ectasia | – | – | 16 (33%) | 38 (81%)
Intestine small, ileum | (47) | (47) | (48) | (47)
Intestine small, jejunum | (47) | (46) | (48) | (48)
Lymphatic, ectasia | – | – | 30 (63%) | 47 (98%)
Liver | (50) | (50) | (50) | (48)
Angiectasis | 1 (2%) | – | 2 (4%) | 3 (6%)
Basophilic focus | 14 (28%) | 6 (12%) | 11 (22%) | 14 (29%)
Cholangiofibrosis | – | 1 (2%) | – | –
Clear cell focus | 6 (12%) | 7 (14%) | 4 (8%) | 18 (38%)
Eosinophilic focus | – | 4 (8%) | 5 (10%) | 6 (13%)
Hepatodiaphragmatic nodule | – | – | 3 (6%) | 2 (4%)
Inflammation, chronic | – | – | – | 1 (2%)
Mixed cell focus | 5 (10%) | 1 (2%) | 5 (10%) | 4 (8%)
Necrosis | 1 (2%) | 2 (4%) | – | –
Pigmentation | 1 (2%) | – | – | –
Thrombosis | – | 1 (2%) | – | –
Bile duct, cyst | 2 (4%) | 1 (2%) | 4 (8%) | 4 (8%)
Bile duct, cyst, multiple | 2 (4%) | 1 (2%) | 2 (4%) | 2 (4%)
Bile duct, hyperplasia | 2 (4%) | – | – | –
Centrilobular, degeneration | – | 1 (2%) | – | –
Mesentery | (0) | (2) | (2) | (1)
Artery, inflammation, chronic active | – | 1 (50%) | – | –
Oral mucosa | (50) | (50) | (50) | (50)
Hyperplasia, squamous | – | – | 1 (2%) | 2 (4%)
Pancreas | (50) | (49) | (49) | (48)
Acinus, hyperplasia | 1 (2%) | 3 (6%) | – | 1 (2%)
Artery, inflammation, chronic active | 1 (2%) | 4 (8%) | 3 (6%) | 6 (13%)
Salivary glands | (50) | (49) | (48) | (50)
Inflammation | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (49)
Hyperplasia | 2 (4%) | 5 (10%) | 7 (14%) | 3 (6%)
Inflammation | 1 (2%) | – | – | 1 (2%)
Pigmentation, melanin | – | 1 (2%) | – | –
Ulcer | 1 (2%) | – | – | –
Stomach, glandular | (50) | (49) | (50) | (49)
Erosion | – | – | 1 (2%) | –
Ulcer | 1 (2%) | – | – | –
Epithelium, hyperplasia | 1 (2%) | – | 1 (2%) | –
Epithelium, mineralization | – | – | 1 (2%) | –
Tongue | (1) | (1) | (0) | (1)
Cyst | – | – | – | 1 (100%)
Erosion | 1 (100%) | – | – | –
Inflammation | – | 1 (100%) | – | –
Tooth | (0) | (1) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Degeneration, focal | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 3 (6%) | 4 (8%) | 7 (14%)
Thrombosis | – | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (49)
Cardiomyopathy | 24 (48%) | 24 (48%) | 24 (48%) | 24 (49%)
Atrium, thrombosis | – | 1 (2%) | – | –
Epicardium, inflammation | 1 (2%) | 3 (6%) | – | 1 (2%)
Pericardium, inflammation | – | – | 2 (4%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (48)
Degeneration, cystic | 16 (32%) | 12 (24%) | 11 (22%) | 15 (31%)
Degeneration, fatty | 5 (10%) | 3 (6%) | – | 1 (2%)
Hyperplasia | 18 (36%) | 11 (22%) | 18 (36%) | 15 (31%)
Hypertrophy | 1 (2%) | – | – | –
Inflammation | – | 1 (2%) | – | 1 (2%)
Necrosis | – | – | 1 (2%) | 1 (2%)
Thrombosis | – | 1 (2%) | 1 (2%) | –
Bilateral, degeneration, cystic | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (48)
Hyperplasia | 15 (30%) | 13 (26%) | 11 (22%) | 12 (25%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Parathyroid gland | (47) | (49) | (46) | (49)
Hyperplasia | – | 2 (4%) | – | –
Pituitary gland | (50) | (50) | (50) | (49)
Pars distalis, hyperplasia | 19 (38%) | 14 (28%) | 18 (36%) | 24 (49%)
Thyroid gland | (49) | (49) | (48) | (47)
C-cell, hyperplasia | 7 (14%) | 5 (10%) | 6 (13%) | 5 (11%)
Follicular cell, hyperplasia | 1 (2%) | – | 1 (2%) | 1 (2%)
Follicular cell, hypertrophy | 27 (55%) | 23 (47%) | 24 (50%) | 30 (64%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (50) | (50) | (50)
Cyst | 5 (10%) | 2 (4%) | 3 (6%) | 4 (8%)
Inflammation | 1 (2%) | – | – | 2 (4%)
Ovary | (50) | (50) | (50) | (49)
Angiectasis | – | – | – | 1 (2%)
Atrophy | 40 (80%) | 23 (46%) | 37 (74%) | 30 (61%)
Cyst | 17 (34%) | 13 (26%) | 16 (32%) | 16 (33%)
Inflammation, acute | – | – | 1 (2%) | 1 (2%)
Inflammation, chronic | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | 1 (2%)
Necrosis, fibrinoid | – | – | 1 (2%) | –
Uterus | (50) | (50) | (50) | (50)
Cyst | – | – | 2 (4%) | –
Dilatation | 9 (18%) | 9 (18%) | 7 (14%) | 5 (10%)
Inflammation, histiocytic, focal | 1 (2%) | – | – | –
Inflammation, acute | 5 (10%) | 12 (24%) | 6 (12%) | 9 (18%)
Thrombosis | – | – | 1 (2%) | 1 (2%)
Endometrium, hyperplasia, cystic | 29 (58%) | 28 (56%) | 29 (58%) | 21 (42%)
Endometrium, metaplasia, squamous | 12 (24%) | 18 (36%) | 20 (40%) | 11 (22%)
Vagina | (2) | (1) | (0) | (2)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | 1 (2%) | –
Hyperplasia | 21 (42%) | 20 (40%) | 23 (46%) | 17 (34%)
Lymph node | (7) | (6) | (4) | (3)
Axillary, hyperplasia, lymphoid | – | – | – | 1 (33%)
Iliac, hyperplasia, lymphoid | – | 1 (17%) | – | –
Iliac, infiltration cellular, histiocyte | – | – | – | 1 (33%)
Inguinal, hemorrhage | – | 1 (17%) | – | –
Inguinal, hyperplasia, lymphoid | 1 (14%) | – | 1 (25%) | –
Lumbar, hemorrhage | 2 (29%) | 1 (17%) | – | –
Lumbar, hyperplasia, lymphoid | 1 (14%) | 1 (17%) | – | –
Lumbar, infiltration cellular, histiocyte | – | 1 (17%) | 1 (25%) | –
Mediastinal, ectasia | – | – | 1 (25%) | –
Mediastinal, hemorrhage | 2 (29%) | – | 1 (25%) | –
Mediastinal, infiltration cellular, histiocyte | 1 (14%) | – | – | –
Lymph node, mandibular | (50) | (49) | (49) | (50)
Lymph node, mesenteric | (50) | (50) | (50) | (48)
Hemorrhage | – | – | – | 1 (2%)
Pigmentation, hemosiderin | 1 (2%) | – | – | –
Lymphatic, ectasia | – | – | 1 (2%) | 15 (31%)
Spleen | (50) | (50) | (50) | (48)
Hematopoietic cell proliferation | 36 (72%) | 32 (64%) | 40 (80%) | 33 (69%)
Thymus | (47) | (50) | (49) | (50)
Atrophy | 38 (81%) | 31 (62%) | 34 (69%) | 38 (76%)
Hemorrhage | – | – | – | 1 (2%)
Inflammation | – | 1 (2%) | 1 (2%) | –
Epithelial cell, hyperplasia | 1 (2%) | 4 (8%) | 3 (6%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | 1 (2%) | – | – | –
Hyperplasia | 8 (16%) | 3 (6%) | 7 (14%) | 7 (14%)
Inflammation | 1 (2%) | 1 (2%) | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Duct, dilatation | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | – | 1 (2%) | – | 1 (2%)
Fibrosis | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibrous osteodystrophy | – | 1 (2%) | 1 (2%) | –
Skeletal muscle | (1) | (0) | (1) | (1)
Degeneration | – | – | 1 (100%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Gliosis | – | 1 (2%) | – | –
Hemorrhage | – | – | – | 1 (2%)
Inflammation | – | 1 (2%) | – | –
Necrosis | 1 (2%) | – | – | 1 (2%)
Meninges, pigmentation, lipofuscin | – | 1 (2%) | – | –
Peripheral nerve | (0) | (2) | (0) | (0)
Spinal cord | (0) | (1) | (0) | (0)
Hemorrhage | – | 1 (100%) | – | –
Necrosis | – | 1 (100%) | – | –
Respiratory System
Lung | (50) | (50) | (50) | (49)
Atelectasis | – | 1 (2%) | – | –
Foreign body | – | 2 (4%) | – | –
Inflammation, granulomatous | 1 (2%) | – | – | –
Inflammation, chronic | 34 (68%) | 30 (60%) | 38 (76%) | 35 (71%)
Alveolar epithelium, hyperplasia | – | – | – | 1 (2%)
Alveolar epithelium, metaplasia, squamous | – | – | – | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 13 (26%) | 16 (32%) | 11 (22%) | 9 (18%)
Bronchiole, hyperplasia | – | 1 (2%) | 1 (2%) | –
Mediastinum, inflammation | – | 1 (2%) | – | –
Pleura, inflammation, chronic active | – | 1 (2%) | – | –
Nose | (49) | (50) | (49) | (50)
Angiectasis | – | – | 1 (2%) | –
Foreign body | 3 (6%) | 2 (4%) | 3 (6%) | 3 (6%)
Inflammation, chronic active | 5 (10%) | 4 (8%) | 5 (10%) | 6 (12%)
Glands, olfactory epithelium, hyperplasia | – | 1 (2%) | – | –
Olfactory epithelium, atrophy | – | – | 2 (4%) | 5 (10%)
Olfactory epithelium, degeneration | 1 (2%) | – | 1 (2%) | –
Respiratory epithelium, hyperplasia | – | – | 3 (6%) | 2 (4%)
Respiratory epithelium, metaplasia, squamous | – | – | 1 (2%) | 1 (2%)
Trachea | (50) | (50) | (50) | (50)
Epithelium, necrosis | – | 1 (2%) | – | –
Special Senses System
Eye | (50) | (50) | (50) | (50)
Cataract | 1 (2%) | – | – | –
Inflammation | – | 1 (2%) | 1 (2%) | –
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia, focal | – | – | 1 (2%) | –
Inflammation | – | 1 (2%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (48)
Nephropathy | 45 (90%) | 41 (82%) | 42 (84%) | 43 (90%)
Pelvis, inflammation | – | – | – | 1 (2%)
Urinary bladder | (49) | (50) | (50) | (50)
Hyperplasia | – | – | 1 (2%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.