# Appendix A Summary of Lesions in Male Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

Table A-1 Summary of the Incidence of Neoplasms in Male Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Disposition Summary
Animals Initially in Study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | – | 1
Moribund | 14 | 23 | 15 | 20
Natural deaths | 16 | 14 | 18 | 17
Survivors
Terminal euthanasia | 20 | 13 | 17 | 12
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Lipoma | – | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (43) | (48) | (47) | (48)
Carcinoma | – | 1 (2%) | – | –
Intestine small, ileum | (35) | (43) | (42) | (38)
Intestine small, jejunum | (40) | (39) | (40) | (42)
Carcinoma | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Hepatocellular adenoma | 1 (2%) | – | – | –
Hepatocellular carcinoma | – | – | – | 1 (2%)
Mesentery | (2) | (2) | (1) | (0)
Fat, sarcoma | – | – | 1 (100%) | –
Oral mucosa | (50) | (50) | (50) | (50)
Squamous cell carcinoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Pancreas | (50) | (50) | (50) | (49)
Carcinoma | – | – | – | 1 (2%)
Mixed tumor malignant | – | – | 1 (2%) | –
Acinus, adenoma | 4 (8%) | 1 (2%) | 4 (8%) | 4 (8%)
Acinus, adenoma, multiple | 1 (2%) | 3 (6%) | – | 1 (2%)
Salivary glands | (50) | (50) | (49) | (50)
Schwannoma malignant | 1 (2%) | – | – | 1 (2%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell carcinoma | 1 (2%) | – | 1 (2%) | –
Squamous cell papilloma | – | – | 1 (2%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (0) | (0) | (0) | (1)
Squamous cell papilloma | – | – | – | 1 (100%)
Tooth | (1) | (0) | (1) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, fibrous histiocytoma, metastatic, skin | – | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Schwannoma malignant | 1 (2%) | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Carcinoma | – | 1 (2%) | – | 1 (2%)
Adrenal medulla | (50) | (49) | (50) | (50)
Pheochromocytoma benign | 5 (10%) | 5 (10%) | 4 (8%) | 3 (6%)
Pheochromocytoma complex | 1 (2%) | – | – | –
Pheochromocytoma malignant | 2 (4%) | 1 (2%) | 1 (2%) | –
Bilateral, pheochromocytoma benign | – | – | 1 (2%) | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | 1 (2%) | 1 (2%) | –
Parathyroid gland | (43) | (46) | (50) | (47)
Carcinoma | – | 1 (2%) | – | –
Pituitary gland | (50) | (49) | (50) | (47)
Pars distalis, adenoma | 5 (10%) | 8 (16%) | 9 (18%) | 8 (17%)
Pars distalis, carcinoma | – | 1 (2%) | – | –
Thyroid gland | (50) | (46) | (48) | (47)
Bilateral, c-cell, adenoma | 2 (4%) | – | 1 (2%) | –
C-cell, adenoma | 11 (22%) | 9 (20%) | 8 (17%) | 4 (9%)
C-cell, carcinoma | – | 1 (2%) | 1 (2%) | –
Follicular cell, adenoma | – | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (50) | (50) | (49) | (50)
Prostate | (50) | (50) | (50) | (50)
Seminal vesicle | (49) | (50) | (50) | (50)
Testes | (49) | (50) | (50) | (50)
Interstitial cell, adenoma | 3 (6%) | 2 (4%) | 2 (4%) | 2 (4%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (4) | (8) | (8) | (6)
Lymph node, mandibular | (50) | (50) | (49) | (50)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Thymus | (46) | (49) | (49) | (47)
Neural crest tumor | – | – | – | 1 (2%)
Thymoma benign | 1 (2%) | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Fibroadenoma | 1 (2%) | 1 (2%) | 1 (2%) | –
Skin | (50) | (50) | (50) | (50)
Basal cell carcinoma | 1 (2%) | 1 (2%) | – | –
Keratoacanthoma | 4 (8%) | – | – | –
Squamous cell carcinoma | 1 (2%) | – | 1 (2%) | –
Squamous cell papilloma | 1 (2%) | – | 1 (2%) | 1 (2%)
Sebaceous gland, adenoma | – | 1 (2%) | – | –
Subcutaneous tissue, fibroma | 5 (10%) | 2 (4%) | 5 (10%) | 2 (4%)
Subcutaneous tissue, fibrosarcoma | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Subcutaneous tissue, fibrous histiocytoma | 1 (2%) | – | – | 1 (2%)
Subcutaneous tissue, sarcoma | – | 2 (4%) | – | –
Subcutaneous tissue, schwannoma malignant | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Vertebra, osteoma | – | – | – | 1 (2%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma malignant | – | 1 (2%) | – | –
Medulloblastoma | – | – | 1 (2%) | –
Meningioma malignant | – | 1 (2%) | – | –
Cerebellum, glioma malignant | – | – | – | 1 (2%)
Spinal cord | (0) | (2) | (1) | (0)
Respiratory System
Lung | (49) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | – | 1 (2%) | –
Carcinoma, metastatic, adrenal cortex | – | – | – | 1 (2%)
Fibrous histiocytoma, metastatic, skin | – | – | – | 1 (2%)
Squamous cell carcinoma | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (0) | (0) | (1) | (0)
Eye | (50) | (50) | (49) | (49)
Harderian gland | (50) | (50) | (49) | (50)
Lacrimal gland | (1) | (2) | (4) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Renal tubule, adenoma | 1 (2%) | – | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Leukemia granulocytic | – | – | – | 1 (2%)
Lymphoma malignant | – | – | 1 (2%) | 1 (2%)
Mesothelioma malignant | 1 (2%) | 1 (2%) | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 33 | 32 | 31 | 33
Total primary neoplasms | 60 | 53 | 50 | 42
Total animals with benign neoplasms | 27 | 23 | 26 | 25
Total benign neoplasms | 47 | 37 | 39 | 29
Total animals with malignant neoplasms | 12 | 15 | 10 | 12
Total malignant neoplasms | 13 | 16 | 11 | 12
Total animals with metastatic neoplasms | – | – | – | 3
Total metastatic neoplasms | – | – | – | 4
Total animals with uncertain neoplasms —benign or malignant | – | – | – | 1
Total uncertain neoplasms | – | – | – | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 5/50 (10%) | 5/49 (10%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate^b^ | 13.0% | 14.7% | 13.5% | 11.7%
Terminal rate^c^ | 3/20 (15%) | 2/13 (15%) | 2/17 (12%) | 3/12 (25%)
First incidence (days) | 645 | 571 | 593 | 621
Poly-3 test^d^ | P = 0.479N | P = 0.549 | P = 0.605 | P = 0.577N
Adrenal Medulla: Benign, Complex, or Malignant Pheochromocytoma
Overall rate | 8/50 (16%) | 6/49 (12%) | 6/50 (12%) | 4/50 (8%)
Adjusted rate | 20.5% | 17.5% | 16.1% | 11.7%
Terminal rate | 4/20 (20%) | 2/13 (15%) | 2/17 (12%) | 3/12 (25%)
First incidence (days) | 634 | 571 | 593 | 621
Poly-3 test | P = 0.190N | P = 0.491N | P = 0.422N | P = 0.243N
Pancreas: Adenoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 4/50 (8%) | 5/49 (10%)
Adjusted rate | 13.0% | 11.8% | 10.9% | 14.8%
Terminal rate | 3/20 (15%) | 2/13 (15%) | 2/17 (12%) | 3/12 (25%)
First incidence (days) | 685 | 648 | 624 | 710
Poly-3 test | P = 0.474 | P = 0.579N | P = 0.527N | P = 0.549
Pancreas: Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 4/50 (8%) | 6/49 (12%)
Adjusted rate | 13.0% | 11.8% | 10.9% | 17.5%
Terminal rate | 3/20 (15%) | 2/13 (15%) | 2/17 (12%) | 3/12 (25%)
First incidence (days) | 685 | 648 | 624 | 589
Poly-3 test | P = 0.337 | P = 0.579N | P = 0.527N | P = 0.418
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 5/50 (10%) | 8/49 (16%) | 9/50 (18%) | 8/47 (17%)
Adjusted rate | 12.9% | 23.3% | 23.4% | 23.3%
Terminal rate | 2/20 (10%) | 3/13 (23%) | 1/17 (6%) | 1/12 (8%)
First incidence (days) | 645 | 617 | 503 | 589
Poly-3 test | P = 0.191 | P = 0.193 | P = 0.180 | P = 0.193
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 9/49 (18%) | 9/50 (18%) | 8/47 (17%)
Adjusted rate | 12.9% | 25.9% | 23.4% | 23.3%
Terminal rate | 2/20 (10%) | 3/13 (23%) | 1/17 (6%) | 1/12 (8%)
First incidence (days) | 645 | 614 | 503 | 589
Poly-3 test | P = 0.218 | P = 0.127 | P = 0.180 | P = 0.193
Skin: Keratoacanthoma
Overall rate | 4/50 (8%) | 0/50 (0%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 10.4% | 0.0% | 0.0% | 0.0%
Terminal rate | 2/20 (10%) | 0/13 (0%) | 0/17 (0%) | 0/12 (0%)
First incidence (days) | 685 | –^e^ | – | –
Poly-3 test | P = 0.015N | P = 0.079N | P = 0.066N | P = 0.077N
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 5/50 (10%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 13.0% | 0.0% | 2.8% | 2.9%
Terminal rate | 3/20 (15%) | 0/13 (0%) | 1/17 (6%) | 0/12 (0%)
First incidence (days) | 685 | – | 727 (T) | 629
Poly-3 test | P = 0.075N | P = 0.043N | P = 0.112N | P = 0.129N
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Squamous Cell Carcinoma
Overall rate | 5/50 (10%) | 0/50 (0%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 13.0% | 0.0% | 5.4% | 2.9%
Terminal rate | 3/20 (15%) | 0/13 (0%) | 1/17 (6%) | 0/12 (0%)
First incidence (days) | 685 | – | 624 | 629
Poly-3 test | P = 0.104N | P = 0.043N | P = 0.233N | P = 0.129N
Skin: Squamous Cell Papilloma, Keratoacanthoma, Basal Cell Carcinoma, or Squamous Cell Carcinoma
Overall rate | 6/50 (12%) | 1/50 (2%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 15.5% | 3.0% | 5.4% | 2.9%
Terminal rate | 3/20 (15%) | 0/13 (0%) | 1/17 (6%) | 0/12 (0%)
First incidence (days) | 645 | 637 | 624 | 629
Poly-3 test | P = 0.048N | P = 0.079N | P = 0.147N | P = 0.077N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 5/50 (10%) | 2/50 (4%) | 5/50 (10%) | 2/50 (4%)
Adjusted rate | 12.6% | 5.8% | 13.4% | 5.7%
Terminal rate | 1/20 (5%) | 0/13 (0%) | 3/17 (18%) | 0/12 (0%)
First incidence (days) | 575 | 597 | 500 | 401
Poly-3 test | P = 0.286N | P = 0.278N | P = 0.596 | P = 0.267N
Skin (Subcutaneous Tissue): Fibrous Histiocytoma, Fibrosarcoma, or Sarcoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 5.0% | 11.2% | 2.7% | 5.7%
Terminal rate | 0/20 (0%) | 1/13 (8%) | 0/17 (0%) | 0/12 (0%)
First incidence (days) | 197 | 382 | 423 | 258
Poly-3 test | P = 0.485N | P = 0.286 | P = 0.526N | P = 0.645
Skin (Subcutaneous Tissue): Fibroma, Fibrous Histiocytoma, Fibrosarcoma, or Sarcoma
Overall rate | 7/50 (14%) | 6/50 (12%) | 6/50 (12%) | 4/50 (8%)
Adjusted rate | 16.9% | 16.4% | 15.7% | 11.1%
Terminal rate | 1/20 (5%) | 1/13 (8%) | 3/17 (18%) | 0/12 (0%)
First incidence (days) | 197 | 382 | 423 | 258
Poly-3 test | P = 0.275N | P = 0.597N | P = 0.562N | P = 0.341N
Testes: Adenoma
Overall rate | 3/49 (6%) | 2/50 (4%) | 2/50 (4%) | 2/50 (4%)
Adjusted rate | 7.9% | 5.9% | 5.4% | 5.8%
Terminal rate | 1/20 (5%) | 1/13 (8%) | 0/17 (0%) | 1/12 (8%)
First incidence (days) | 635 | 671 | 570 | 532
Poly-3 test | P = 0.446N | P = 0.553N | P = 0.506N | P = 0.543N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 13/50 (26%) | 9/46 (20%) | 9/48 (19%) | 4/47 (9%)
Adjusted rate | 32.5% | 27.5% | 24.2% | 12.0%
Terminal rate | 7/20 (35%) | 4/13 (31%) | 3/17 (18%) | 2/12 (17%)
First incidence (days) | 421 | 456 | 503 | 519
Poly-3 test | P = 0.024N | P = 0.416N | P = 0.289N | P = 0.033N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 13/50 (26%) | 10/46 (22%) | 10/48 (21%) | 4/47 (9%)
Adjusted rate | 32.5% | 30.2% | 26.6% | 12.0%
Terminal rate | 7/20 (35%) | 4/13 (31%) | 3/17 (18%) | 2/12 (17%)
First incidence (days) | 421 | 456 | 503 | 519
Poly-3 test | P = 0.025N | P = 0.516N | P = 0.373N | P = 0.033N
All Organs: Benign Neoplasms
Overall rate | 27/50 (54%) | 23/50 (46%) | 26/50 (52%) | 25/50 (50%)
Adjusted rate | 63.7% | 58.1% | 62.3% | 62.2%
Terminal rate | 12/20 (60%) | 6/13 (46%) | 10/17 (59%) | 8/12 (67%)
First incidence (days) | 421 | 382 | 482 | 258
Poly-3 test | P = 0.544 | P = 0.378N | P = 0.540N | P = 0.537N
All Organs: Malignant Neoplasms
Overall rate | 12/50 (24%) | 15/50 (30%) | 10/50 (20%) | 12/50 (24%)
Adjusted rate | 29.3% | 37.1% | 25.2% | 30.8%
Terminal rate | 5/20 (25%) | 2/13 (15%) | 1/17 (6%) | 2/12 (17%)
First incidence (days) | 197 | 357 | 423 | 258
Poly-3 test | P = 0.480N | P = 0.301 | P = 0.438N | P = 0.540
All Organs: Benign or Malignant Neoplasms
Overall rate | 33/50 (66%) | 32/50 (64%) | 31/50 (62%) | 33/50 (66%)
Adjusted rate | 75.2% | 73.1% | 71.0% | 76.1%
Terminal rate | 14/20 (70%) | 7/13 (54%) | 11/17 (65%) | 9/12 (75%)
First incidence (days) | 197 | 357 | 423 | 258
Poly-3 test | P = 0.495 | P = 0.507N | P = 0.414N | P = 0.564

(T) Terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal medulla, pancreas, pituitary gland, testes, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Sprague Dawley Rats in the Two-year Gavage Study of Indole-3-carbinol^a^

| Vehicle Control | 75 mg/kg | 150 mg/kg | 300 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | – | – | – | 1
Moribund | 14 | 23 | 15 | 20
Natural deaths | 16 | 14 | 18 | 17
Survivors
Terminal euthanasia | 20 | 13 | 17 | 12
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Epithelium, hyperplasia | – | 1 (2%) | – | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Necrosis | 1 (2%) | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Erosion | 1 (2%) | – | – | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Fibrosis | – | – | – | 1 (2%)
Intestine small, duodenum | (43) | (48) | (47) | (48)
Lymphatic, ectasia | – | – | 15 (32%) | 14 (29%)
Intestine small, ileum | (35) | (43) | (42) | (38)
Intestine small, jejunum | (40) | (39) | (40) | (42)
Lymphatic, ectasia | – | 2 (5%) | 27 (68%) | 41 (98%)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Basophilic focus | 3 (6%) | – | 3 (6%) | 1 (2%)
Cholangiofibrosis | – | 1 (2%) | 3 (6%) | 1 (2%)
Clear cell focus | 14 (28%) | 13 (26%) | 18 (36%) | 9 (18%)
Degeneration, cystic | – | – | 1 (2%) | –
Eosinophilic focus | 10 (20%) | 12 (24%) | 10 (20%) | 6 (12%)
Hepatodiaphragmatic nodule | 2 (4%) | – | 1 (2%) | 1 (2%)
Mixed cell focus | 4 (8%) | 2 (4%) | 1 (2%) | 2 (4%)
Necrosis | 3 (6%) | 3 (6%) | 5 (10%) | 7 (14%)
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Bile duct, cyst | – | – | 1 (2%) | 5 (10%)
Bile duct, cyst, multiple | – | – | 1 (2%) | –
Bile duct, fibrosis | 2 (4%) | – | 1 (2%) | 1 (2%)
Bile duct, hyperplasia | 7 (14%) | 4 (8%) | 3 (6%) | 3 (6%)
Oval cell, hyperplasia | – | – | – | 1 (2%)
Periportal, inflammation, chronic active | 1 (2%) | – | – | –
Mesentery | (2) | (2) | (1) | (0)
Artery, inflammation, chronic active | 1 (50%) | – | – | –
Artery, mineralization | – | 1 (50%) | – | –
Fat, necrosis | 1 (50%) | – | – | –
Oral mucosa | (50) | (50) | (50) | (50)
Foreign body | – | 1 (2%) | – | –
Hyperplasia, squamous | – | 1 (2%) | 2 (4%) | 1 (2%)
Sebaceous gland, ectopic tissue | – | – | – | 1 (2%)
Pancreas | (50) | (50) | (50) | (49)
Angiectasis | – | – | – | 1 (2%)
Thrombosis | – | 1 (2%) | – | –
Acinus, atrophy | 1 (2%) | 1 (2%) | – | 2 (4%)
Acinus, hyperplasia | 16 (32%) | 10 (20%) | 14 (28%) | 10 (20%)
Artery, inflammation, chronic active | 22 (44%) | 32 (64%) | 27 (54%) | 21 (43%)
Salivary glands | (50) | (50) | (49) | (50)
Metaplasia | – | 1 (2%) | – | 2 (4%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Erosion | – | – | 1 (2%) | –
Hyperplasia | 19 (38%) | 19 (38%) | 19 (38%) | 22 (44%)
Inflammation | 2 (4%) | – | 4 (8%) | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Ulcer | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Epithelium, amyloid deposition | – | – | 1 (2%) | –
Epithelium, hyperplasia | 2 (4%) | 5 (10%) | 7 (14%) | 3 (6%)
Epithelium, inflammation | – | 1 (2%) | – | –
Epithelium, inflammation, chronic active | 3 (6%) | 4 (8%) | 2 (4%) | 1 (2%)
Epithelium, mineralization | 7 (14%) | 12 (24%) | 6 (12%) | 10 (20%)
Epithelium, necrosis | 1 (2%) | – | – | –
Epithelium, ulcer | – | 1 (2%) | – | –
Epithelium, muscularis, hyperplasia, focal | – | 1 (2%) | – | –
Tongue | (0) | (0) | (0) | (1)
Tooth | (1) | (0) | (1) | (0)
Malformation | – | – | 1 (100%) | –
Necrosis | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Dilatation | 1 (2%) | – | – | –
Inflammation, chronic active | 30 (60%) | 38 (76%) | 30 (60%) | 29 (58%)
Mineralization | – | 2 (4%) | 1 (2%) | 1 (2%)
Thrombosis | – | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 47 (94%) | 48 (96%) | 49 (98%) | 48 (96%)
Mineralization | 1 (2%) | – | – | 1 (2%)
Atrium, thrombosis | 1 (2%) | 3 (6%) | 3 (6%) | 3 (6%)
Epicardium, inflammation | 1 (2%) | 1 (2%) | – | –
Pericardium, inflammation | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Degeneration, cystic | 4 (8%) | 3 (6%) | 5 (10%) | 4 (8%)
Degeneration, fatty | 8 (16%) | 13 (27%) | 5 (10%) | 16 (32%)
Hematopoietic cell proliferation | – | – | 1 (2%) | –
Hemorrhage | – | – | 1 (2%) | –
Hyperplasia | 14 (28%) | 19 (39%) | 19 (38%) | 6 (12%)
Necrosis | 1 (2%) | – | – | 2 (4%)
Thrombosis | – | 1 (2%) | – | –
Adrenal medulla | (50) | (49) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Degeneration, fatty | – | 1 (2%) | – | –
Hyperplasia | 18 (36%) | 22 (45%) | 20 (40%) | 19 (38%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 3 (6%) | 6 (12%) | 1 (2%) | 3 (6%)
Parathyroid gland | (43) | (46) | (50) | (47)
Hyperplasia | 3 (7%) | 10 (22%) | 13 (26%) | 8 (17%)
Pituitary gland | (50) | (49) | (50) | (47)
Pars distalis, hyperplasia | 17 (34%) | 18 (37%) | 19 (38%) | 12 (26%)
Thyroid gland | (50) | (46) | (48) | (47)
Thrombosis | 1 (2%) | – | – | –
C-cell, hyperplasia | 6 (12%) | 4 (9%) | 4 (8%) | 5 (11%)
C-cell, hypertrophy | – | – | – | 1 (2%)
Follicular cell, hyperplasia | – | 1 (2%) | – | –
Follicular cell, hypertrophy | 21 (42%) | 34 (74%) | 33 (69%) | 36 (77%)
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (49) | (50)
Cyst | 7 (14%) | – | 3 (6%) | 5 (10%)
Fibrosis | 1 (2%) | – | – | –
Inflammation | 2 (4%) | – | – | 1 (2%)
Prostate | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | 1 (2%) | – | –
Fibrosis | 1 (2%) | 3 (6%) | 2 (4%) | 1 (2%)
Hyperplasia | 3 (6%) | 4 (8%) | 7 (14%) | 3 (6%)
Inflammation, acute | 1 (2%) | 6 (12%) | – | 6 (12%)
Inflammation, chronic active | – | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Seminal vesicle | (49) | (50) | (50) | (50)
Hypoplasia | – | – | 1 (2%) | –
Inflammation, acute | – | – | – | 2 (4%)
Testes | (49) | (50) | (50) | (50)
Atrophy | 30 (61%) | 37 (74%) | 35 (70%) | 33 (66%)
Pigmentation, hemosiderin | – | – | 1 (2%) | –
Artery, inflammation, chronic active | 28 (57%) | 34 (68%) | 33 (66%) | 33 (66%)
Interstitial cell, hyperplasia | 1 (2%) | – | 1 (2%) | 2 (4%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 2 (4%) | 4 (8%) | 3 (6%)
Lymph node | (4) | (8) | (8) | (6)
Angiectasis | – | – | – | 1 (17%)
Bronchial, hemorrhage | – | 1 (13%) | 1 (13%) | –
Deep cervical, hemorrhage | – | 1 (13%) | – | –
Deep cervical, hyperplasia, plasma cell | – | 1 (13%) | – | –
Deep cervical, inflammation | – | 1 (13%) | – | –
Iliac, infiltration cellular, histiocyte | – | – | 1 (13%) | –
Lumbar, hemorrhage | – | – | 2 (25%) | –
Mediastinal, ectasia | – | 1 (13%) | 1 (13%) | –
Mediastinal, hemorrhage | 1 (25%) | 2 (25%) | 3 (38%) | 1 (17%)
Mediastinal, hyperplasia, lymphoid | – | 1 (13%) | – | –
Mediastinal, infiltration cellular, lipocyte | – | – | – | 1 (17%)
Mediastinal, infiltration cellular, histiocyte | – | 1 (13%) | – | –
Mediastinal, pigmentation, hemosiderin | – | – | – | 1 (17%)
Pancreatic, hemorrhage | – | 1 (13%) | – | 1 (17%)
Renal, ectasia | 2 (50%) | – | – | –
Renal, hemorrhage | 1 (25%) | 2 (25%) | – | –
Renal, pigmentation, hemosiderin | – | – | – | 1 (17%)
Lymph node, mandibular | (50) | (50) | (49) | (50)
Ectasia | – | 1 (2%) | 1 (2%) | 1 (2%)
Hemorrhage | – | – | 1 (2%) | –
Hyperplasia, plasma cell | 1 (2%) | – | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Ectasia | – | 1 (2%) | – | –
Hemorrhage | – | 1 (2%) | – | –
Hyperplasia, lymphoid | 1 (2%) | – | – | 1 (2%)
Lymphatic, ectasia | – | – | 1 (2%) | 5 (10%)
Spleen | (50) | (50) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 28 (56%) | 33 (66%) | 28 (56%) | 29 (58%)
Inflammation | 1 (2%) | – | – | –
Necrosis | – | – | 1 (2%) | –
Thymus | (46) | (49) | (49) | (47)
Atrophy | 41 (89%) | 41 (84%) | 42 (86%) | 41 (87%)
Hemorrhage | – | – | 1 (2%) | –
Epithelial cell, hyperplasia | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Fibrosis | – | – | 1 (2%) | –
Inflammation | – | – | – | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 5 (10%) | 3 (6%) | 2 (4%) | 2 (4%)
Inflammation | 3 (6%) | 2 (4%) | – | 2 (4%)
Necrosis | – | 2 (4%) | – | –
Epidermis, ulcer | 1 (2%) | – | – | –
Sebaceous gland, hyperplasia | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibrous osteodystrophy | 12 (24%) | 19 (38%) | 13 (26%) | 8 (16%)
Maxilla, fracture | – | – | 1 (2%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | – | – | – | 1 (2%)
Gliosis | – | 2 (4%) | – | –
Necrosis | – | – | – | 2 (4%)
Spinal cord | (0) | (2) | (1) | (0)
Degeneration | – | 2 (100%) | 1 (100%) | –
Respiratory System
Lung | (49) | (50) | (50) | (50)
Edema | – | – | 1 (2%) | 1 (2%)
Fibrosis | – | – | – | 1 (2%)
Foreign body | – | 1 (2%) | 1 (2%) | –
Hemorrhage | – | – | 1 (2%) | 1 (2%)
Hemorrhage, multifocal | 3 (6%) | 3 (6%) | 7 (14%) | 7 (14%)
Inflammation, granulomatous | – | – | 1 (2%) | –
Inflammation, chronic | 17 (35%) | 21 (42%) | 24 (48%) | 23 (46%)
Mineralization | – | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Alveolar epithelium, hyperplasia | 1 (2%) | – | 1 (2%) | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 19 (39%) | 22 (44%) | 19 (38%) | 13 (26%)
Alveolus, mineralization | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Foreign body | 4 (8%) | 12 (24%) | 11 (22%) | 10 (20%)
Fungus | 1 (2%) | – | – | –
Inflammation | 1 (2%) | – | – | –
Inflammation, chronic active | 11 (22%) | 15 (30%) | 16 (32%) | 15.(30%)
Thrombosis | – | 1 (2%) | – | –
Respiratory epithelium, hyperplasia | 2 (4%) | 2.(4%) | 4 (8%) | 7 (14%)
Respiratory epithelium, metaplasia, squamous | – | – | 2 (4%) | –
Trachea | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 1.(2%) | 1 (2%) | –
Special Senses System
Ear | (0) | (0) | (1) | (0)
External ear, hyperplasia, squamous | – | – | 1 (100%) | –
Eye | (50) | (50) | (49) | (49)
Cataract | – | – | – | 1 (2%)
Anterior chamber, inflammation, acute | 2 (4%) | 1 (2%) | 4 (8%) | 3 (6%)
Cornea, inflammation, acute | 20 (40%) | 25 (50%) | 17 (35%) | 21 (43%)
Retina, fibrosis | – | – | – | 1 (2%)
Harderian gland | (50) | (50) | (49) | (50)
Angiectasis | – | – | – | 1 (2%)
Pigmentation, porphyrin | 1 (2%) | – | – | –
Lacrimal gland | (1) | (2) | (4) | (0)
Degeneration | 1 (100%) | 2 (100%) | 4 (100%) | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Metaplasia, osseous | – | 1 (2%) | – | –
Nephropathy | 50 (100%) | 49 (98%) | 49 (98%) | 50 (100%)
Renal tubule, dilatation | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Hemorrhage | – | – | – | 1 (2%)
Inflammation | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.