# Overview of Water Disinfection By-products Program

The disinfection of drinking water by chlorination or chloramination leads to the production of halogenated by-products. The disinfection by-products are produced by interactions with reactive chlorine and humic acids derived from algae and the breakdown of vegetative matter. The composition of the by-products depends on the disinfection process and the source water. There are seasonal variations in concentrations of disinfection by-products due to increased algal blooms in warmer weather. Source water high in bromine will contain higher concentrations of bromo- and mixed chloro/bromo disinfection by-products. Several epidemiologic studies suggest an association between exposure to disinfection by-products and bladder cancer and reproductive toxicity.^1,2^ To better understand the risks associated with exposure to disinfection by-products, the American Water Works Association Research Foundation, the United States Environmental Protection Agency (USEPA), and others have nominated disinfection by-products for study by the NTP. In response to this nomination, the NTP developed a plan to evaluate the potential human health effects of various disinfection by-products. At the start of this program, many of the disinfection by-products in finished drinking water were unidentified. Thus, the initial focus was on the chlorinated and brominated trihalomethanes, haloacetic acids, and the oxyhalides. There are four chloro/bromo trihalomethanes [trichloromethane (chloroform), tribromomethane (bromoform), bromodichloromethane, and chlorodibromomethane], nine chloro/bromo haloacetic acids (mono-, di-, and trichloroacetic acids; mono-, di- and tribromoacetic acids; bromochloroacetic acid, bromodichloroacetic acid, and dibromochloroacetic acid), and three oxyhalides (bromate, chlorate, and chlorite).

Since these chemicals were nominated for toxicity and carcinogenicity studies, mouse and rat cancer bioassays were performed by the NTP on all chemicals except bromoacetic acid, dichloroacetic acid, trichloroacetic acid, tribromoacetic acid, bromate, and chlorite. Bioassay data are available in the peer-reviewed literature for dichloroacetic acid, trichloroacetic acid, bromate, and chlorite (reviewed in Richardson et al.^1^). Dichloroacetic acid induced liver neoplasms in rats^3^ and mice,^3,4^ while trichloroacetic acid induced liver neoplasms only in mice.^4,5^ In mice, bromate increased the incidences of renal neoplasms^6^; in rats, it increased the incidences of renal and thyroid tumors as well as mesotheliomas.^7^ Sodium chlorite was negative in both rats and mice.^8,9^ Bromoacetic acid and tribromoacetic acid do not have chronic toxicity and carcinogenicity studies.

The NTP has evaluated the toxicity and carcinogenicity of all the trihalomethanes. When administered in corn oil by gavage, all four trihalomethanes were carcinogenic in rats and/or mice (Table 1). Trichloromethane (chloroform)^10^ and bromodichloromethane^11-13^ both produced renal tubule adenomas and adenocarcinomas in rats while bromodichloromethane induced these tumors in rats and mice. In mice, liver tumors were observed with trichloromethane (chloroform) (male and female), bromodichloromethane (female) and chlorodibromomethane (male and female).^14^ When administered in drinking water, no evidence of carcinogenicity was observed in male rats and female mice receiving bromodichloromethane.^12^ However, average daily exposures in the drinking water studies of bromodichloromethane are approximately fourfold lower than those of the corn oil gavage studies, and the lower dose levels may explain the discrepancy of the cancer findings between the two studies. Tribromomethane (bromoform) only increased the incidence of neoplasms of the large intestine in male and female rats, and in mice there was no evidence of a carcinogenic effect.^15^

Table 1 NTP Water Disinfection By-product Program^a^

Chemical (CAS #) | Maximum Contaminant Level^b^ | Study Conditions | Carcinogenicity (Clear Evidence or Some Evidence) | Genetic Toxicology
Trihalomethanes
Trichloromethane (Chloroform) (67-66-3) | Sum of the concentrations of all four trihalomethanes as an annual average: 0.080 mg/L or 80 ppb | By corn oil gavage^10^ [underlined: Rats]: males (0, 90 or 180 mg/kg per day); females (0, 100 or 200 mg/kg per day) [underlined: Mice]: males (0, 138 or 277 mg/kg per day); females (0, 238, or 477 mg/kg per day) | [underlined: Rats]: renal tubule adenoma and adenocarcinoma (males) [underlined: Mice]: hepatocellular carcinoma (males and females) | CHO cell sister chromatid exchange: negative CHO cell chromosome aberration: equivocal Salmonella typhimurium: negative Rodent bone marrow cytogenetics chromosome aberrations: negative Rodent bone marrow cytogenetics sister chromosome exchange: equivocal Mouse lymphoma: positive Micronucleus, male mouse: positive
Tribromomethane (Bromoform) (75-25-2) | | By corn oil gavage^15^ [underlined: Rats]: males and females (0, 100, or 200 mg/kg per day) [underlined: Mice]: males (0, 50, or 100 mg/kg per day); females (0, 100, or 200 mg/kg per day) | [underlined: Rats]: uncommon neoplasms of the large intestine (males and females) [underlined: Mice]: no evidence | CHO cell sister chromatid exchange: weakly positive CHO cell chromosome aberration: negative Salmonella typhimurium: positive Rodent bone marrow cytogenetics chromosome aberrations: negative Rodent bone marrow cytogenetics sister chromosome exchange: positive Mouse lymphoma: positive Micronucleus, male mouse: negative Drosophila sex-linked recessive lethal: positive Drosophila reciprocal translocations: negative Drosophila sex-linked recessive lethal: positive Drosophila reciprocal translocations: negative
Bromodichloromethane (75-27-4) | | In drinking water^12^ [underlined: Rats]: males only (0, 6, 12, or 25 mg/kg per day) [underlined: Mice]: females only (0, 9, 18, or 36 mg/kg per day) | [underlined: Rats]: no evidence [underlined: Mice]: no evidence | CHO cell sister chromatid exchange: equivocal CHO cell chromosome aberration: negative Salmonella typhimurium: negative Rodent bone marrow cytogenetics chromosome aberrations: negative Rodent bone marrow cytogenetics sister chromosome exchange: positive Mouse lymphoma: positive Micronucleus, mouse: negative
| | By corn oil gavage^11^ [underlined: Rats]: males and females (0, 50, or 100 mg/kg per day) [underlined: Mice]: males (0, 25, or 50 mg/kg per day); females (0, 75, or 150 mg/kg per day) | [underlined: Rats]: renal tubule cell adenocarcinoma (males and females); large intestine adenocarcinoma (males and females) [underlined: Mice]: renal tubule cell adenoma and adenocarcinoma (males) hepatocellular adenoma and adenocarcinoma (females)
| | By dermal application, in drinking water, or by corn oil gavage^13^ [underlined: FVB Tg.AC hemizygous mice]: Dermal (0,64, 128, or 256 mg/kg per day) Drinking water (males: 0, 20, 36, or 61 mg/kg per day; females: 0, 31, 61, or 130 mg/kg per day) Gavage (0, 25, 50, or 100 mg/kg per day) | [underlined: FVB Tg.AC hemizygous mice]: no evidence
| | [underlined: B6.129-][underlined: Trp53][underlined: ^tm1Brd^ (N5) haploinsufficient mice]: Drinking water (males: 0, 16, 31, or 65 mg/kg per day; females: 0, 26, 50, or 100 mg/kg per day) Gavage (0, 25, 50, or 100 mg/kg per day) | [underlined: B6.129-][underlined: Trp53][underlined: ^tm1Brd^ (N5) haploinsufficient mice]: no evidence
Chlorodibromomethane (124-48-1) | | By corn oil gavage^14^ [underlined: Rats]: males and females (0, 40, or 80 mg/kg per day) [underlined: Mice]: males and females (0, 50, or 100 mg/kg per day) | [underlined: Rats]: no evidence [underlined: Mice]: hepatocellular adenoma or carcinoma (females) | CHO cell sister chromatid exchange: positive CHO cell chromosome aberration: negative Salmonella typhimurium: weakly positive Rodent bone marrow cytogenetics chromosome aberrations: positive Rodent bone marrow cytogenetics sister chromosome exchange: negative Mouse lymphoma: positive Micronucleus, male mouse: negative Drosophila sex-linked recessive lethal: positive Drosophila sex-linked recessive lethal: negative
Regulated Haloacetic Acids
Monochloroacetic acid (79-11-8) | Sum of the concentrations of all five regulated haloacetic acids as an annual average: 0.060 mg/L or 60 ppb | By water gavage^17^ [underlined: Rats]: 0, 15, or 30 mg/kg per day [underlined: Mice]: 0, 50, or 100 mg/kg per day | [underlined: Rats]: no evidence [underlined: Mice]: no evidence | CHO cell sister chromatid exchange: weakly positive CHO cell chromosome aberration: negative Salmonella typhimurium: negative Mouse lymphoma: positive Micronucleus, male mouse: negative Drosophila sex-linked recessive lethal: positive Drosophila reciprocal translocations: negative Drosophila sex-linked recessive lethal: equivocal
Monobromoacetic acid (79-08-3) | | Not tested by the NTP | | Salmonella typhimurium: positive
Dichloroacetic acid (79-43-6) | Sum of the concentrations of all five regulated haloacetic acids as an annual average: 0.060 mg/L or 60 ppb | By dermal application or in drinking water^16^ [underlined: FVB Tg.AC hemizygous mice]: Dermal (0, 31.25, 125, or 500 mg/kg per day) Drinking water (males: 0, 75, 145, or 265 mg/kg per day; females: 0, 100, 185, or 285 mg/kg per day) [underlined: B6.129-][underlined: Trp53][underlined: ^tm1Brd^ (N5) haploinsufficient mice]: Drinking water (males: 0, 16, 31, or 65 mg/kg per day; females: 0, 26, 50, or 100 mg/kg per day) | [underlined: FVB Tg.AC hemizygous mice]: Dermal: increased incidences of squamous cell papilloma (males and females) Drinking water: marginally increased incidences of alveolar/bronchiolar tumors (males and females) [underlined: B6.129-][underlined: Trp53][underlined: ^tm1Brd^ (N5) haploinsufficient mice]: no evidence | Salmonella typhimurium: positive Mouse micronuclei: negative
Dibromoacetic acid (631-64-1) | | In drinking water^18^ [underlined: Rats]: males (0, 2, 20, or 40 mg/kg per day); females (0, 2, 25, or 45 mg/kg per day) [underlined: Mice]: males (0, 4, 45, or 87 mg/kg per day); females (0, 4, 35, or 67 mg/kg per day) | [underlined: Rats]: malignant mesothelioma (males) and mononuclear cell leukemia (females) [underlined: Mice]: hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma (males and females); alveolar/bronchiolar adenoma (males) | Salmonella typhimurium: positive Mouse micronuclei: positive
Trichloroacetic acid (76-03-9) | | Not tested by the NTP | | Salmonella typhimurium: negative
Unregulated Haloacetic Acids
Bromochloroacetic acid (5589-96-8) | Not regulated | In drinking water^19^ [underlined: Rats]: males (0, 10, 20, or 40 mg/kg per day); females (0, 13, 25, or 50 mg/kg per day) [underlined: Mice]: males (0, 20, 50, or 90 mg/kg per day); females (0, 15, 30, or 60 mg/kg per day) | [underlined: Rats]: malignant mesothelioma (males); large intestine adenomas (males and females); mammary gland (females) [underlined: Mice]: hepatocellular adenoma, carcinoma (males and females); hepatoblastoma (males) | Salmonella typhimurium: positive Mouse micronuclei: negative
Tribromoacetic acid (75-96-7) | Not regulated | Not tested by the NTP | Not tested | Salmonella typhimurium: positive
Bromodichloroacetic acid (71133-14-7) | Not regulated | In drinking water [current report] [underlined: Rats (F344/NTac)]: males (0, 11, 21, or 43 mg/kg per day); females (0, 13, 28, or 57 mg/kg per day) [underlined: Mice]: males (0, 23, 52, or 108 mg/kg per day); females (0, 17, 34, or 68 mg/kg per day) | [underlined: Rats]: malignant mesothelioma and skin neoplasia (males); mammary gland (females) [underlined: Mice]: hepatocellular carcinoma and hepatoblastoma (males and females); Harderian gland (males) | Salmonella typhimurium: positive Mouse micronuclei: negative
Chlorodibromoacetic acid (5728-95-5) | Not regulated | Not tested by the NTP | | On test
Oxyhalides
Sodium bromate (7789-38-0) | 0.010 mg/L or 10 ppb as an annual average | By dermal application or in drinking water^20^ [underlined: FVB Tg.AC hemizygous mice]: Dermal (0, 64, 128, or 256 mg/kg per day in ethanol) Drinking water (males: 0, 13, 63, or 129 mg/kg per day; females: 0, 15, 72, or 148 mg/kg per day) [underlined: B6.129-][underlined: Trp53][underlined: ^tm1Brd^ (N5) haploinsufficient mice]: Drinking Water (males: 0, 16, 31, or 65 mg/kg per day; females: 0, 26, 50, or 100 mg/kg per day) | [underlined: FVB Tg.AC hemizygous mice]: no evidence [underlined: B6.129-][underlined: Trp53][underlined: ^tm1Brd^ (N5) haploinsufficient mice]: no evidence | Mouse micronuclei: positive in FVB Tg.AC hemizygous and B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice
Sodium chlorite (7758-19-2) | 1.0 mg/L or 1 ppm | Not tested by the NTP | Not tested | Not tested
Sodium chlorate (7775-09-9) | Not regulated | In drinking water^21^ [underlined: Rats]: males (0, 5, 35, or 75 mg/kg per day); females (0, 5, 45, or 95 mg/kg per day) [underlined: Mice]: males (0, 40, 80, or 160 mg/kg per day); females (0, 30, 60, or 120 mg/kg per day) | [underlined: Rats]: thyroid gland follicular cell carcinoma (male) or adenoma (female) [underlined: Mice]: none | Salmonella typhimurium: negative Mouse micronuclei: negative

^a^ Unless otherwise stated, rats are F344/N and mice are B6C3F1.

^b^ Maximum concentration levels are set as close to the health goals as possible, considering cost, benefits, and the ability of public water systems to detect and remove contaminants using suitable treatment technologies.

Of the nine haloacetic acids, the NTP has evaluated four (monochloroacetic acid, dibromoacetic acid, bromochloroacetic acid and bromodichloroacetic acid) for toxicity and carcinogenicity in rats and mice. Dichloroacetic acid was evaluated using the genetically modified mouse models.^16^ Monochloroacetic acid was not carcinogenic in either rats or mice.^17^ Dibromoacetic acid,^18^ bromochloroacetic acid,^19^ and bromodichloroacetic acid (current study) increased the incidences of malignant mesothelioma in male rats, and all three also increased the incidences of hepatocellular carcinoma and hepatoblastoma in either male or female mice. Bromochloroacetic acid and bromodichloroacetic acid also increased the incidences of mammary gland fibroadenoma in female rats, but dibromoacetic acid did not.

In general, the trihalomethanes and haloacetic acids evaluated by the NTP increased the incidence of mouse liver tumors. Renal tumors in rats and mice may be a common finding for the trihalomethanes, while malignant mesotheliomas in male rats may be a common finding for the brominated haloacetic acids.

The NTP also ran screening-level reproductive and developmental studies and immunotoxicity screens on several of the disinfection by-products. The results from these screens are used to aid in prioritization of disinfection by-products for further testing. The reproductive and developmental screens were typically performed on one rodent species/chemical and examined the reproductive effects on adult males and females. During the past decade, numerous studies of the developmental effects of specific disinfection by-products have become available (reviewed in Colman et al.^2^), and the need for further reproductive and developmental toxicity studies of disinfection by-products conducted by the NTP will be considered in light of the published reports.

The immunotoxicity screens consisted of 28-day repeat dose studies in one gender of rats or mice. These studies evaluated immune parameters such as T-cell dependent antibody response and natural killer cell activity as well as hematology and organ weights. Only five of the 16 disinfection by-products under consideration at the NTP have been evaluated in these immunotoxicity screens, and only dibromoacetic acid produced results consistent with an immunotoxic potential. Since the beginning of the disinfection by-product program, a number of other classes of disinfection by-products have been identified, including the iodinated trihalomethanes and acetic acids, halonitriles, and N-nitrosamines.^1^