# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-583

Report Series: NTP Technical Report Series

Report Series Number: 583

Official citation: National Toxicology Program (NTP). 2015. NTP technical report on the toxicology studies of bromodichloroacetic acid (CASRN 71133-14-7) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of bromodichloroacetic acid in F344/NTac rats and B6C3F1/N mice (drinking water studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 583.