# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M.J. DeVito, Ph.D., Study Scientist
  S. Bhusari, B.V.Sc. & A.H., Ph.D.
  C.R. Blystone, M.S., Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hoenerhoff, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.R. Pandiri, B.V.Sc. & A.H., Ph.D., Co-study Pathologist
- ILS, Inc. Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A. Nyska, D.V.M., Co-study Pathologist
- Southern Research Institute, Birmingham, Alabama, USA
  Conducted 2-week and 3-month studies and evaluated pathology findings
  C.D. Hébert, Ph.D., Principal Investigator
  W.R. Richter, D.V.M., M.S., Principal Investigator
  D.R. Farnell, D.V.M., M.S., Ph.D.
  J.E. Heath, D.V.M.
  R.B. Thompson, D.V.M., Ph.D.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted 2-year studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  A.J. Skowronek, D.V.M., Ph.D.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  A.E. Brix, D.V.M., Ph.D.
  J.F. Hardisty, D.V.M.
  H.M. Kolenda-Roberts, D.V.M., Ph.D.
  P.B. Little, D.V.M., M.S., Ph.D.
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups on 2-year rats (March 20, 2012) and mice (July 12, 2011; August 17, 2011; and March 20, 2012)
  C.L. Johnson, D.V.M.
- TherImmune Research Corporation, Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  G.W. Wolfe, Ph.D., Principal Investigator
  H.S. Seung, M.Sc.
  Y. Wang, M.S.