# References

1 Richardson SD Plewa MJ Wagner ED Schoeny R Demarini DM Occurrence, genotoxicity, and carcinogenicity of regulated and emerging disinfection by-products in drinking water: a review and roadmap for research. Mutat Res. 2007;636(1-3):178–242. http://dx.doi.org/10.1016/j.mrrev.2007.09.001 17980649
2 Colman J Rice GE Wright JM Hunter ES 3rd Teuschler LK Lipscomb JC Hertzberg RC Simmons JE Fransen M Osier M Identification of developmentally toxic drinking water disinfection byproducts and evaluation of data relevant to mode of action. Toxicol Appl Pharmacol. 2011;254(2):100–126. http://dx.doi.org/10.1016/j.taap.2011.02.002 21296098
3 DeAngelo AB Daniel FB Most BM Olson GR The carcinogenicity of dichloroacetic acid in the male Fischer 344 rat. Toxicology. 1996;114(3):207–221. http://dx.doi.org/10.1016/S0300-483X(96)03510-X 8980710
4 Bull RJ Sanchez IM Nelson MA Larson JL Lansing AJ Liver tumor induction in B6C3F1 mice by dichloroacetate and trichloroacetate. Toxicology. 1990;63(3):341–359. http://dx.doi.org/10.1016/0300-483X(90)90195-M 2219130
5 DeAngelo AB Daniel FB Most BM Olson GR Failure of monochloroacetic acid and trichloroacetic acid administered in the drinking water to produce liver cancer in male F344/N rats. J Toxicol Environ Health. 1997;52(5):425–445. 9388534
6 DeAngelo AB George MH Kilburn SR Moore TM Wolf DC Carcinogenicity of potassium bromate administered in the drinking water to male B6C3F1 mice and F344/N rats. Toxicol Pathol. 1998;26(5):587–594. http://dx.doi.org/10.1177/019262339802600501 9789944
7 Kurokawa Y Hayashi Y Maekawa A Takahashi M Kokubo T Odashima S Carcinogenicity of potassium bromate administered orally to F344 rats. J Natl Cancer Inst. 1983;71(5):965–972. 6580498
8 Kurokawa Y Takayama S Konishi Y Hiasa Y Asahina S Takahashi M Maekawa A Hayashi Y Long-term in vivo carcinogenicity tests of potassium bromate, sodium hypochlorite, and sodium chlorite conducted in Japan. Environ Health Perspect. 1986;69:221–235. http://dx.doi.org/10.1289/ehp.8669221 3816726
9 Yokose Y Uchida K Nakae D Shiraiwa K Yamamoto K Konishi Y Studies of carcinogenicity of sodium chlorite in B6C3F1 mice. Environ Health Perspect. 1987;76:205–210. http://dx.doi.org/10.1289/ehp.8776205 3447900
10 National Cancer Institute (NCI). Report on the carcinogenesis bioassay of chloroform (CAS No. 67-66-3). Bethesda, MD: U.S. Department of Health, Education, and Welfare, Public Health Service, National Institutes of Health; 1976. NTIS Report No. PB2640-18. DHEW Publication No. 76-1279.
11 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of bromodichloromethane (CAS No. 75-27-4) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1987. Technical Report Series No. 321. NIH Publication No. 88-2537.
12 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of bromodichloromethane (CAS No. 75-27-4) in male F344/N rats and female B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 532. NIH Publication No. 06-4468.
13 National Toxicology Program (NTP). Toxicology studies of bromodichloromethane (CAS No. 75-27-4) in genetically modified (FVB Tg.AC Hemizygous) mice (dermal, drinking water, and gavage studies) and carcinogenicity studies of bromodichloromethane in genetically modified [B6.129-Trp53(tm1Brd) (N5) haploinsufficient] mice (drinking water and gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2007. Report Series No. GMM-5. NIH Publication No. 07-4422.
14 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of chlorodibromomethane (bromoform) (CAS No. 124481) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1985. Technical Report Series No. 282. NIH Publication No. 85-2538.
15 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of tribromomethane (bromoform) (CAS No. 75-25-2) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1989. Technical Report Series No. 350. NIH Publication No. 89-2805.
16 National Toxicology Program (NTP). Toxicology studies of dichloroacetic acid (CAS No. 79-43-6) in genetically modified (FVB Tg.AC hemizygous) mice (dermal and drinking water studies) and carcinogenicity studies of dichloroacetic acid in genetically modified [B6.129-Trp53tm1Brd (N5) haploinsufficient] mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2007. Report Series No. GMM-11. NIH Publication No. 07-4428.
17 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of monochloroacetic acid (CAS No. 79-11-8) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1992. Technical Report Series No. 396. NIH Publication No. 92-2851.
18 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of dibromoacetic acid (CAS No. 631-64-1) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2007. Technical Report Series No. 537. NIH Publication No. 07-4475.
19 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of bromo-chloroacetic acid (CAS No. 5589-96-8) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2009. Technical Report Series No. 549. NIH Publication No. 09-5890.
20 National Toxicology Program (NTP). Toxicology studies of sodium bromate (CAS No. 7789-38-0) in genetically modified (FVB Tg.AC hemizygous) mice (dermal and drinking water studies) and carcinogenicity studies of sodium bromate in genetically modified [B6.129-Trp53tm1Brd (N5) haploinsufficient] mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2007. Report Series No. GMM-6. NIH Publication No. 07-4423.
21 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of sodium chlorate (CAS No. 7775-09-9) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2005. Technical Report Series No. 517. NIH Publication No. 06-4457.
22 Sigma-Aldrich. Material data safety sheet for bromodichloroacetic acid. 2012. https://www.sigmaaldrich.com/MSDS/MSDS/DisplayMSDSPage.do?country=US&language=en&productNumber=442499&brand=SUPELCO&PageToGoToURL=http%3A%2F%2Fwww.sigmaaldrich.com%2Fcatalog%2Fproduct%2Fsupelco%2F442499%3Flang%3Den [Accessed: May 31, 2013]
23 Schultz IR Merdink JL Gonzalez-Leon A Bull RJ Comparative toxicokinetics of chlorinated and brominated haloacetates in F344 rats. Toxicol Appl Pharmacol. 1999;158(2):103–114. http://dx.doi.org/10.1006/taap.1999.8698 10406925
24 Urbansky ET. Letter to the editor: Disinfection byproducts in drinking water. Anal Chem. 2000; 72(13):439A-440A.
25 Hazardous Substances Data Bank (HSDB). Bromodichloroacetic acid. TOXNET: Toxicology Data Network. National Library of Medicine; 2013. https://toxnet.nlm.nih.gov/cgi-bin/sis/search2/f?./temp/~zXHOUq:1 [Accessed: April 9, 2013]
26 Liang L Singer PC Factors influencing the formation and relative distribution of haloacetic acids and trihalomethanes in drinking water. Environ Sci Technol. 2003;37(13):2920–2928. http://dx.doi.org/10.1021/es026230q 12875395
27 Huang WJ Chen LY Peng HS Effect of NOM characteristics on brominated organics formation by ozonation. Environ Int. 2004;29(8):1049–1055. http://dx.doi.org/10.1016/S0160-4120(03)00099-0 14680887
28 Urbansky ET The fate of the haloacetates in drinking water—chemical kinetics in aqueous solution. Chem Rev. 2001;101(11):3233–3243. http://dx.doi.org/10.1021/cr000883c 11840985
29 Code of Federal Regulations (CFR). 40:Part 141.164.
30 Weinberg HS, Krasner SW, Richardson S, Thruston AD. The occurrence of disinfection by-products (DBPs) of health concern in drinking water: Results of a nationwide DBP occurrence study. Athens GA: U.S. Environmental Protection Agency; 2002. EPA/600/R-02/068.
31 Environmental Working Group (EWG). National drinking water database: Study findings. 2009. https://www.ewg.org/tap-water/reportfindings.php [Accessed: December, 2009]
32 James MO Yan Z Cornett R Jayanti VM Henderson GN Davydova N Katovich MJ Pollock B Stacpoole PW Pharmacokinetics and metabolism of [14C]dichloroacetate in male Sprague-Dawley rats. Identification of glycine conjugates, including hippurate, as urinary metabolites of dichloroacetate. Drug Metab Dispos. 1998;26(11):1134–1143. 9806957
33 Saghir SA Schultz IR Toxicokinetics and oral bioavailability of halogenated acetic acids mixtures in naïve and GSTzeta-depleted rats. Toxicol Sci. 2005;84(2):214–224. http://dx.doi.org/10.1093/toxsci/kfi070 15625187
34 Xu G Stevens DK Bull RJ Metabolism of bromodichloroacetate in B6C3F1 mice. Drug Metab Dispos. 1995;23(12):1412–1416. 8689953
35 Merdink JL Bull RJ Schultz IR Toxicokinetics of bromodichloroacetate in B6C3F1 mice. J Appl Toxicol. 2001;21(1):53–57. http://dx.doi.org/10.1002/jat.732 11180280
36 Saghir SA Ghanayem BI Schultz IR Kinetics of trihalogenated acetic acid metabolism and isoform specificity in liver microsomes. Int J Toxicol. 2011;30(5):551–561. http://dx.doi.org/10.1177/1091581811414213 21933969
37 Kato-Weinstein J Stauber AJ Orner GA Thrall BD Bull RJ Differential effects of dihalogenated and trihalogenated acetates in the liver of B6C3F1 mice. J Appl Toxicol. 2001;21(2):81–89. http://dx.doi.org/10.1002/jat.717 11288130
38 Walgren JL Jollow DJ McMillan JM Induction of peroxisome proliferation in cultured hepatocytes by a series of halogenated acetates. Toxicology. 2004;197(3):189–197. http://dx.doi.org/10.1016/j.tox.2004.01.007 15033542
39 Melnick RL Nyska A Foster PM Roycroft JH Kissling GE Toxicity and carcinogenicity of the water disinfection byproduct, dibromoacetic acid, in rats and mice. Toxicology. 2007;230(2-3):126–136. http://dx.doi.org/10.1016/j.tox.2006.11.006 17157429
40 Moser VC Phillips PM Levine AB McDaniel KL Sills RC Jortner BS Butt MT Neurotoxicity produced by dibromoacetic acid in drinking water of rats. Toxicol Sci. 2004;79(1):112–122. http://dx.doi.org/10.1093/toxsci/kfh081 14976349
41 Moser VC Phillips PM McDaniel KL MacPhail RC Behavioral evaluation of the neurotoxicity produced by dichloroacetic acid in rats. Neurotoxicol Teratol. 1999;21(6):719–731. http://dx.doi.org/10.1016/S0892-0362(99)00029-X 10560779
42 Balchak SK Hedge JM Murr AS Mole ML Goldman JM Influence of the drinking water disinfection by-product dibromoacetic acid on rat estrous cyclicity and ovarian follicular steroid release in vitro. Reprod Toxicol. 2000;14(6):533–539. http://dx.doi.org/10.1016/S0890-6238(00)00104-0 11099878
43 Klinefelter GR Strader LF Suarez JD Roberts NL Bromochloroacetic acid exerts qualitative effects on rat sperm: implications for a novel biomarker. Toxicol Sci. 2002;68(1):164–173. http://dx.doi.org/10.1093/toxsci/68.1.164 12075119
44 Linder RE Klinefelter GR Strader LF Suarez JD Roberts NL Spermatotoxicity of dichloroacetic acid. Reprod Toxicol. 1997;11(5):681–688. http://dx.doi.org/10.1016/S0890-6238(97)00031-2 9311576
45 Linder RE Klinefelter GR Strader LF Suarez JD Roberts NL Dyer CJ Spermatotoxicity of dibromoacetic acid in rats after 14 daily exposures. Reprod Toxicol. 1994;8(3):251–259. http://dx.doi.org/10.1016/0890-6238(94)90009-4 8075514
46 Linder RE Klinefelter GR Strader LF Suarez JD Dyer CJ Acute spermatogenic effects of bromoacetic acids. Fundam Appl Toxicol. 1994;22(3):422–430. http://dx.doi.org/10.1006/faat.1994.1048 8050637
47 Linder RE Klinefelter GR Strader LF Veeramachaneni DN Roberts NL Suarez JD Histopathologic changes in the testes of rats exposed to dibromoacetic acid. Reprod Toxicol. 1997;11(1):47–56. http://dx.doi.org/10.1016/S0890-6238(96)00196-7 9138633
48 Tully DB Luft JC Rockett JC Ren H Schmid JE Wood CR Dix DJ Reproductive and genomic effects in testes from mice exposed to the water disinfectant byproduct bromochloroacetic acid. Reprod Toxicol. 2005;19(3):353–366. http://dx.doi.org/10.1016/j.reprotox.2004.06.009 15686870
49 Linder RE Klinefelter GR Strader LF Narotsky MG Suarez JD Roberts NL Perreault SD Dibromoacetic acid affects reproductive competence and sperm quality in the male rat. Fundam Appl Toxicol. 1995;28(1):9–17. http://dx.doi.org/10.1006/faat.1995.1140 8566488
50 Kaydos EH Suarez JD Roberts NL Bobseine K Zucker R Laskey J Klinefelter GR Haloacid induced alterations in fertility and the sperm biomarker SP22 in the rat are additive: validation of an ELISA. Toxicol Sci. 2004;81(2):430–442. http://dx.doi.org/10.1093/toxsci/kfh218 15254336
51 National Toxicology Program (NTP). Short term reproductive and developmental toxicity of bromochloroacetic acid (CAS No. 5589-96-8) administered in the drinking water to Sprague-Dawley rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1998. NTP Study Number RDGT96001. NTIS #PB98-172414.
52 Cummings AM Hedge JM Dibromoacetic acid does not adversely affect early pregnancy in rats. Reprod Toxicol. 1998;12(4):445–448. http://dx.doi.org/10.1016/S0890-6238(98)00025-2 9717694
53 Goldman JM Murr AS Dibromoacetic acid-induced elevations in circulating estradiol: effects in both cycling and ovariectomized/steroid-primed female rats. Reprod Toxicol. 2003;17(5):585–592. http://dx.doi.org/10.1016/S0890-6238(03)00068-6 14555197
54 Bodensteiner KJ Sawyer HR Moeller CL Kane CM Pau KY Klinefelter GR Veeramachaneni DN Chronic exposure to dibromoacetic acid, a water disinfection byproduct, diminishes primordial follicle populations in the rabbit. Toxicol Sci. 2004;80(1):83–91. http://dx.doi.org/10.1093/toxsci/kfh135 15141106
55 Klinefelter GR Strader LF Suarez JD Roberts NL Goldman JM Murr AS Continuous exposure to dibromoacetic acid delays pubertal development and compromises sperm quality in the rat. Toxicol Sci. 2004;81(2):419–429. http://dx.doi.org/10.1093/toxsci/kfh217 15254335
56 Christian MS York RG Hoberman AM Diener RM Fisher LC Gates GA Biodisposition of dibromoacetic acid (DBA) and bromodichloromethane (BDCM) administered to rats and rabbits in drinking water during range-finding reproduction and developmental toxicity studies. Int J Toxicol. 2001;20(4):239–253. http://dx.doi.org/10.1080/109158101750408064 11563419
57 Christian MS York RG Hoberman AM Frazee J Fisher LC Brown WR Creasy DM Oral (drinking water) two-generation reproductive toxicity study of dibromoacetic acid (DBA) in rats. Int J Toxicol. 2002;21(4):237–276. http://dx.doi.org/10.1080/10915810290096432 12171628
58 Hunter ES 3rd Rogers EH Schmid JE Richard A Comparative effects of haloacetic acids in whole embryo culture. Teratology. 1996; 54(2):57-64. 10.1002/(SICI)1096-9926(199606)54:2%3C57::AID-TERA1%3E3.0.CO;2-1
59 Hunter ES 3rd Blanton MR Rogers EH Leonard Mole M Andrews J Chernoff N Short-term exposures to dihaloacetic acids produce dysmorphogenesis in mouse conceptuses in vitro. Reprod Toxicol. 2006;22(3):443–448. http://dx.doi.org/10.1016/j.reprotox.2006.01.001 16527447
60 Hunter ES 3rd Rogers E Blanton M Richard A Chernoff N Bromochloro-haloacetic acids: effects on mouse embryos in vitro and QSAR considerations. Reprod Toxicol. 2006;21(3):260–266. http://dx.doi.org/10.1016/j.reprotox.2005.09.012 16293395
61 Richardson SD Thruston AD Jr Krasner SW Weinberg HS Miltner RJ Schenck KM Narotsky MG McKague AB Simmons JE Integrated disinfection by-products mixtures research: comprehensive characterization of water concentrates prepared from chlorinated and ozonated/postchlorinated drinking water. J Toxicol Environ Health A. 2008;71(17):1165–1186. http://dx.doi.org/10.1080/15287390802182417 18636390
62 Narotsky MG Klinefelter GR Goldman JM Best DS McDonald A Strader LF Suarez JD Murr AS Thillainadarajah I Hunter ES 3rd Comprehensive assessment of a chlorinated drinking water concentrate in a rat multigenerational reproductive toxicity study. Environ Sci Technol. 2013;47(18):10653–10659. http://dx.doi.org/10.1021/es402646c 23909560
63 Nieuwenhuijsen MJ Toledano MB Eaton NE Fawell J Elliott P Chlorination disinfection byproducts in water and their association with adverse reproductive outcomes: a review. Occup Environ Med. 2000;57(2):73–85. http://dx.doi.org/10.1136/oem.57.2.73 10711274
64 King WD Dodds L Allen AC Armson BA Fell D Nimrod C Haloacetic acids in drinking water and risk for stillbirth. Occup Environ Med. 2005;62(2):124–127. http://dx.doi.org/10.1136/oem.2004.013797 15657195
65 Hoffman CS Mendola P Savitz DA Herring AH Loomis D Hartmann KE Singer PC Weinberg HS Olshan AF Drinking water disinfection by-product exposure and duration of gestation. Epidemiology. 2008;19(5):738–746. http://dx.doi.org/10.1097/EDE.0b013e3181812beb 18633329
66 Hinckley AF Bachand AM Reif JS Late pregnancy exposures to disinfection by-products and growth-related birth outcomes. Environ Health Perspect. 2005;113(12):1808–1813. http://dx.doi.org/10.1289/ehp.8282 16330369
67 Herren-Freund SL Pereira MA Khoury MD Olson G The carcinogenicity of trichloroethylene and its metabolites, trichloroacetic acid and dichloroacetic acid, in mouse liver. Toxicol Appl Pharmacol. 1987;90(2):183–189. http://dx.doi.org/10.1016/0041-008X(87)90325-5 3629594
68 DeAngelo AB Daniel FB Stober JA Olson GR The carcinogenicity of dichloroacetic acid in the male B6C3F1 mouse. Fundam Appl Toxicol. 1991;16(2):337–347. http://dx.doi.org/10.1016/0272-0590(91)90118-N 2055364
69 Daniel FB DeAngelo AB Stober JA Olson GR Page NP Hepatocarcinogenicity of chloral hydrate, 2-chloroacetaldehyde, and dichloroacetic acid in the male B6C3F1 mouse. Fundam Appl Toxicol. 1992;19(2):159–168. http://dx.doi.org/10.1016/0272-0590(92)90147-A 1516771
70 Pereira MA Carcinogenic activity of dichloroacetic acid and trichloroacetic acid in the liver of female B6C3F1 mice. Fundam Appl Toxicol. 1996;31(2):192–199. http://dx.doi.org/10.1006/faat.1996.0091 8789785
71 Austin EW Parrish JM Kinder DH Bull RJ Lipid peroxidation and formation of 8-hydroxydeoxyguanosine from acute doses of halogenated acetic acids. Fundam Appl Toxicol. 1996;31(1):77–82. http://dx.doi.org/10.1006/faat.1996.0078 8998956
72 Stauber AJ Bull RJ Differences in phenotype and cell replicative behavior of hepatic tumors induced by dichloroacetate (DCA) and trichloroacetate (TCA). Toxicol Appl Pharmacol. 1997;144(2):235–246. http://dx.doi.org/10.1006/taap.1997.8159 9194407
73 Stauber AJ Bull RJ Thrall BD Dichloroacetate and trichloroacetate promote clonal expansion of anchorage-independent hepatocytes in vivo and in vitro. Toxicol Appl Pharmacol. 1998;150(2):287–294. http://dx.doi.org/10.1006/taap.1998.8417 9653059
74 Pereira MA Kramer PM Conran PB Tao L Effect of chloroform on dichloroacetic acid and trichloroacetic acid-induced hypomethylation and expression of the c-myc gene and on their promotion of liver and kidney tumors in mice. Carcinogenesis. 2001;22(9):1511–1519. http://dx.doi.org/10.1093/carcin/22.9.1511 11532874
75 Tao L Wang W Li L Kramer PM Pereira MA Effect of dibromoacetic acid on DNA methylation, glycogen accumulation, and peroxisome proliferation in mouse and rat liver. Toxicol Sci. 2004;82(1):62–69. http://dx.doi.org/10.1093/toxsci/kfh266 15342954
76 Tao L Wang W Li L Kramer PK Pereira MA DNA hypomethylation induced by drinking water disinfection by-products in mouse and rat kidney. Toxicol Sci. 2005;87(2):344–352. http://dx.doi.org/10.1093/toxsci/kfi257 16014735
77 Anna CH Maronpot RR Pereira MA Foley JF Malarkey DE Anderson MW ras proto-oncogene activation in dichloroacetic acid-, trichloroethylene- and tetrachloroethylene-induced liver tumors in B6C3F1 mice. Carcinogenesis. 1994;15(10):2255–2261. http://dx.doi.org/10.1093/carcin/15.10.2255 7955063
78 Morris RD Audet AM Angelillo IF Chalmers TC Mosteller F Chlorination, chlorination by-products, and cancer: a meta-analysis. Am J Public Health. 1992;82(7):955–963. http://dx.doi.org/10.2105/AJPH.82.7.955 1535181
79 McGeehin MA Reif JS Becher JC Mangione EJ Case-control study of bladder cancer and water disinfection methods in Colorado. Am J Epidemiol. 1993;138(7):492–501. http://dx.doi.org/10.1093/oxfordjournals.aje.a116883 8213753
80 Cantor KP Lynch CF Hildesheim ME Dosemeci M Lubin J Alavanja M Craun G Drinking water source and chlorination byproducts in Iowa. III. Risk of brain cancer. Am J Epidemiol. 1999;150(6):552–560. http://dx.doi.org/10.1093/oxfordjournals.aje.a010052 10489993
81 Villanueva CM Fernández F Malats N Grimalt JO Kogevinas M Meta-analysis of studies on individual consumption of chlorinated drinking water and bladder cancer. J Epidemiol Community Health. 2003;57(3):166–173. http://dx.doi.org/10.1136/jech.57.3.166 12594192
82 Villanueva CM Cantor KP Cordier S Jaakkola JJ King WD Lynch CF Porru S Kogevinas M Disinfection byproducts and bladder cancer: a pooled analysis. Epidemiology. 2004;15(3):357–367. http://dx.doi.org/10.1097/01.ede.0000121380.02594.fc 15097021
83 Villanueva CM Cantor KP Grimalt JO Malats N Silverman D Tardon A Garcia-Closas R Serra C Carrato A Castaño-Vinyals G Bladder cancer and exposure to water disinfection by-products through ingestion, bathing, showering, and swimming in pools. Am J Epidemiol. 2007;165(2):148–156. http://dx.doi.org/10.1093/aje/kwj364 17079692
84 Plewa MJ Simmons JE Richardson SD Wagner ED Mammalian cell cytotoxicity and genotoxicity of the haloacetic acids, a major class of drinking water disinfection by-products. Environ Mol Mutagen. 2010;51(8-9):871–878. http://dx.doi.org/10.1002/em.20585 20839218
85 DeMarini DM Perry E Shelton ML Dichloroacetic acid and related compounds: induction of prophage in E. coli and mutagenicity and mutation spectra in Salmonella TA100. Mutagenesis. 1994;9(5):429–437. http://dx.doi.org/10.1093/mutage/9.5.429 7837977
86 Giller S Le Curieux F Erb F Marzin D Comparative genotoxicity of halogenated acetic acids found in drinking water. Mutagenesis. 1997;12(5):321–328. http://dx.doi.org/10.1093/mutage/12.5.321 9379909
87 Kargalioglu Y McMillan BJ Minear RA Plewa MJ Analysis of the cytotoxicity and mutagenicity of drinking water disinfection by-products in Salmonella typhimurium. Teratog Carcinog Mutagen. 2002;22(2):113–128. http://dx.doi.org/10.1002/tcm.10010 11835289
88 Plewa MJ Kargalioglu Y Vankerk D Minear RA Wagner ED Mammalian cell cytotoxicity and genotoxicity analysis of drinking water disinfection by-products. Environ Mol Mutagen. 2002;40(2):134–142. http://dx.doi.org/10.1002/em.10092 12203407
89 Chang LW Daniel FB DeAngelo AB Analysis of DNA strand breaks induced in rodent liver in vivo, hepatocytes in primary culture, and a human cell line by chlorinated acetic acids and chlorinated acetaldehydes. Environ Mol Mutagen. 1992;20(4):277–288. http://dx.doi.org/10.1002/em.2850200406 1330547
90 Harrington-Brock K Doerr CL Moore MM Mutagenicity of three disinfection by-products: di- and trichloroacetic acid and chloral hydrate in L5178Y/TK +/- (-)3.7.2C mouse lymphoma cells. Mutat Res. 1998;413(3):265–276. http://dx.doi.org/10.1016/S1383-5718(98)00026-6 9651541
91 Fuscoe JC Afshari AJ George MH DeAngelo AB Tice RR Salman T Allen JWIn vivo genotoxicity of dichloroacetic acid: Evaluation with the mouse peripheral blood micronucleus assay and the single cell gel assay. Environ Mol Mutagen. 1996; 27(1):1-9. 10.1002/(SICI)1098-2280(1996)27:1<1::AID-EM1>3.0.CO;2-L
92 Nelson MA Bull RJ Induction of strand breaks in DNA by trichloroethylene and metabolites in rat and mouse liver in vivo. Toxicol Appl Pharmacol. 1988;94(1):45–54. http://dx.doi.org/10.1016/0041-008X(88)90335-3 3376113
93 Parrish JM Austin EW Stevens DK Kinder DH Bull RJ Haloacetate-induced oxidative damage to DNA in the liver of male B6C3F1 mice. Toxicology. 1996;110(1-3):103–111. http://dx.doi.org/10.1016/0300-483X(96)03342-2 8658551
94 Leavitt SA DeAngelo AB George MH Ross JA Assessment of the mutagenicity of dichloroacetic acid in lacI transgenic B6C3F1 mouse liver. Carcinogenesis. 1997;18(11):2101–2106. http://dx.doi.org/10.1093/carcin/18.11.2101 9395208
95 King-Herbert A Thayer K NTP workshop: animal models for the NTP rodent cancer bioassay: stocks and strains—should we switch? Toxicol Pathol. 2006;34(6):802–805. http://dx.doi.org/10.1080/01926230600935938 17162538
96 DeAngelo AB George MH House DE Hepatocarcinogenicity in the male B6C3F1 mouse following a lifetime exposure to dichloroacetic acid in the drinking water: dose-response determination and modes of action. J Toxicol Environ Health A. 1999;58(8):485–507. http://dx.doi.org/10.1080/009841099157115 10632141
97 Nakanishi Y Okamoto K Isohashi F Effects of chronic administration of the peroxisome proliferator, clofibrate, on cytosolic acetyl-CoA hydrolase in rat liver. Biochem Pharmacol. 1993;45(7):1403–1407. http://dx.doi.org/10.1016/0006-2952(93)90038-X 8097090
98 Lowry OH Rosebrough NJ Farr AL Randall RJ Protein measurement with the Folin phenol reagent. J Biol Chem. 1951;193(1):265–275. 14907713
99 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
100 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
101 McConnell[underlined: EE]Solleveld HA Swenberg JA Boorman GA Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986;76(2):283–289. 3456066
102 Hoenerhoff MJ Pandiri AR Snyder SA Hong HH Ton TV Peddada S Shockley K Witt K Chan P Rider C Hepatocellular carcinomas in B6C3F1 mice treated with Ginkgo biloba extract for two years differ from spontaneous liver tumors in cancer gene mutations and genomic pathways. Toxicol Pathol. 2013;41(6):826–841. http://dx.doi.org/10.1177/0192623312467520 23262642
103 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53:457–481. 10.1080/01621459.1958.10501452
104 Cox D Regression models and life tables. J R Stat Soc [Ser A]. 1972;34(2):187–220.
105 Tarone RE Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690. 10.1093/biomet/62.3.679
106 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. http://dx.doi.org/10.2307/2531856 3390507
107 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. http://dx.doi.org/10.1016/0272-0590(89)90004-3 2744275
108 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology, Section 6.3.2. London: Chapeman and Hall; 1997.
109 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
110 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. http://dx.doi.org/10.2307/2532200 8241374
111 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
112 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
113 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
114 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
115 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
116 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
117 Dunn OJ Multiple comparison using RANK sums. Technometrics. 1964;6:241–252. 10.1080/00401706.1964.10490181
118 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1-2):133–145. 10.1093/biomet/41.1-2.133
119 Dixon WJ Massey FJ Introduction to statistical analysis. 2nd ed. New York: McGraw-Hill Book Company; 1957. p. 276–278, 412.
120 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987:225-234. 10.2307/2531963
121 Haseman JK Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26:191–200. 10.1177/009286159202600210
122 Haseman JKData analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharm. 1995; 21:52-59. 10.1006/rtph.1995.1009
123 Haseman JK Rao GN Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992;20(1):52–60. http://dx.doi.org/10.1177/019262339202000107 1411131
124 Code of Federal Regulations (CFR). 21:Part 58.
125 Schmid W The micronucleus test. Mutat Res. 1975;31(1):9–15. http://dx.doi.org/10.1016/0165-1161(75)90058-8 48190
126 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983;123(1):61–118. http://dx.doi.org/10.1016/0165-1110(83)90047-7 6888413
127 Miller JA Miller EC Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH Watson JD Winsten JAeditors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
128 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67(2):233–241. 7021938
129 Crawford BD Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co., Inc.; 1985. Perspectives on the somatic mutation model of carcinogensises; p. 13–59.
130 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991;257(3):229–306. http://dx.doi.org/10.1016/0165-1110(91)90003-E 1707500
131 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987;236(4804):933–941. http://dx.doi.org/10.1126/science.3554512 3554512
132 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RW Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990;16 Suppl 18:1–14. http://dx.doi.org/10.1002/em.2850160502 2091921
133 Shelby MD Erexson GL Hook GJ Tice RR Evaluation of a three-exposure mouse bone marrow micronucleus protocol: results with 49 chemicals. Environ Mol Mutagen. 1993;21(2):160–179. http://dx.doi.org/10.1002/em.2850210210 8444144
134 Shelby MD Witt KL Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995;25(4):302–313. http://dx.doi.org/10.1002/em.2850250407 7607185
135 Witt KL Knapton A Wehr CM Hook GJ Mirsalis J Shelby MD MacGregor JTMicronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
136 National Cancer Institute (NCI). Bioassay of phenoxybenzamine hydrochloride for possible carcinogenicity (CAS No. 63-92-3). Bethesda, MD: U.S. Department of Health, Education, and Welfare, Public Health Service, National Institutes of Health; 1978. Technical Report Series No. 72. NIH Publication No. 78-1322.
137 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of pentachlorophenol (CAS NO. 87-86-5) in F344/N rats (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1999. Technical Report Series No. 483. NIH Publication No. 99-3973.
138 Corton JC Evaluation of the role of peroxisome proliferator-activated receptor alpha (PPARalpha) in mouse liver tumor induction by trichloroethylene and metabolites. Crit Rev Toxicol. 2008;38(10):857–875. http://dx.doi.org/10.1080/10408440802209796 18821149
139 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992;19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
140 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990;14(3):513–522. http://dx.doi.org/10.1016/0272-0590(90)90255-I 2111256
141 The Aldrich library of FT-IR spectra. 1st ed. Vol. 1, Spectra A, B, C, and D. Milwaukee, WI: Aldrich Chemical Co.; 1985.
142 National Toxicology Program (NTP). Chemicals associated with site-specific tumor induction in mammary gland. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2012. https://www.niehs.nih.gov/go/SA-39
143 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,2-bis(bromomethyl)-1,3-propanediol (FR-1138(R)) (CAS No. 3296-90-0) in F344 rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. Technical Report Series No. 452. NIH Publication No. 96-3368.
144 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of nickel sulfate hexahydrate (CAS No. 10101-97-0) in F344 rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. Technical Report Series No. 454. NIH Publication No. 97-3370.
145 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of D&C Yellow No. 11 (CAS No. 8003-22-3) in F344/N rats (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1997. Technical Report Series No. 463. NIH Publication No. 97-3379.
146 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 3,3',4,4'-tetrachloroazobenzene (TCAB) (CAS No. 14047-09-7) in Harlan Sprague-Dawley rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2010. Technical Report Series No. 558. NIH Publication No. 11-5899.
147 Pfaffl MW A new mathematical model for relative quantification in real-time RT-PCR. Nucleic Acids Res. 2001;29(9):e45. http://dx.doi.org/10.1093/nar/29.9.e45 11328886
148 Efron B Tibshirani RJ An introduction to the bootstrap. New York (NY): Chapman and Hall; 1994.
149 Peddada SD Lobenhofer EK Li L Afshari CA Weinberg CR Umbach DM Gene selection and clustering for time-course and dose-response microarray experiments using order-restricted inference. Bioinformatics. 2003;19(7):834–841. http://dx.doi.org/10.1093/bioinformatics/btg093 12724293
150 Peddada S Harris S Zajd J Harvey E ORIOGEN: order restricted inference for ordered gene expression data. Bioinformatics. 2005;21(20):3933–3934. http://dx.doi.org/10.1093/bioinformatics/bti637 16109745
151 Guo W Sarkar SK Peddada SD Controlling false discoveries in multidimensional directional decisions, with applications to gene expression data on ordered categories. Biometrics. 2010;66(2):485–492. http://dx.doi.org/10.1111/j.1541-0420.2009.01292.x 19645703
152 Moustakas A Pardali K Gaal A Heldin CH Mechanisms of TGF-beta signaling in regulation of cell growth and differentiation. Immunol Lett. 2002;82(1-2):85–91. http://dx.doi.org/10.1016/S0165-2478(02)00023-8 12008039
153 Akhurst RJ Derynck R TGF-beta signaling in cancer—a double-edged sword. Trends Cell Biol. 2001;11(11):S44–S51. http://dx.doi.org/10.1016/S0962-8924(01)02130-4 11684442
154 Tang B Vu M Booker T Santner SJ Miller FR Anver MR Wakefield LM TGF-beta switches from tumor suppressor to prometastatic factor in a model of breast cancer progression. J Clin Invest. 2003;112(7):1116–1124. http://dx.doi.org/10.1172/JCI200318899 14523048
155 Ivanović V Todorović-Raković N Demajo M Nesković-Konstantinović Z Subota V Ivanisević-Milovanović O Nikolić-Vukosavljević D Elevated plasma levels of transforming growth factor-beta 1 (TGF-beta 1) in patients with advanced breast cancer: association with disease progression. Eur J Cancer. 2003;39(4):454–461. http://dx.doi.org/10.1016/S0959-8049(02)00502-6 12751375
156 Moore-Smith L Pasche B TGFBR1 signaling and breast cancer. J Mammary Gland Biol Neoplasia. 2011;16(2):89–95. http://dx.doi.org/10.1007/s10911-011-9216-2 21461994
157 Wiercinska E Naber HP Pardali E van der Pluijm G van Dam H ten Dijke P The TGF-β/Smad pathway induces breast cancer cell invasion through the up-regulation of matrix metalloproteinase 2 and 9 in a spheroid invasion model system. Breast Cancer Res Treat. 2011;128(3):657–666. http://dx.doi.org/10.1007/s10549-010-1147-x 20821046
158 Stetler-Stevenson WG Progelatinase A activation during tumor cell invasion. Invasion Metastasis. 1994-1995;14(1-6):259–268. 7657518
159 Egeblad M Werb Z New functions for the matrix metalloproteinases in cancer progression. Nat Rev Cancer. 2002;2(3):161–174. http://dx.doi.org/10.1038/nrc745 11990853
160 Cupić DF Tesar EC Ilijas KM Nemrava J Kovacević M Expression of matrix metalloproteinase 9 in primary and recurrent breast carcinomas. Coll Antropol. 2011;35 Suppl 2:7–10. 22220395
161 Liang YY Brunicardi FC Lin X Smad3 mediates immediate early induction of Id1 by TGF-beta. Cell Res. 2009;19(1):140–148. http://dx.doi.org/10.1038/cr.2008.321 19079362
162 Tobin NP Sims AH Lundgren KL Lehn S Landberg G Cyclin D1, Id1 and EMT in breast cancer. BMC Cancer. 2011;11:417. http://dx.doi.org/10.1186/1471-2407-11-417 21955753
163 Yee KO Connolly CM Duquette M Kazerounian S Washington R Lawler J The effect of thrombospondin-1 on breast cancer metastasis. Breast Cancer Res Treat. 2009;114(1):85–96. http://dx.doi.org/10.1007/s10549-008-9992-6 18409060
164 Roberts DD Regulation of tumor growth and metastasis by thrombospondin-1. FASEB J. 1996;10(10):1183–1191. http://dx.doi.org/10.1096/fasebj.10.10.8751720 8751720
165 Soufla G Porichis F Sourvinos G Vassilaros S Spandidos DA Transcriptional deregulation of VEGF, FGF2, TGF-beta1, 2, 3 and cognate receptors in breast tumorigenesis. Cancer Lett. 2006;235(1):100–113. http://dx.doi.org/10.1016/j.canlet.2005.04.022 15949894
166 Breier G Blum S Peli J Groot M Wild C Risau W Reichmann E Transforming growth factor-beta and Ras regulate the VEGF/VEGF-receptor system during tumor angiogenesis. Int J Cancer. 2002;97(2):142–148. http://dx.doi.org/10.1002/ijc.1599 11774256
167 Sakurai T Kudo M Signaling pathways governing tumor angiogenesis. Oncology. 2011;81 Suppl 1:24–29. http://dx.doi.org/10.1159/000333256 22212932
168 Hoenerhoff MJ Pandiri AR Lahousse SA Hong HH Ton TV Masinde T Auerbach SS Gerrish K Bushel PR Shockley KR Global gene profiling of spontaneous hepatocellular carcinoma in B6C3F1 mice: similarities in the molecular landscape with human liver cancer. Toxicol Pathol. 2011;39(4):678–699. http://dx.doi.org/10.1177/0192623311407213 21571946
169 Pandiri AR Sills RC Ziglioli V Ton TV Hong HH Lahousse SA Gerrish KE Auerbach SS Shockley KR Bushel PR Differential transcriptomic analysis of spontaneous lung tumors in B6C3F1 mice: comparison to human non-small cell lung cancer. Toxicol Pathol. 2012;40(8):1141–1159. http://dx.doi.org/10.1177/0192623312447543 22688403
170 Irizarry RA Hobbs B Collin F Beazer-Barclay YD Antonellis KJ Scherf U Speed TP Exploration, normalization, and summaries of high density oligonucleotide array probe level data. Biostatistics. 2003;4(2):249–264. http://dx.doi.org/10.1093/biostatistics/4.2.249 12925520
171 Rozen S Skaletsky H Primer3 on the WWW for general users and for biologist programmers. Methods Mol Biol. 2000;132:365–386. 10547847
172 Kupershmidt I Su QJ Grewal A Sundaresh S Halperin I Flynn J Shekar M Wang H Park J Cui W Ontology-based meta-analysis of global collections of high-throughput public data. PLoS One. 2010;5(9):e13066. http://dx.doi.org/10.1371/journal.pone.0013066 20927376
173 Otu HH Naxerova K Ho K Can H Nesbitt N Libermann TA Karp SJ Restoration of liver mass after injury requires proliferative and not embryonic transcriptional patterns. J Biol Chem. 2007;282(15):11197–11204. http://dx.doi.org/10.1074/jbc.M608441200 17227769
174 Chaignat E Yahya-Graison EA Henrichsen CN Chrast J Schütz F Pradervand S Reymond A Copy number variation modifies expression time courses. Genome Res. 2011;21(1):106–113. http://dx.doi.org/10.1101/gr.112748.110 21084671
175 Jablkowski M Bocian A Bialkowska J Bartkowiak J A comparative study of P53/MDM2 genes alterations and P53/MDM2 proteins immunoreactivity in liver cirrhosis and hepatocellular carcinoma. J Exp Clin Cancer Res. 2005;24(1):117–125. 15943041
176 Megger DA Bracht T Kohl M Ahrens M Naboulsi W Weber F Hoffmann AC Stephan C Kuhlmann K Eisenacher M Proteomic differences between hepatocellular carcinoma and nontumorous liver tissue investigated by a combined gel-based and label-free quantitative proteomics study. Mol Cell Proteomics. 2013;12(7):2006–2020. http://dx.doi.org/10.1074/mcp.M113.028027 23462207
177 Utsunomiya T Shimada M Molecular characteristics of non‐cancerous liver tissue in non‐B non‐C hepatocellular carcinoma. Hepatol Res. 2011; (41):711-721. 10.1111/j.1872-034X.2011.00818.x
178 Farazi PA DePinho RA Hepatocellular carcinoma pathogenesis: from genes to environment. Nat Rev Cancer. 2006;6(9):674–687. http://dx.doi.org/10.1038/nrc1934 16929323
179 Kaposi-Novak P Libbrecht L Woo HG Lee YH Sears NC Coulouarn C Conner EA Factor VM Roskams T Thorgeirsson SS Central role of c-Myc during malignant conversion in human hepatocarcinogenesis. Cancer Res. 2009;69(7):2775–2782. http://dx.doi.org/10.1158/0008-5472.CAN-08-3357 19276364
180 Uematsu S Higashi T Nouso K Kariyama K Nakamura S Suzuki M Nakatsukasa H Kobayashi Y Hanafusa T Tsuji T Altered expression of vascular endothelial growth factor, fibroblast growth factor-2 and endostatin in patients with hepatocellular carcinoma. J Gastroenterol Hepatol. 2005;20(4):583–588. http://dx.doi.org/10.1111/j.1440-1746.2005.03726.x 15836707
181 Harimoto N Taguchi K Shirabe K Adachi E Sakaguchi Y Toh Y Okamura T Kayashima H Taketomi A Maehara Y The significance of fibroblast growth factor receptor 2 expression in differentiation of hepatocellular carcinoma. Oncology. 2010;78(5-6):361–368. http://dx.doi.org/10.1159/000320463 20798558
182 Clevers H Wnt/beta-catenin signaling in development and disease. Cell. 2006;127(3):469–480. http://dx.doi.org/10.1016/j.cell.2006.10.018 17081971
183 Cairo S Armengol C De Reyniès A Wei Y Thomas E Renard CA Goga A Balakrishnan A Semeraro M Gresh L Hepatic stem-like phenotype and interplay of Wnt/beta-catenin and Myc signaling in aggressive childhood liver cancer. Cancer Cell. 2008;14(6):471–484. http://dx.doi.org/10.1016/j.ccr.2008.11.002 19061838
184 Monga SP Role of Wnt/β-catenin signaling in liver metabolism and cancer. Int J Biochem Cell Biol. 2011;43(7):1021–1029. http://dx.doi.org/10.1016/j.biocel.2009.09.001 19747566
185 Haegebarth A Clevers H Wnt signaling, lgr5, and stem cells in the intestine and skin. Am J Pathol. 2009;174(3):715–721. http://dx.doi.org/10.2353/ajpath.2009.080758 19197002
186 Polyak K Weinberg RA Transitions between epithelial and mesenchymal states: acquisition of malignant and stem cell traits. Nat Rev Cancer. 2009;9(4):265–273. http://dx.doi.org/10.1038/nrc2620 19262571
187 Bisson I Prowse DM WNT signaling regulates self-renewal and differentiation of prostate cancer cells with stem cell characteristics. Cell Res. 2009;19(6):683–697. http://dx.doi.org/10.1038/cr.2009.43 19365403
188 Takayasu H Horie H Hiyama E Matsunaga T Hayashi Y Watanabe Y Suita S Kaneko M Sasaki F Hashizume K Frequent deletions and mutations of the beta-catenin gene are associated with overexpression of cyclin D1 and fibronectin and poorly differentiated histology in childhood hepatoblastoma. Clin Cancer Res. 2001;7(4):901–908. 11309340
189 Nagata T Takahashi Y Ishii Y Asai S Nishida Y Murata A Koshinaga T Fukuzawa M Hamazaki M Asami K Transcriptional profiling in hepatoblastomas using high-density oligonucleotide DNA array. Cancer Genet Cytogenet. 2003;145(2):152–160. http://dx.doi.org/10.1016/S0165-4608(03)00065-7 12935928
190 Berenblum I Shubik P An experimental study of the initiating state of carcinogenesis, and a re-examination of the somatic cell mutation theory of cancer. Br J Cancer. 1949;3(1):109–118. http://dx.doi.org/10.1038/bjc.1949.13 18128325
191 Anna CH Sills RC Foley JF Stockton PS Ton TV Devereux TR Beta-catenin mutations and protein accumulation in all hepatoblastomas examined from B6C3F1 mice treated with anthraquinone or oxazepam. Cancer Res. 2000;60(11):2864–2868. 10850429
192 Rubin H Fields and field cancerization: the preneoplastic origins of cancer: asymptomatic hyperplastic fields are precursors of neoplasia, and their progression to tumors can be tracked by saturation density in culture. BioEssays. 2011;33(3):224–231. http://dx.doi.org/10.1002/bies.201000067 21254148
193 Ushijima T Hattori N Molecular pathways: involvement of Helicobacter pylori-triggered inflammation in the formation of an epigenetic field defect, and its usefulness as cancer risk and exposure markers. Clin Cancer Res. 2012;18(4):923–929. http://dx.doi.org/10.1158/1078-0432.CCR-11-2011 22205689
194 Maronpot RR Fox T Malarkey DE Goldsworthy TL Mutations in the ras proto-oncogene: clues to etiology and molecular pathogenesis of mouse liver tumors. Toxicology. 1995;101(3):125–156. http://dx.doi.org/10.1016/0300-483X(95)03112-S 7676462
195 Sills RC Boorman GA Neal JE Hong HL Devereux TR Mutations in ras genes in experimental tumours of rodents. IARC Sci Publ. 1999;(146):55–86. 10353384
196 Hayashi SM Ton TV Hong HH Irwin RD Haseman JK Devereux TR Sills RC Genetic alterations in the Catnb gene but not the H-ras gene in hepatocellular neoplasms and hepatoblastomas of B6C3F(1) mice following exposure to diethanolamine for 2 years. Chem Biol Interact. 2003;146(3):251–261. http://dx.doi.org/10.1016/j.cbi.2003.07.001 14642737