# Conclusions

Under the conditions of these 2-year studies, there was clear evidence of carcinogenic activity^a^ of bromodichloroacetic acid in male F344/NTac rats based on increased incidences of malignant mesothelioma and the combined incidences of epithelial tumors of the skin. Occurrences of subcutaneous fibromas were also related to exposure to bromodichloroacetic acid. Occurrences of glioma or oligodendroglioma (combined) of the brain, squamous cell papilloma and squamous cell carcinoma of the oral cavity (oral mucosa or tongue), adenoma of the large intestine, and fibroadenoma of the mammary gland may have been related to exposure to bromodichloroacetic acid. There was clear evidence of carcinogenic activity of bromodichloroacetic acid in female F344/NTac rats based on increased incidences of fibroadenoma and carcinoma of the mammary gland. The occurrences of glioma or oligodendroglioma (combined) of the brain may have been related to bromodichloroacetic acid exposure. There was clear evidence of carcinogenic activity of bromodichloroacetic acid in male B6C3F1/N mice based on increased incidences of hepatocellular carcinoma and hepatoblastoma and increased incidences of adenoma or carcinoma (combined) of the Harderian gland. There was clear evidence of carcinogenic activity of bromodichloroacetic acid in female B6C3F1/N mice based on increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma.

a See Explanation of Levels of Evidence of Carcinogenic Activity. A summary of the Peer Review Panel’s comments and the public discussion on this Technical Report appears in Appendix P.

Exposure to bromodichloroacetic acid for 2 years resulted in increased incidences of nonneoplastic lesions in the bone marrow and liver of male and female rats, spleen of female rats, liver of male and female mice, and testis and epididymis of male mice.