# Discussion

Bromodichloroacetic acid is a haloacetic acid that is produced by the interaction of naturally occurring bromides in water reacting with humic acids and halogenated oxidants used in water disinfection. There are nine chlorinated, brominated, or mixed chloro/bromo haloacetic acids. The United States Environmental Protection Agency (USEPA) regulates five haloacetic acids in drinking water at a level of 60 µg/L. Bromodichloroacetic acid is not included in this standard, and no drinking water standard has been developed for this chemical. In a nationwide survey, bromodichloroacetic acid was found in water distribution systems as well as finished water at concentrations up to 15 µg/L.^30^ Bromodichloroacetic acid typically makes up 1% to 20% of the haloacetic acids present in water distribution systems and finished water.^30^ The disinfection by-products were nominated to the NTP by the USEPA and the American Water Works Association Research Foundation for evaluation of their carcinogenic potential. Bromodichloroacetic acid is the latest in this class to be evaluated. There were no previous in vivo toxicity studies available for bromodichloroacetic acid.

Including the current study, cancer bioassays in rats and/or mice are available for six of the nine haloacetic acids. No cancer data for bromoacetic acid, dibromochloroacetic acid, or tribromoacetic acid are available in the published literature. The carcinogenic potential of monochloroacetic acid in drinking water was evaluated in rats and mice by the NTP and no evidence of carcinogenicity was observed.^17^ Dichloroacetic acid in drinking water increased the incidences of liver neoplasms in male mice^4,96^ and rats.^3^ Dibromoacetic acid exposure in drinking water was carcinogenic in male (liver and lung) and female (liver) mice and male (mesothelioma and leukemia) and female (mesothelioma) rats.^18^ The potential carcinogenic effects of bromochloroacetic acid in drinking water were evaluated by the NTP and clear evidence of carcinogenicity was observed in male (hepatocellular carcinoma and hepatocellular adenoma or carcinoma) and female (hepatocellular adenoma or carcinoma) mice and male (malignant mesothelioma and large intestine adenoma) and female (large intestine adenoma and mammary gland fibroadenoma) rats.^19^ Trichloroacetic acid induced liver neoplasms in male mice but not in male rats. Given some of the limitations of these data, it appears that the monohalogenated chemicals are less likely to be carcinogenic and that the addition of bromine increases the potency and carcinogenicity of the haloacetic acid. A common neoplasm site for haloacetic acids is the liver in male and female mice, and mesotheliomas are common neoplasms in male rats.

Drinking water concentrations of bromodichloroacetic acid ranged from 62.5 to 1,000 mg/L in the current 2-week and 3-month studies in F344/N rats. These concentrations were based on earlier studies of haloacetic acids. In the current 2-week and 3-month rat studies, exposure to bromodichloroacetic acid in drinking water produced minimal effects and no chemical-related gross or histopathology findings were observed. In the 3-month study, there were minor changes (less than 10% from control) in organ weights and/or organ weight to body weight ratios in the liver of male rats and the kidney of female rats, which were not considered biologically significant. Based on the minimal effects of bromodichloroacetic acid in the subchronic studies, the drinking water concentrations of bromodichloroacetic acid were set at 0, 250, 500, and 1,000 mg/L for the 2-year study in F344/NTac rats. These concentrations resulted in average daily doses in the 2-year study of approximately 11, 21, and 43 mg bromodichloroacetic acid/kg body weight to males and approximately 13, 28, and 57 mg/kg to females.

In female F344/NTac rats exposed to 1,000 mg/L for 2 years, body weights were 90% of controls starting on day 85 and decreased to about 80% of controls by day 365. Exposure to bromodichloroacetic acid in the drinking water significantly decreased survival at the two highest exposure concentrations in female rats. Sixty-eight percent of the control females survived to the end of the study, while only 14% and 4% of the females exposed to 500 and 1,000 mg/L, respectively, survived to the end of the study. The morbidity associated with bromodichloroacetic acid exposure was due to increased incidences of mammary gland fibroadenoma and carcinoma.

Bromodichloroacetic acid exposure caused clear exposure concentration-dependent increases in incidences of mammary gland fibroadenoma (including multiples) and carcinoma in female F344/NTac rats. The incidences of fibroadenoma in females were significantly increased at all exposure concentrations tested, and there was a statistically significant increase in the incidence of carcinoma in the 1,000 mg/L group. Bromodichloroacetic acid also caused an exposure concentration-dependent increase in the incidences of mammary gland hyperplasia. The determination of clear evidence is supported by the exposure concentration-dependent increase in the incidences of fibroadenomas that are associated with possible progression to mammary gland carcinomas.

In male rats, the incidences of mammary gland fibroadenoma were greater in the exposed animals compared to the controls, but these differences did not reach statistical significance. Due to the low background incidence of these tumors in male rats and the clear evidence of mammary gland neoplasms in the females, these neoplasms may also have been related to bromodichloroacetic acid exposure.

Examination of gene expression using PCR arrays (Appendix N) indicated that the female mammary gland adenocarcinomas from bromodichloroacetic acid-treated animals were enriched for Mmp2, Mmp9, Id1, Thbs1, Hic1, Adam23, Vegfa, and Cdh13 compared to spontaneous mammary gland adenocarcinomas from control female F344/N and Sprague Dawley rats from other NTP studies. Five of these eight genes are associated with Tgfβ pathway signaling, including its effects on matrix remodeling, mammary cancer progression, tumor invasion, and metastasis (Mmp2, Mmp9, Id1, Vegfa, Thbs1). The overrepresentation of Tgfβ mediators that were significantly upregulated in mammary gland adenocarcinomas from bromodichloroacetic acid-exposed female F344/NTac rats compared to spontaneous mammary gland adenocarcinomas may suggest a correlation between this pathway and the increased incidences of proliferative mammary gland lesions observed in bromodichloroacetic acid-exposed animals. These data suggest that mammary gland carcinogenesis in bromodichloroacetic acid-exposed animals may be influenced in part by Tgfβ-dependent mechanisms.

In the NTP study of bromochloroacetic acid, the incidences of multiple mammary gland fibroadenoma in female rats were significantly increased at the two highest exposure concentrations; these lesions were considered exposure related.^19^ Bromochloroacetic acid and bromodichloroacetic acid are mixed bromo/chloro substituted haloacetic acids. While the mechanism for these increased incidences of fibroadenoma is uncertain, the structural and toxicologic similarity of these two chemicals further supports the determination of clear evidence for increased mammary gland neoplasms caused by bromodichloroacetic acid exposure. The remaining mixed bromo/chloroacetic acids and dibromochloroacetic acid have not been evaluated for carcinogenicity in rodents.

Exposure to bromodichloroacetic acid in the drinking water was clearly related to increased incidences of malignant mesotheliomas in male rats. Support for the determination of clear evidence of carcinogenicity is the exposure concentration-dependent increase in the incidences of malignant mesothelioma that were found primarily in the epididymis, testis, seminal vesicle, and prostate gland of male F344/NTac rats. In addition, malignant mesotheliomas were found in interim evaluation male rats at 13 months. Despite group sizes of only eight at the 13-month necropsy, one 500 mg/L male and five 1,000 mg/L males had malignant mesothelioma, and the incidence in the 1,000 mg/L group was significantly greater than the control incidence. These findings were similar to those observed with dibromoacetic acid^18^ and bromochloroacetic acid.^19^ The similarity of the structures and the carcinogenic effect increases confidence that exposure to haloacetic acids causes an increase in the incidences of malignant mesothelioma in rats and provides further support for clear evidence of carcinogenicity.

Chemically induced mesotheliomas in rats have been observed with 19 test chemicals out of the 587 tested at the NTP. This neoplasm has been found predominantly in male rats compared to female rats or male or female mice. Positive male rat findings were reported in 17 of the 19 studies with an increase in mesotheliomas. These chemicals are structurally diverse, ranging from persistent organic pollutants such as pentachlorophenol to rapidly metabolized chemicals such as glycidol. Of these 17 studies, including the current study of bromodichloroacetic acid, in which male rat mesotheliomas were chemically induced; 13 of these chemicals also induced clear or some evidence of female rat mammary gland carcinogenic activity. The exceptions to this list are pentachlorophenol, phenoxybenzamine hydrochloride, and dibromoacetic acid. Phenoxybenzamine hydrochloride was administered by intraperitoneal injection and is the only chemical that increased the incidences of mesothelioma in both male and female rats and mice, and it is also the only chemical that induced only mesotheliomas^136^; all other chemicals that induced mesothelioma also induced tumors at multiple sites. In the pentachlorophenol study, male rat mesotheliomas were only observed in animals from the stop-exposure study and not in animals exposed for the full 2 years.^137^ Conversely, there are 31 chemicals that resulted in clear or some evidence of mammary gland carcinogenic activity in female rats with 13 of 31 inducing male rat mesothelioma. If a chemical induced male rat mesothelioma and female rat mammary gland adenomas or carcinomas, it was also positive for carcinogenicity in mice, although there was no consistent target tissue or tumor finding. The mechanistic relationship, if any, between male rat mesotheliomas and female rat mammary gland carcinogenesis is undetermined.

In male F344/NTac rats, there were clear exposure concentration-dependent increases in the combined incidences of all cutaneous epithelial neoplasms including squamous cell papilloma, keratoacanthoma, basal cell adenoma, basal cell carcinoma, or squamous cell carcinoma, and the increase was statistically significant at the highest exposure concentration. The incidence of keratoacanthoma (including multiples) was significantly increased at the highest exposure concentration tested as was the incidence of the combination of basal cell adenoma or carcinoma. Because the squamous cell papillomas, keratoacanthomas, basal cell adenomas, basal cell carcinomas, and squamous cell carcinomas are all epithelial neoplasms in the skin, the increased incidences of the combined neoplasms increase confidence that the neoplasms are indeed treatment related.

The incidences of fibroma (including multiples) in subcutaneous tissue also demonstrated an exposure concentration-dependent effect that was statistically significant in 1,000 mg/L male rats. These neoplasms appear to be related to systemic exposure because they did not occur around the mouth or snout, which may be considered sites of contact for a drinking water study. While bromodichloroacetic acid is the only haloacetic acid to increase incidences of neoplasms of the skin in rats, the statistically significant exposure concentration-dependent trends in these neoplasms support the determination that these tumors were also related to chemical exposure.

Exposure to bromodichloroacetic acid also caused small increases in neoplasm incidences at several sites that have very low background rates. Because of the low background incidence, it is difficult to discriminate between spontaneous and chemically induced tumors. In order to confirm the low tumor incidence, extended histological evaluation was done on a case by case basis. In the present rat study, the brain was chosen for extended evaluation, and all tongues, not just those with macroscopic lesions, were examined microscopically.

In the original evaluation of the brain, sporadic neoplasms were observed in F344/NTac rats, and an extended evaluation was performed on this tissue to rule out any missed microscopic lesions. In the males, there was an exposure concentration-dependent increase in the incidences of glioma and oligodendroglioma. The incidences for the combined neoplasms from both evaluations were 1/50, 1/50, 4/50, and 3/50 in male rats and 1/50, 0/50, 3/50, and 1/50 in female rats in the control, 250, 500, and 1,000 mg/L groups, respectively. While exposed groups of animals had increased incidences of these neoplasms, the rates were very low. However, in the 2013 historical control database, the occurrence of oligodendrogliomas or gliomas was 0/699 male F344/N rats and 3/700 female F344/N rats. In the 2009 historical control database, the occurrence of oligodendrogliomas or gliomas was 7/1,397 male F344/N rats and 8/1,350 female F344/N rats. There were no studies in males that had an occurrence of oligodendrogliomas or gliomas of more than 1/50. Occurrences of oligodendrogliomas or gliomas in male F344/NTac rats of 4/50 and 3/50 were observed at the 500 mg/L and 1,000 mg/L concentrations, respectively, in the current study. While these neoplasms were not significantly increased, they are greater than any historical controls in the past 10 years; and bromodichloroacetic acid is genotoxic. Because the incidence of these tumors were not statistically significant, but outside of the range of the historical controls, these tumors may have been related to chemical exposure.

Similarly, three males in the 500 and 1,000 mg/L groups had a squamous cell papilloma or squamous cell carcinoma of the oral cavity (oral mucosa or tongue). The carcinomas were associated with hyperplasia of the lingual epithelium. Because bromodichloroacetic acid is genotoxic, the oral cavity is one of the portals of entry, and these are rare neoplasms (in F344/N male rats, the 2013 historical control range is 0% to 2% with an incidence of 5/699 animals and in the 2009 historical control range is 0% to 2% with an incidence of 11/1,398), the incidence of these tumors may have been related to chemical exposure.

The large intestine was a target site for bromochloroacetic acid in male and female F344/N rats with adenoma incidences of 4/50 and 7/50 in 1,000 mg/L males and females, respectively^19^ with no adenomas present in the control male or female rats. In the current study in F344/NTac rats, the background rates of large intestine adenoma were 0/50 for males and 1/50 for females. At 500 and 1,000 mg/L in male rats and 1,000 mg/L in female rats, the incidences of large intestine adenoma were 2/50 each. This was considered equivocal evidence of carcinogenicity because, in F344/N male rats, the 2013 historical control incidence was 0/699 animals, the 2009 historical control range was 0% to 2% with an incidence of 3/1,398, and neither database ever had a study with more than 1/50 large intestine adenomas. These neoplasms may have been related to chemical exposure.

Exposure to bromodichloroacetic acid for 2 years was associated with additional nonneoplastic effects in the liver, bone marrow, and spleen of F344/NTac rats. Significantly increased incidences of hematopoietic cell proliferation were noted in the liver of 500 and 1,000 mg/L females; the lesion was characterized by multifocal aggregations of erythroid and myeloid precursors. Significantly increased incidences of hematopoietic cell proliferation were also noted in the spleen of female rats exposed to 500 and 1,000 mg/L. In the bone marrow, exposure concentration-dependent increased incidences of angiectasis, a dilation of the blood vessels, and hematopoietic hyperplasia were observed in male and female rats.

Similar to F344/N rats, drinking water concentrations of bromodichloroacetic acid ranged from 62.5 to 1,000 mg/L in the 2-week and 3-month studies in mice. In the 2-week and 3-month studies, exposure to bromodichloroacetic acid did not induce chemical-related gross or clinical findings. While histopathology findings were observed in the liver of females and kidney of males in the 3-month study, these effects were considered minor. Based on the minimal effects of bromodichloroacetic acid in the subchronic studies, the drinking water concentrations of bromodichloroacetic acid were set at 0, 250, 500, and 1,000 mg/L for the 2-year study in mice. In mice, these concentrations resulted in average daily doses in the 2-year study of approximately 23, 52, and 108 mg bromodichloroacetic acid/kg body weight to males and approximately 17, 34, and 68 mg/kg to females.

In the 2-year study, exposure to bromodichloroacetic acid in the drinking water resulted in significantly decreased survival in male mice exposed to 500 or 1,000 mg/L. The most common cause of early death appeared to be liver neoplasms. In male mice, there was clear evidence of a carcinogenic effect based on increased incidences of hepatocellular carcinoma (including multiples) and hepatoblastoma (including multiples); the incidences of these neoplasms were significantly increased at all exposure concentrations. The exposure concentration-dependent increased incidences of hepatocellular carcinoma and hepatoblastoma support the determination of clear evidence of hepatocarcinogenicity of bromodichloroacetic acid in male mice. In females, there were exposure concentration-dependent increases in incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma. Statistically significant increases were observed in the incidences of adenoma in all exposed groups, carcinoma in the 500 and 1,000 mg/L groups, and hepatoblastoma in the 1,000 mg/L group. For the combination of all three neoplasms, statistically significant increases were observed in all exposed groups. The exposure concentration-dependent increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma support the determination of clear evidence of hepatocarcinogenicity of bromodichloroacetic acid in female mice.

The mouse liver is a common target site for the carcinogenic effects of the trihalomethanes and haloacetic acids that occur in drinking water as disinfection by-products. The proposed mechanism of hepatocarcinogenicity of these chemicals involves both genotoxic and non-genotoxic mechanisms. In vitro, the lot of bromodichloroacetic acid that was used in the 2-year studies was mutagenic in Salmonella typhimurium strains TA97, TA98, and TA100 and the Escherichia coli strain WP2 uvrA/pkM101 over a concentration range of 500 to 6,000 µg/plate in the absence of S9. With S9, equivocal responses were seen with the three S. typhimurium tester strains, and a positive response was observed in the E. coli strain. This data supports the role of a genotoxic mechanism for the mouse liver neoplasms due to bromodichloroacetic acid.

Non-genotoxic mechanisms for the haloacetic acids may involve activation of PPARα. Trichloroacetic acid is thought to be carcinogenic, in part due to activation of PPARα^138^. In the 2-week studies, activation of PPARα by bromodichloroacetic acid was evaluated by determining hepatic acetyl-CoA hydrolase activity in F344/N rats and mice. Previous studies have used induction of hepatic acetyl-CoA hydrolase as a marker for PPARα activation.^97^ Acetyl-CoA hydrolase activity was not consistently induced by bromodichloroacetic acid in either rats or mice. If bromodichloroacetic acid activated PPARα, induction of hepatic peroxisome proliferation would have been evident in either the 3-month or 2-year studies. Because neither the induction of an enzymatic marker of PPARα activation nor peroxisome proliferation was observed in either rats or mice, it is unlikely that bromodichloroacetic acid is a PPARα activator. These findings are consistent with the literature reports that bromodichloroacetic acid does not induce PPARα activation even at high doses.^34^

The increased incidences of hepatic neoplasms were associated with increased incidences of atypical foci of cellular alteration in mice. This lesion was observed at necropsy at the 14-month interim evaluation and consisted of eosinophilic cell focus and mixed cell focus, which occurred as either single or multifocal nodular aggregates of abnormally enlarged hepatocytes that merged with the surrounding parenchyma and occasionally caused slight compression. In males at 2 years, this lesion occurred more frequently and the incidences were significantly increased in all exposed groups, while in females, the incidences of this lesion were significantly increased in the 500 and 1,000 mg/L groups. At 2 years, this lesion did not occur in the control mice. The relationship between this lesion and the hepatic neoplasms is undetermined.

Key differences in gene expression were observed between bromodichloroacetic acid-exposed adjacent nontumor liver tissue compared to control liver involving genes mostly involved in metabolic pathways, cell death, cell growth and proliferation, and neoplasia, suggesting that bromodichloroacetic acid causes specific toxic and carcinogenic effects in the liver of exposed B6C3F1/N mice. Gene changes in bromodichloroacetic acid-treated adjacent nontumor liver tissue are consistent with neoplastic signaling and may suggest microenvironmental changes preceding neoplastic transformation due to chemical exposure or a type of “field cancerization.” However, given the fact that these bromodichloroacetic acid-exposed nontumor liver tissues were isolated from sections adjacent to hepatocellular carcinoma, these gene expression changes may represent microenvironmental effects of the adjacent hepatocellular carcinoma on the histologically normal adjacent tissue.

In bromodichloroacetic acid-exposed hepatocellular carcinoma, a number of genes were altered that were either classic oncogenes involved in hepatocarcinogenesis or alterations in genes that were suggestive of loss of normal hepatic function. In terms of dysregulated cancer pathways, well known pathways involved in mouse hepatic carcinogenesis were altered including cell cycle G2/M checkpoint regulation and apoptosis regulation.

Further, bromodichloroacetic acid-treated mouse hepatoblastomas are markedly different from adjacent hepatocellular carcinoma in terms of their morphology, global gene expression, and H-ras/Ctnnb1 mutation profiles. Mouse hepatoblastoma and human hepatoblastoma share significant similarities in global gene expression, including dysregulation of genes involved in Wnt/β-catenin signaling, embryonic/stem cell pluripotency pathways, metabolic dysregulation, and expression of genomic imprinting genes. Furthermore, meta-analysis using Nextbio shows that mouse hepatoblastoma is very similar to mouse early embryonic liver in terms of gene expression profile. These findings suggest that hepatoblastoma and hepatocellular carcinoma are very different entities, likely arising from the same hepatic lineage, but hepatoblastoma arising as a result of transformation of a hepatic stem or multipotential progenitor cell. However, further studies are required to further understand the molecular tumorigenesis of hepatoblastoma and hepatocellular carcinoma.

Exposure to bromodichloroacetic acid increased the incidences of glandular epithelial hyperplasia, adenoma, and the combination of adenoma or carcinoma in the Harderian gland of male mice. The associated increased incidences of Harderian gland adenoma and the combination of adenoma or carcinoma were considered clear evidence of carcinogenicity of bromodichloroacetic acid. The determination of clear evidence is supported by the exposure concentration-dependent increase in the incidences of adenoma, at 500 and 1,000 mg/L, and the exposure concentration-dependent increased incidences of glandular epithelial hyperplasia.

Bromodichloroacetic acid exposure increased the incidences and severities of testicular and epididymal atrophy in male mice; the incidences were significantly increased in the 500 and 1,000 mg/L groups for the testes and in all exposed groups for the epididymis. Incidences of hypospermia (1,000 mg/L) and epithelium degeneration (500 and 1,000 mg/L) were also significantly increased in the epididymis of males treated with bromodichloroacetic acid. The testis was not a target in the 3-month study in mice. There were minimal changes in left testis weight, but not right testis weight, in the 3-month study in F344/N rats, and no testicular lesions were observed in the 2-year study in F344/NTac rats. Bromochloroacetic acid was evaluated in a reproductive and developmental screen by the NTP and was negative in males but caused a 16% decrease in total implants per litter and a 50% decrease in the number of live fetuses per litter in female Sprague Dawley rats following peri-conception exposure.^51^ Dibromoacetic acid has been shown to decrease the number of sperm in the caput epididymis in male rats, resulting in decreased epididymal weight.^45^ Bromochloroacetic acid also decreased the number and progressive motility of cauda epididymal sperm in male rats.^43^ Similar findings were also reported for dichloroacetic acid.^44^

Bromodichloroacetic acid is not routinely monitored by water suppliers. However, the Environmental Working Group^31^ has developed a database of chemical analysis of 47,576 water suppliers, of which 938 have tested for bromodichloroacetic acid from 2004 to 2009. The highest average level of bromodichloroacetic acid reported in drinking water was 11.12 µg/L with a range of 7.22 to 16.85 µg/L. These levels are similar to those reported by Weinberg et al.,^30^ in which bromodichloroacetic acid was reported up to 15 µg/L in 12 water supplies. At the highest end of the range, 16.85 µg/L, the concentration is approximately 15,000 times lower than the concentration used as the lowest exposure in the present study. In addition, if an adult male ingests 2 L of water/day and weighs 70 kg, then the average daily exposure is 0.48 µg/kg and is approximately 23,000 times lower than the lowest exposure of male rats from the present study. While these margins of exposure may be high, it should be noted that the lowest exposure used in the current study had statistically significant increases in a number of neoplasms, and bromodichloroacetic acid is genotoxic.

There are nine haloacetic acids, of which carcinogenicity data are available for seven either from the NTP or in the published literature. For the di- and trihaloacetic acids, the mouse liver is one of the target sites for dibromoacetic acid, bromochloroacetic acid, bromodichloroacetic acid, dichloroacetic acid, and trichloroacetic acid. Of interest is the similarity in neoplasias between bromochloroacetic acid and bromodichloroacetic acid. Both chemicals are associated with malignant mesotheliomas in male rats; mammary gland fibroadenomas in female rats; and hepatocellular adenomas, hepatocellular carcinomas, and hepatoblastomas in male and female mice. The finding of consistent neoplasias for these chemicals further supports the determination of clear evidence of carcinogenicity for bromodichloroacetic acid. Bromodichloroacetic acid exposure also increased the incidences of cutaneous and subcutaneous epithelial skin neoplasms in male rats and Harderian gland tumors in male mice, which were not increased with other haloacetic acids. The remaining mixed bromo/chloro acetic acid, dibromochloroacetic acid, has not been evaluated for carcinogenicity. The NTP has evaluated a number of the trihalomethanes and haloacetic acids that are drinking water disinfection by-products. In general, the higher the halogenation of the haloacetic acid, the greater its carcinogenic potential. In addition, it would appear that the mixed chloro/bromo haloacetic acids are associated with a greater number of neoplasias than the chlorinated- or brominated-only analogues.