# Results

## Two-week Study in F344/N Rats

All rats survived to the end of the study (Table 3). Final mean body weights and body weight gains of exposed groups of male and female rats were similar to those of the controls. Water consumption by exposed and control groups was similar. Drinking water concentrations of 62.5, 125, 250, 500, and 1,000 mg/L resulted in average daily doses of approximately 7, 15, 31, 56, and 131 mg bromodichloroacetic acid/kg body weight to males and 8, 15, 30, 58, and 113 mg/kg to females. There were no clinical findings related to bromodichloroacetic acid exposure.

Table 3 Survival, Body Weights, and Water Consumption of F344/N Rats in the Two-week Drinking Water Study of Bromodichloroacetic Acid^a^

Concentration (mg/L) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Water Consumption Week 1 | Water Consumption Week 3
Male
0 | 5/5 | 102 ± 2 | 163 ± 5 | 61 ± 4 | | 13 | 16
62.5 | 5/5 | 105 ± 2 | 170 ± 4 | 66 ± 3 | 104 | 15 | 17
125 | 5/5 | 101 ± 2 | 165 ± 4 | 64 ± 3 | 102 | 14 | 17
250 | 5/5 | 103 ± 2 | 170 ± 7 | 68 ± 5 | 105 | 16 | 17
500 | 5/5 | 102 ± 2 | 158 ± 5 | 55 ± 6 | 97 | 14 | 15
1,000 | 5/5 | 100 ± 2 | 164 ± 3 | 64 ± 3 | 101 | 15 | –^c^
Female
0 | 5/5 | 90 ± 1 | 124 ± 2 | 34 ± 1 | | 13 | 12
62.5 | 5/5 | 91 ± 2 | 125 ± 3 | 35 ± 1 | 101 | 13 | 14
125 | 5/5 | 88 ± 2 | 124 ± 2 | 36 ± 3 | 100 | 13 | 13
250 | 5/5 | 88 ± 1 | 123 ± 2 | 35 ± 1 | 99 | 12 | 13
500 | 5/5 | 90 ± 2 | 118 ± 3 | 29 ± 1 | 96 | 12 | 12
1,000 | 5/5 | 88 ± 3 | 120 ± 3 | 32 ± 2 | 97 | 11 | 12

^a^ Weights and weight changes are given as mean ± standard error. Water consumption is expressed as grams per animal per day. Differences in weights and weight changes from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 16 days/number initially in group.

^c^ Used bottle was spilled; no water consumption data available for week 3.

At the end of the 2-week study, no increases in acetyl-CoA hydrolase activities were observed in either male or female rats (Table G-1), suggesting that bromodichloroacetic acid does not activate PPARα, and these assays were not performed in the 3-month and 2-year studies.

No organ weight differences were attributed to exposure to bromodichloroacetic acid (Table H-1). No gross or microscopic lesions related to chemical exposure were observed.

Exposure Concentration Selection Rationale: Because no mortality or toxicologic effects were seen in the 2-week study, exposure concentrations selected for the 3-month drinking water study in F344/N rats were 62.5, 125, 250, 500, and 1,000 mg/L.

## Three-month Study in F344/N Rats

All rats survived until the end of the study except one female in the control group that died during week 7 (Table 4). Final mean body weights and body weight gains of 1,000 mg/L females were less than those of the controls by approximately 5% and 12%, respectively (Table 4 and Figure 3). No treatment-related effects on body weights or body weight gains were observed in male rats. Drinking water concentrations of 62.5, 125, 250, 500, and 1,000 mg/L resulted in average daily doses of approximately 5, 9, 19, 37, and 72 mg bromodichloroacetic acid/kg body weight to males and 5, 10, 20, 43, and 69 mg/kg to females. No chemical-related clinical findings were observed.

Table 4 Survival, Body Weights, and Water Consumption of F344/N Rats in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

Concentration (mg/L) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Water Consumption Week 1 (g) | Water Consumption Week 13 (g)
Male
0 | 10/10 | 115 ± 1 | 341 ± 5 | 226 ± 5 | | 16 | 16
62.5 | 10/10 | 115 ± 1 | 349 ± 8 | 234 ± 7 | 102 | 16 | 16
125 | 10/10 | 114 ± 1 | 349 ± 6 | 235 ± 7 | 102 | 16 | 17
250 | 10/10 | 116 ± 2 | 356 ± 5 | 240 ± 6 | 104 | 16 | 17
500 | 10/10 | 115 ± 2 | 350 ± 6 | 235 ± 6 | 103 | 16 | 16
1,000 | 10/10 | 113 ± 2 | 336 ± 6 | 2293 ± 6 | 99 | 14 | 15
Female
0 | 9/10^c^ | 103 ± 1 | 194 ± 3 | 91 ± 2 | | 14 | 11
62.5 | 10/10 | 103 ± 1 | 206 ± 3 | 103 ± 3 | 106 | 14 | 15
125 | 10/10 | 104 ± 1 | 203 ± 2 | 99 ± 2 | 105 | 13 | 12
250 | 10/10 | 102 ± 1 | 193 ± 3 | 90 ± 3 | 100 | 14 | 11
500 | 10/10 | 104 ± 1 | 197 ± 2 | 93 ± 2 | 101 | 14 | 12
1,000 | 10/10 | 103 ± 1 | 184 ± 2** | 80 ± 2** | 95 | 11 | 10

** Significantly different (p ≤ 0.01) from the control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Water consumption is expressed as grams per animal per day.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of death: 7.

Figure 3

Growth Curves for F344/N Rats Exposed to Bromodichloroacetic Acid in Drinking Water for Three Months

Compared to the control group, on day 3, there were mild increases (≤11%) in hematocrit values, hemoglobin concentrations, and red blood cell counts in several exposed groups of female rats, but most consistently at 1,000 mg/L (Table F-1). These increases were not seen on day 21 and were consistent with mild transient hemoconcentration, as evidenced by the decrease in water consumption by the 1,000 mg/L females. Urea nitrogen concentrations were also mildly increased in females, consistent with mild dehydration as the rats acclimated to the study; this parameter was mildly elevated in all the exposed groups on day 3 and in the 250 mg/L or greater groups on day 21. This change in urea nitrogen concentration resolved by week 14.

At week 14, the 500 and 1,000 mg/L females had mild decreases in serum total protein concentrations (Table F-1). In addition, serum albumin concentrations were mildly decreased in all exposed female groups. The magnitude of the decrease was greatest in the 1,000 mg/L females (≥11%). The decreases in the total protein concentration were driven by the decreases in albumin concentration, as albumin is a major component of the total protein concentration. The mechanism for the decrease in albumin concentration was not clear.

The absolute kidney weights of 1,000 mg/L females and relative kidney weights of 250, 500, and 1,000 mg/L females were significantly greater than those of the controls by approximately 5% to 15% (Table H-2). Relative liver weights were increased by approximately 9% in males exposed to 1,000 mg/L. These changes in organ weights, though statistically significant, were considered minor effects.

Male rats exposed to 1,000 mg/L bromodichloroacetic acid in drinking water exhibited decreased left testis weights and sperm motility (approximately 5% less than concurrent controls) (Table I-1). A similar decrease in weight was not observed in the right testis (Table H-2) or epididymis measurement (Table I-1). No correlating histopathology findings were noted. Given the small magnitude of change, inconsistent response in testis weight, and absence of correlating histopathology, the relationship of the observed changes to bromodichloroacetic acid exposure is uncertain. Female rats exposed to 250 mg/L exhibited a higher probability of extended estrus (Table I-2). Given that this was only observed at the lowest exposure concentration tested and occurred in the absence of histopathology findings, its relationship to bromodichloroacetic acid exposure is uncertain.

No chemical-related gross or histopathology findings were observed in either male or female rats.

Exposure Concentration Selection Rationale: Based on the limited effects of bromodichloroacetic acid exposure in the 3-month study, exposure concentrations selected for the 2-year drinking water study in F344/NTac rats were 250, 500, and 1,000 mg/L. Higher concentrations of bromodichloroacetic acid were not considered based on the 2-year NTP study of bromochloroacetic acid,^19^ which used these exposure concentrations and resulted in clear evidence of carcinogenicity in rats.

## Two-year Study in F344/NTac Rats

### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 5 and in the Kaplan-Meier survival curves (Figure 4). Survival of 500 and 1,000 mg/L females was significantly less than that of the controls. Early deaths in the female rats were due to moribund sacrifice of animals with mammary gland fibroadenomas and carcinomas. There was no significant effect on survival in male rats.

Table 5 Survival of F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^a^ | 8 | 8 | 8 | 8
Thirteen-month interim evaluation^a^ | 8 | 8 | 8 | 8
Moribund | 26 | 23 | 20 | 27
Natural deaths | 5 | 6 | 5 | 4
Animals surviving to study termination | 19 | 21 | 25 | 19
Percent probability of survival at end of study^b^ | 38 | 42 | 50 | 38
Mean survival (days)^c^ | 658 | 655 | 676 | 654
Survival analysis^d^ | P = 1.000 | P = 0.648N | P = 0.186N | P = 1.000
Female
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^a^ | 8 | 8 | 8 | 8
Thirteen-month interim evaluation^a^ | 8 | 8 | 8 | 8
Moribund | 10 | 22 | 42 | 44
Natural deaths | 6 | 2 | 1 | 4
Animals surviving to study termination | 34 | 26 | 7 | 2
Percent probability of survival at end of study | 68 | 52 | 14 | 4
Mean survival (days) | 694 | 683 | 616 | 589
Survival analysis | P < 0.001 | P = 0.141 | P < 0.001 | P < 0.001

^a^ Censored from survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored and terminal kill).

^d^ The result of the life table trend test^105^ is in the control column, and the results of the life table pairwise comparisons^104^ with the controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

Figure 4

Kaplan-Meier Survival Curves for F344/NTac Rats Exposed to Bromodichloroacetic Acid in Drinking Water for Two Years

### Body Weights, Water and Compound Consumption, Clinical Findings, and Organ Weights

The mean body weights of 1,000 mg/L males were approximately 10% less than those of controls after week 89 (Table 6; Figure 5). This was associated with an approximately 10% decrease in water consumption (Table K-1). Body weights of the 1,000 mg/L females were 10% less than those of the controls after week 13 and dropped to about 80% of controls by 52 weeks (Table 7; Figure 5). In 1,000 mg/L females, water consumption was less during the first year of the study but similar to control values during the second year (Table K-2). The decreased body weight and moribundity and mortality appears unrelated to the decreased water intake in the females. Drinking water concentrations of 250, 500, and 1,000 mg/L resulted in average daily doses of approximately 11, 21, and 43 mg bromodichloroacetic acid/kg body weight to males and approximately 13, 28, and 57 mg/kg to females. No clinical findings related to chemical exposure were observed. At the 6-month interim evaluation, absolute and relative liver weights of 500 mg/L females were significantly increased, as was the relative live weight in 1,000 mg/L females (Table H-3).

Table 6 Mean Body Weights and Survival of Male F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 94 | 66 | 93 | 99 | 66 | 93 | 99 | 66 | 94 | 100 | 66
29 | 211 | 66 | 206 | 98 | 66 | 205 | 97 | 66 | 201 | 95 | 66
57 | 282 | 66 | 276 | 98 | 66 | 270 | 96 | 66 | 267 | 95 | 66
85 | 330 | 66 | 321 | 97 | 66 | 312 | 95 | 66 | 309 | 94 | 66
113 | 365 | 66 | 356 | 98 | 66 | 345 | 95 | 66 | 342 | 94 | 66
141 | 395 | 66 | 382 | 97 | 65 | 370 | 94 | 66 | 367 | 93 | 66
169 | 420 | 66 | 405 | 97 | 65 | 393 | 94 | 66 | 387 | 92 | 66
197^a^ | 431 | 58 | 420 | 97 | 57 | 407 | 95 | 58 | 400 | 93 | 58
225 | 449 | 58 | 438 | 97 | 57 | 425 | 95 | 58 | 417 | 93 | 58
253 | 464 | 58 | 449 | 97 | 57 | 438 | 94 | 58 | 430 | 93 | 58
281 | 478 | 58 | 464 | 97 | 57 | 452 | 95 | 58 | 440 | 92 | 58
309 | 490 | 58 | 474 | 97 | 56 | 462 | 94 | 58 | 451 | 92 | 58
337 | 500 | 58 | 486 | 97 | 56 | 474 | 95 | 58 | 457 | 91 | 58
365 | 510 | 58 | 491 | 96 | 56 | 479 | 94 | 58 | 463 | 91 | 58
393^a^ | 517 | 49 | 498 | 96 | 48 | 484 | 94 | 50 | 470 | 91 | 49
421 | 520 | 49 | 502 | 97 | 48 | 486 | 94 | 50 | 472 | 91 | 49
449 | 524 | 49 | 505 | 96 | 48 | 490 | 94 | 49 | 472 | 90 | 48
477 | 527 | 48 | 506 | 96 | 48 | 492 | 94 | 48 | 473 | 90 | 47
505 | 526 | 48 | 511 | 97 | 48 | 497 | 95 | 47 | 473 | 90 | 45
533 | 528 | 48 | 512 | 97 | 43 | 500 | 95 | 46 | 470 | 89 | 45
561 | 519 | 45 | 507 | 98 | 42 | 496 | 95 | 46 | 472 | 91 | 43
589 | 509 | 40 | 504 | 99 | 42 | 496 | 97 | 43 | 470 | 92 | 39
617 | 509 | 34 | 503 | 99 | 37 | 491 | 96 | 41 | 468 | 92 | 37
645 | 512 | 32 | 498 | 97 | 33 | 482 | 94 | 38 | 457 | 89 | 32
673 | 494 | 26 | 479 | 97 | 32 | 474 | 96 | 35 | 445 | 90 | 27
701 | 485 | 20 | 465 | 96 | 25 | 468 | 96 | 29 | 434 | 89 | 23
Mean for Weeks
1–13 | 229 | | 224 | 98 | | 220 | 96 | | 218 | 95
14–52 | 444 | | 430 | 97 | | 418 | 94 | | 410 | 92
53–101 | 514 | | 499 | 97 | | 487 | 95 | | 465 | 90

^a^ Animals removed for interim evaluations during weeks 27 and 54.

Figure 5

Growth Curves for F344/NTac Rats Exposed to Bromodichloroacetic Acid in Drinking Water for Two Years

Table 7 Mean Body Weights and Survival of Female F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 87 | 66 | 87 | 100 | 66 | 88 | 100 | 66 | 88 | 100 | 66
29 | 147 | 66 | 145 | 99 | 66 | 143 | 97 | 66 | 138 | 94 | 66
57 | 175 | 66 | 171 | 98 | 66 | 167 | 95 | 66 | 159 | 91 | 66
85 | 189 | 66 | 184 | 98 | 66 | 180 | 95 | 66 | 171 | 90 | 66
113 | 202 | 66 | 195 | 96 | 66 | 191 | 94 | 66 | 178 | 88 | 66
141 | 213 | 66 | 204 | 96 | 66 | 198 | 93 | 66 | 186 | 87 | 66
169 | 223 | 66 | 212 | 95 | 66 | 206 | 92 | 66 | 191 | 86 | 66
197^a^ | 231 | 58 | 220 | 95 | 58 | 212 | 92 | 58 | 197 | 85 | 58
225 | 241 | 58 | 229 | 95 | 58 | 221 | 92 | 58 | 204 | 85 | 58
253 | 250 | 58 | 238 | 95 | 58 | 227 | 91 | 58 | 210 | 84 | 57
281 | 258 | 58 | 246 | 95 | 58 | 235 | 91 | 58 | 214 | 83 | 57
309 | 266 | 58 | 255 | 96 | 58 | 241 | 91 | 58 | 218 | 82 | 57
337 | 277 | 57 | 263 | 95 | 58 | 252 | 91 | 57 | 224 | 81 | 57
365 | 285 | 57 | 272 | 95 | 58 | 258 | 91 | 57 | 229 | 80 | 57
393^a^ | 295 | 49 | 282 | 96 | 50 | 269 | 91 | 48 | 238 | 81 | 49
421 | 304 | 49 | 293 | 96 | 50 | 276 | 91 | 48 | 244 | 80 | 47
449 | 313 | 48 | 300 | 96 | 50 | 283 | 91 | 46 | 247 | 79 | 47
477 | 321 | 48 | 306 | 95 | 50 | 290 | 90 | 46 | 251 | 78 | 47
505 | 327 | 48 | 314 | 96 | 50 | 294 | 90 | 44 | 256 | 78 | 45
533 | 334 | 48 | 320 | 96 | 50 | 300 | 90 | 43 | 260 | 78 | 40
561 | 340 | 47 | 327 | 96 | 47 | 306 | 90 | 40 | 266 | 78 | 35
589 | 344 | 47 | 328 | 95 | 43 | 307 | 89 | 34 | 272 | 79 | 30
617 | 349 | 46 | 335 | 96 | 40 | 313 | 90 | 31 | 266 | 76 | 25
645 | 353 | 41 | 338 | 96 | 35 | 312 | 88 | 18 | 268 | 76 | 7
673 | 351 | 40 | 340 | 97 | 34 | 306 | 87 | 10 | 266 | 76 | 3
701 | 348 | 36 | 342 | 98 | 32 | 312 | 90 | 9 | 265 | 76 | 3
Mean for Weeks
1–13 | 150 | | 147 | 98 | | 145 | 97 | | 139 | 94
14–52 | 240 | | 229 | 95 | | 220 | 92 | | 202 | 85
53–101 | 328 | | 315 | 96 | | 294 | 90 | | 256 | 78

^a^ Animals removed for interim evaluations during weeks 27 and 54.

## Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of mesothelioma and neoplasms and/or nonneoplastic lesions of the mammary gland, skin, large intestine, brain, bone marrow, liver, oral cavity (oral mucosa and tongue), and spleen. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for male rats and Appendix B for female rats.

Mammary Gland: Fibroadenoma was noted in all exposed groups of males (Table 8, Table A-1, and Table A-2). In females, there were positive trends in the incidences of fibroadenoma; carcinoma; and fibroadenoma, adenoma, or carcinoma (combined) (Table 8, Table B-1, Table B-2). The incidences of fibroadenoma and of the combined neoplasms in all exposed groups were significantly greater than the control incidences, as was the incidence of carcinoma at 1,000 mg/L. In both male and female rats, mammary gland fibroadenomas were characterized by multiple, discrete, variably sized islands of well differentiated glandular alveoli that frequently contained secretory material within abundant fibrous connective tissue stroma. In the case of female mammary gland adenoma, the neoplasm was well demarcated from the adjacent mammary tissue. The regular architecture of the gland was distorted, and there was an increase in size and variability in diameter of glandular lobules. Mammary gland carcinomas occasionally arose within fibroadenomas and consisted of epithelium arranged in alveolar, papillary, or solid patterns. Neoplastic alveolar epithelium often piled up to 10 layers thick and the nuclear/cytoplasmic ratio was increased in epithelial cells. Mammary gland carcinomas sometimes contained areas of squamous differentiation and/or central areas of necrosis.

Table 8 Incidences of Neoplasms and Nonneoplastic Lesions of the Mammary Gland in F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Number Necropsied | 50 | 50 | 50 | 50
Hyperplasia^a^ | 6 (1.2)^b^ | 1* (1.0) | 2 (1.0) | 1 (1.0)
Fibroadenoma^c^ | 0 | 2 | 3 | 1
Female
Number Necropsied | 50 | 50 | 50 | 50
Hyperplasia | 0 | 4 (1.3) | 2 (1.5) | 10** (1.2)
Fibroadenoma, Multiple | 6 | 34** | 37** | 27**
Fibroadenoma (includes multiple)^d^
Overall ratee | 28/50 (56%) | 47/50 (94%) | 47/50 (94%) | 39/50 (78%)
Adjusted rate^f^ | 60.1% | 96.6% | 99.1% | 89.6%
Terminal rate^g^ | 21/34 (62%) | 26/26 (100%) | 7/7 (100%) | 2/2 (100%)
First incidence (days) | 551 | 558 | 449 | 414
Poly-3 test^h^ | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Adenoma^i^ | 1 | 2 | 3 | 1
Carcinoma^i^
Overall rate | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 8/50 (16%)
Adjusted rate | 0.0% | 2.3% | 9.1% | 25.8%
Terminal rate | 0/34 (0%) | 0/26 (0%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | –^j^ | 558 | 533 | 509
Poly-3 test | P < 0.001 | P = 0.492 | P = 0.074 | P < 0.001
Adenoma or Carcinoma^k^ | 1 | 3 | 6* | 9**
Fibroadenoma, Adenoma, or Carcinoma^l^
Overall rate | 28/50 (56%) | 47/50 (94%) | 48/50 (96%) | 42/50 (84%)
Adjusted rate | 60.1% | 96.6% | 99.4% | 92.5%
Terminal rate | 21/34 (62%) | 26/26 (100%) | 7/7 (100%) | 2/2 (100%)
First incidence (days) | 551 | 558 | 386 | 414
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001

* Significantly different (P ≤ 0.05) from the control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for 2-year studies (all routes): 1/100.

^d^ Historical control incidence: 46/100.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^i^ Historical control incidence: 2/100.

^j^ Not applicable; no neoplasms in animal group.

^k^ Historical control incidence: 4/100.

^l^ Historical control incidence: 48/100.

Increased incidences of hyperplasia of the mammary gland were noted in all female exposed groups; the incidence in the 1,000 mg/L group was significantly increased. In most cases, the severity assigned was minimal. Mammary gland hyperplasia is characterized by enlarged lobules with increased numbers of alveoli of variable sizes lined usually by a single layer of well differentiated epithelium with minimal cellular atypia. The interlobular ducts and the alveoli are separated by scant collagenous connective tissue stroma.

Malignant Mesothelioma: In the testis at 13 months, two 500 mg/L males and five 1,000 mg/L males had malignant mesothelioma, and the incidence in the 1,000 mg/L group was significantly increased (Table 9). Minimal to moderate hyperplasia of the mesothelial layer was also observed in these groups [0 mg/L, 0/8; 250 mg/L, 0/8; 500 mg/L, 1/8 (1.0); 1,000 mg/L, 3/8 (2.0)]. Malignant mesothelioma was characterized by discrete proliferative single or multiple layers of plump mesothelial cells often overlying fibrovascular cores, and these neoplasms occasionally invaded the subjacent tissues.

Table 9 Incidences of Malignant Mesothelioma in Male F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Thirteen-month Interim Evaluation
Number with Testis Examined Microscopically | 8 | 8 | 8 | 8
Malignant Mesothelioma, Bilateral^a^ | 0 | 0 | 1 | 1
Malignant Mesothelioma (includes bilateral)^b^ | 0 | 0 | 2 | 5*
Two-year Study
Multiple Organs, Malignant Mesothelioma^c^
Overall rate^d^ | 1/50 (2%) | 12/50 (24%) | 18/50 (36%) | 37/50 (74%)
Adjusted rate^e^ | 2.6% | 28.0% | 40.6% | 77.5%
Terminal rate^f^ | 0/19 (0%) | 3/21 (14%) | 10/25 (40%) | 12/19 (63%)
First incidence (days) | 683 | 309 | 442 | 389
Poly-3 test^g^ | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001

* Significantly different (P ≤ 0.05) from the control group by the Fisher exact test.

^a^ Number of animals with neoplasm.

^b^ Historical control data not available.

^c^ Historical control incidence for 2-year studies (all routes): 3/100.

^d^ Number of animals with neoplasm per number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

The incidences of malignant mesothelioma in multiple organs at 2 years occurred with a positive trend and were significantly increased in all exposed groups (Table 9 and Table A-2). Mesotheliomas were seen primarily in the tunica vaginalis of the testis and epididymis and in some cases extended to the seminal vesicle and prostate gland of male rats.

Histologically, malignant mesotheliomas were characterized by areas of mesothelial proliferation along the peritoneal surface of the tunica vaginalis of male reproductive tissues and comprised plump papillary projections of neoplastic mesothelial cells overlying fibrovascular cores (Figure 9). The most prominent proliferations were generally located along the epididymides with smaller areas associated with the testes, seminal vesicles, and prostate gland.

Skin: The incidences of basal cell adenoma or carcinoma (combined) in males occurred with a positive trend, and the 1,000 mg/L group incidence was significantly greater than the control incidence (Table 10, Table A-1, and Table A-2). Microscopically, basal cell adenomas were present as elevated nodules that extended into the dermis and were composed of ribbons and cords of basal cells separated by a thin fibrovascular stroma. In some of these cases, there was multifocal sebaceous differentiation. The superficial surface of some basal cell adenomas was ulcerated and contained small areas of hemorrhage. Basal cell carcinoma consisted of an epithelial mass that extended far into the dermis and was composed of basal cells arranged in cords, nests, and solid sheets. Basal cell carcinomas displayed moderate nuclear pleomorphism and numerous mitotic figures. Frequently, areas of squamous and sebaceous differentiation were present, as well as small areas of necrosis and associated inflammation.

Table 10 Incidences of Neoplasms of the Skin in Male F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Number Necropsied | 50 | 50 | 50 | 50
Squamous Cell Papilloma^a, b^ | 3 | 1 | 0 | 1
Keratoacanthoma, Multiple | 0 | 0 | 0 | 3
Keratoacanthoma (includes multiple)^c^
Overall rate^d^ | 7/50 (14%) | 3/50 (6%) | 10/50 (20%) | 15/50 (30%)
Adjusted rate^e^ | 17.3% | 7.6% | 23.2% | 37.1%
Terminal rate^f^ | 1/19 (5%) | 2/21 (10%) | 5/25 (20%) | 7/19 (37%)
First incidence (days) | 544 | 716 | 493 | 621
Poly-3 test^g^ | P = 0.003 | P = 0.162N | P = 0.346 | P = 0.035
Basal Cell Adenoma^h^ | 0 | 0 | 4 | 4
Basal Cell Carcinoma^i^ | 0 | 0 | 0 | 1
Basal Cell Adenoma or Carcinoma^h^
Overall rate | 0/50 (0%) | 0/50 (0%) | 4/50 (8%) | 5/50 (10%)
Adjusted rate | 0.0% | 0.0% | 9.3% | 12.8%
Terminal rate | 0/19 (0%) | 0/21 (0%) | 1/25 (4%) | 3/19 (16%)
First incidence (days) | –^j^ | – | 513 | 629
Poly-3 test | P = 0.004 | —^k^ | P = 0.074 | P = 0.030
Squamous Cell Carcinoma^l^ | 0 | 1 | 1 | 0
Squamous Cell Papilloma, Keratoacanthoma, Basal Cell Adenoma, Basal Cell Carcinoma, or Squamous Cell Carcinoma^i^
Overall rate | 9/50 (18%) | 5/50 (10%) | 14/50 (28%) | 19/50 (38%)
Adjusted rate | 22.2% | 12.7% | 31.8% | 46.8%
Terminal rate | 2/19 (11%) | 3/21 (14%) | 7/25 (28%) | 10/19 (53%)
First incidence (days) | 544 | 716 | 493 | 621
Poly-3 test | P < 0.001 | P = 0.201N | P = 0.226 | P = 0.014
Sebaceous Gland, Adenoma^m^ | 0 | 2 | 2 | 2
Squamous Cell Papilloma, Keratoacanthoma, Sebaceous Gland Adenoma, Basal Cell Adenoma, Basal Cell Carcinoma, or Squamous Cell Carcinoma^m^
Overall rate | 9/50 (18%) | 7/50 (14%) | 15/50 (30%) | 21/50 (42%)
Adjusted rate | 22.2%. | 17.4% | 33.7% | 50.4%
Terminal rate | 2/19 (11%) | 4/21 (19%) | 7/25 (28%) | 10/19 (53%)
First incidence (days) | 544 | 509 | 493 | 436
Poly-3 test | P < 0.001 | P = 0.397N | P = 0.171 | P = 0.005
Subcutaneous Tissue, Fibroma, Multiple | 0 | 1 | 0 | 2
Subcutaneous Tissue, Fibroma (includes multiple)^m^
Overall rate | 4/50 (8%) | 6/50 (12%) | 10/50 (20%) | 15/50 (30%)
Adjusted rate | 10.2% | 14.8% | 23.3% | 36.0%
Terminal rate | 2/19 (11%) | 2/21 (10%) | 7/25 (28%) | 7/19 (37%)
First incidence (days) | 657 | 595 | 442 | 467
Poly-3 test | P < 0.001 | P = 0.391 | P = 0.098 | P = 0.005

^a^ Number of animals with neoplasm.

^b^ Historical control incidence for 2-year studies (all routes): 3/100.

^c^ Historical control incidence: 11/100.

^d^ Number of animals with neoplasm per number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^h^ Historical control incidence: 2/100.

^i^ Historical control incidence: 0/100.

^j^ Not applicable; no neoplasms in animal group.

^k^ Value of statistic cannot be computed.

^l^ Historical control incidence: 1/100.

^m^ No historical control data available.

Two incidences of sebaceous gland adenoma were noted in each exposed group of males. Histologically, sebaceous gland adenomas were characterized by well circumscribed lobular dermal masses composed of irregularly shaped acini of sebaceous epithelium containing abundant foamy cytoplasm lined by a thin layer of basal epithelium.

The incidences of keratoacanthoma in males exposed to 500 and 1,000 mg/L were increased (significantly for the 1,000 mg/L group) and occurred with a positive trend. Keratoacanthoma is a well demarcated cup-shaped mass arising in the epithelium and extending into the dermis. The central portion of these masses was filled with abundant layers of desquamated keratin debris and lined by a thickened layer of squamous epithelium.

The combined incidence of squamous cell papilloma, keratoacanthoma, sebaceous gland adenoma, basal cell adenoma, basal cell carcinoma, or squamous cell carcinoma in 1,000 mg/L males was significantly increased.

Also, in males, exposure concentration-related increased incidences of fibroma in the subcutaneous tissue were noted in the exposed groups, and the increase was significant in the 1,000 mg/L group. Fibroma is a noninvasive expansile circumscribed neoplasm consisting of proliferative fibrocytes in an abundant collagenous stroma. Mitoses and cellular atypia are minimal to absent.

Large Intestine: At 6 and 13 months, no significant microscopic findings were present in the colon. At 2 years, no adenomas of the large intestine (cecum, colon, or rectum) were observed in the male control group or the 250 mg/L group, while one and two adenomas were observed in the 500 and 1,000 mg/L groups of the males (Table 11 and Table A-1). There were one, zero, one, and two adenomas of the large intestine (cecum, colon, or rectum) in the control, 250, 500, and 1,000 mg/L groups of females, respectively (Table 11 and Table B-1).

Table 11 Incidences of Adenoma of the Large Intestine in F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Cecum^a^ | 50 | 50 | 49 | 50
Adenoma^b, c^ | 0 | 0 | 1 | 0
Colon | 50 | 50 | 50 | 50
Adenoma^d^ | 0 | 0 | 1 | 1
Rectum | 50 | 50 | 50 | 50
Adenoma^d^ | 0 | 0 | 0 | 1
Colon or Rectum: Adenoma^d^
Overall rate^e^ | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate^f^ | 0.0% | 0.0% | 2.4% | 5.2%
Terminal rate^g^ | 0/19 (0%) | 0/21 (0%) | 1/25 (4%) | 2/19 (11%)
First incidence (days) | –^i^ | – | 726 (T) | 726 (T)
Poly-3 test^h^ | P = 0.068 | —^j^ | P = 0.516 | P = 0.235
Cecum, Colon, or Rectum: Adenoma^c^
Overall rate | 0/50 (0%) | 0/50 (0%) | 2/50 (4%) | 2/50 (4%)
Adjusted rate | 0.0% | 0.0% | 4.8% | 5.2%
Terminal rate | 0/19 (0%) | 0/21 (0%) | 2/25 (8%) | 2/19 (11%)
First incidence (days) | – | – | 726 (T) | 726 (T)
Poly-3 test | P = 0.082 | — | P = 0.254 | P = 0.235
Female
Colon | 50 | 50 | 50 | 50
Adenoma^d^ | 0 | 0 | 0 | 2
Rectum | 50 | 50 | 50 | 50
Adenoma^k^ | 1 | 0 | 1 | 0
Colon or Rectum: Adenoma^k^
Overall rate | 1/50 (0%) | 0/50 (0%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 2.2% | 0.0% | 3.1% | 7.0%
Terminal rate | 1/34 (3%) | 0/26 (0%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | 727 (T) | – | 643 | 631
Poly-3 test | P = 0.165 | P = 0.511N | P = 0.684 | P = 0.353

(T) Terminal kill.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with neoplasm.

^c^ No historical control data available.

^d^ Historical control incidence for 2-year studies (all routes): 0/100.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^i^ Not applicable; no neoplasms in animal group.

^j^ Value of statistic cannot be computed.

^k^ Historical control incidence: 1/100.

The adenomas consisted of well circumscribed solitary exophytic masses composed of single to multiple layered neoplastic epithelial cells arranged in variably differentiated acinar structures and overlying a broad fibromuscular stalk. The neoplastic cells were tall, columnar with indistinct borders, moderate amphophilic cytoplasm, ovoid nuclei with finely stippled chromatin and up to three nucleoli. Epithelial cells often piled up to six layers thick and the mitotic index averaged up to six per high power field among all cases. The neoplastic cells had increased basophilia when compared to the adjacent unaffected intestinal epithelium due to loss of goblet cells and a decreased amount of intervening fibrous connective tissue.

Brain: Sporadic incidences of brain neoplasms were seen in control and exposed groups of males and females in the original three sections of the brain examined (Table 12, Table A-1, and Table B-1). These included glioma, oligodendroglioma, and benign granular cell tumors of the meninges. Due to the microscopic and focal nature of these lesions, an extended evaluation of additional brain sections, up to nine per animal, was conducted. No additional neoplasms were found in females. One control male had a glioma, and one additional 500 mg/L male had an oligodendroglioma; benign granular cell tumors of the meninges were found in one male each in the 250 and 1,000 mg/L groups. Based on the combined original and extended evaluations, there were no statistically significant differences between exposed and control incidences of glioma or oligodendroglioma (combined) or the benign granular cell tumors of the meninges based on the Poly-3 test in either males or females.

Table 12 Incidences of Neoplasms of the Brain and Meninges in F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Original Evaluation
Number Examined Microscopically | 50 | 50 | 50 | 50
Brain, Glioma^a, b^ | 0 | 1 | 2 | 2
Brain, Oligodendroglioma NOS^b^ | 0 | 0 | 1 | 1
Brain, Glioma or Oligodendroglioma^b^
Overall rate^c^ | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate^d^ | 0.0% | 2.5% | 7.1% | 7.7%
Terminal rate^e^ | 0/19 (0%) | 1/21 (5%) | 0/25 (0%) | 0/19 (0%)
First incidence (days) | –^g^ | 726 (T) | 685 | 644
Poly-3 test^f^ | P = 0.066 | P = 0.504 | P = 0.134 | P = 0.119
Meninges, Granular Cell Tumor Benign^h^ | 2 | 0 | 0 ^k^ | 0
Extended Evaluation
Number Examined Microscopically | 50 | 50 | 50 | 50
Brain, Glioma | 1 | 0 | 0 | 0
Brain, Oligodendroglioma NOS | 0 | 0 | 1 | 0
Meninges, Granular Cell Tumor Benign | 0 | 1 | 0 | 1
Original and Extended Evaluations (Combined)
Number Examined Microscopically | 50 | 50 | 50 | 50
Brain, Glioma | 1 | 1 | 2 | 2
Brain, Oligodendroglioma NOS | 0 | 0 | 2 | 1
Brain, Glioma or Oligodendroglioma
Overall rate | 1/50 (2%) | 1/50 (2%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 2.6% | 2.5% | 9.5% | 7.7%
Terminal rate | 0/19 (0%) | 1/21 (5%) | 1/25 (4%) | 0/19 (0%)
First incidence (days) | 719 | 726 (T) | 685 | 644
Poly-3 test | P = 0.162 | P = 0.757N | P = 0.204 | P = 0.306
Meninges, Granular Cell Tumor Benign | 2 | 1 | 1 | 1
Female^i^
Number Examined Microscopically | 50 | 50 | 50 | 50
Brain, Glioma^j^ | 1 | 0 | 2 | 0
Brain, Oligodendroglioma NOS^b^ | 0 | 0 | 1 | 1
Brain, Glioma or Oligodendroglioma^j^
Overall rate | 1/50 (2%) | 0/50 (0%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 2.2% | 0.0% | 9.0% | 3.5%
Terminal rate | 0/34 (0%) | 0/26 (0%) | 1/7 (14%) | 0/2 (0%)
First incidence (days) | 645 | – | 561 | 631
Poly-3 test | P = 0.266 | P = 0.512N | P = 0.207 | P = 0.647

(T) Terminal kill.

^a^ Number of animals with neoplasm.

^b^ Historical control incidence for 2-year studies (all routes) (mean ± standard deviation): 0/100.

^c^ Number of animals with neoplasm per number of animals with brain examined microscopically.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal kill.

^f^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^g^ Not applicable; no neoplasms in animal group.

^h^ Historical control incidence: 2/100.

^i^ While an extended evaluation of the female brain was conducted, no additional neoplasms were found.

^j^ Historical control incidence: 1/100.

^k^ ERRATUM: An error was identified in the NTP Technical Report on the Toxicology Studies of Bromodichloroacetic Acid (CASRN 71133-14-7) in F344/N Rats and B6C3F1/N Mice and Toxicology and Carcinogenesis Studies of Bromodichloroacetic Acid in F344/NTac Rats and B6C3F1/N Mice (Drinking Water Studies). The number of benign granular cell tumors in the meninges (original evaluation) of 500 mg/L male rats in the 2-year study was 0, rather than 1 as included in this table in the original publication of this report. This error has been corrected in this table; the new information is italicized.

Gliomas were invasive and were not clearly demarcated from the surrounding normal neuropil. The neoplastic cells occasionally demonstrated invasion of meninges and cuffing of blood vessels. Neoplastic cells had indistinct cell borders, moderate to abundant eosinophilic granular cytoplasm, and elongated nuclei. Oligodendrogliomas consisted of moderately well-demarcated tumors with small, uniformly sized neoplastic cells with small round hyperchromatic nuclei and perinuclear halos that imparted a classic honeycomb appearance. Characteristic endothelial hyperplasia and hypertrophy (vascular garlands/glomeruloid vascular proliferations) were often noted in oligodendrogliomas. Benign granular cell tumors of the meninges are usually circumscribed, noninvasive, and slightly compressive and are confined to the meninges. These tumors are characterized by a relatively homogenous neoplastic polygonal cell population within a fine vascular stroma. The neoplastic cells have a fine granular eosinophilic cytoplasm and central to eccentric round nuclei with little atypia.

Oral Cavity (oral mucosa and tongue): Hyperplasia of the epithelium was seen in one 500 and two 1,000 mg/L males, and two males in each of these groups had squamous cell papilloma (Table 13, Table A-1, and Table A-3). One male each in these groups as well as one control male had squamous cell carcinoma. Two 1,000 mg/L males had a squamous cell papilloma. One female control rat had hyperplasia of the epithelium, two females each in the 250 and 1,000 mg/L groups had squamous cell papilloma, and one 500 mg/L female had squamous cell carcinoma (Table 13, Table B-1, Table B-3).

Table 13 Incidences of Neoplasms and Nonneoplastic Lesions of the Oral Cavity (Oral Mucosa or Tongue) in F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Number Necropsied | 50 | 50 | 50 | 50
Epithelium, Hyperplasia^a^ | 0 | 0 | 1 (2.0)^b^ | 2 (2.5)
Squamous Cell Papilloma^c^ | 0 | 0 | 2 | 2
Squamous Cell Carcinoma^d^ | 1 | 0 | 1 | 1
Squamous Cell Papilloma or Squamous Cell Carcinoma^d^
Overall rate^e^ | 1/50 (2%) | 0/50 (0%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate^f^ | 2.6% | 0.0% | 7.0% | 7.7%
Terminal rate^g^ | 0/19 (0%) | 0/21 (0%) | 1/25 (4%) | 1/19 (5%)
First incidence (days) | 593 | –^i^ | 442 | 642
Poly-3 test^h^ | P = 0.105 | P = 0.498N | P = 0.338 | P = 0.302
Female
Number Necropsied | 50 | 50 | 50 | 50
Epithelium, Hyperplasia | 1 (1.0) | 0 | 0 | 0
Squamous Cell Papilloma^d^ | 0 | 2 | 0 | 2
Squamous Cell Carcinoma^c^ | 0 | 0 | 1 | 0
Squamous Cell Papilloma or Squamous Cell Carcinoma^d^
Overall rate | 0/50 (0%) | 2/50 (4%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 0.0% | 4.6% | 3.1% | 6.9%
Terminal rate | 0/34 (0%) | 0/26 (0%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | – | 588 | 533 | 529
Poly-3 test | P = 0.121 | P = 0.230 | P = 0.439 | P = 0.157

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for 2-year studies (all routes): 0/100.

^d^ Historical control incidence: 1/100.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^i^ Not applicable; no neoplasms in animal group.

All proliferative lesions in the tongue arose from the dorsal center or slightly dorsolateral surface of the tongue with no involvement of the ventral aspect of the tongue. The microscopically examined oral mucosa consisted of the dorsal palate. Squamous hyperplasia was characterized by a focal epithelial thickening composed of 20 cell layers of squamous epithelium in contrast to about a five cell layer thick normal squamous epithelium. These areas were occasionally covered by a moderate amount of laminated keratin. Rete pegs in hyperplastic regions were elongate, branching, and anastomosing, in comparison with more normal regions in which the pegs were all of similar size with a flattened ventral surface. In contrast to papillomas and carcinomas, areas of squamous hyperplasia did not form exophytic projections or significantly distort the surface of the oral mucosa or tongue. Squamous cell papillomas were characterized by focally extensive, fairly well demarcated exophytic masses projecting from the oral mucosa or the central dorsal surface of the tongue. These neoplasms were composed of squamous epithelial cells that formed multiple, elongated papillary projections thickened by orthokeratotic hyperkeratosis. Squamous cell carcinoma consisted of an unencapsulated, invasive neoplastic mass that originated from and effaced the oral mucosa or the dorsal surface of the tongue. The mass was composed of polygonal cells arranged in nests, cords, and anastomosing trabeculae supported on a dense fibrous stroma with elongate fronds that projected from the oral mucosa or the dorsal surface of the tongue.

Bone Marrow: The incidences of angiectasis in exposed groups of males and females increased with exposure concentration, and these differences were significant when compared to the control group incidences (Table 14, Table A-3, and Table B-3). Angiectasis consisted of a larger blood-filled area that exceeded the normal vascular boundary (Figure 10). The criteria for assigning severity grades to areas of angiectasis were as follows: Minimal severity was represented by one or two small focal areas of angiectasis, mild severity was used when one to three areas were present that were a little larger and encompassed up to 30% of the marrow cavity, moderate severity consisted of multiple areas that encompassed approximately 30% to 70% of the marrow cavity, and marked severity was assigned when multiple areas of angiectasis were present that filled over 70% of the marrow cavity. Sections of both femur bones were evaluated in determining severity grade. Angiectasis was occasionally surrounded by clusters of histiocytes containing intracytoplasmic pale golden yellow pigment with numerous clear acicular clefts, (Figure 11). These aggregates were considered to be a response to areas of angiectasis and therefore did not warrant a separate diagnosis.

Table 14 Incidences of Nonneoplastic Lesions of the Bone Marrow in F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Angiectasis^a^ | 4 (1.3)^b^ | 29** (1.7) | 34** (2.1) | 40** (2.1)
Hyperplasia | 17 (3.1) | 19 (2.7) | 20 (2.9) | 30* (2.7)
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Angiectasis | 1 (1.0) | 19** (1.5) | 32** (1.7) | 39** (1.7)
Hyperplasia | 23 (2.5) | 35** (2.7) | 40** (2.7) | 43** (2.7)

* Significantly different (P ≤ 0.05) from the control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Increased incidences of hyperplasia of the bone marrow were noted in all exposed groups when compared to controls; the increases were significant in all exposed groups of females and in the 1,000 mg/L males. Bone marrow hyperplasia was composed of large numbers of hematopoietic cells that completely filled the marrow cavity and reduced the number of adipocytes. The proportion of myeloid to erythroid precursors was equivalent with no single population predominating.

Liver: The incidences of eosinophilic focus were significantly increased in 1,000 mg/L males (6/50, 10/50, 7/50, 14/50, Table A-3) and 500 and 1,000 mg/L females (6/50, 13/50, 21/50, 22/50, Table B-3). Eosinophilic focus is a slightly hypereosinophilic aggregate of hepatocytes that are well demarcated, noncompressive, and blend imperceptibly with the adjacent normal hepatocytes. The hepatocytes within the focus are usually enlarged with finely granular pale or intensely eosinophilic cytoplasm and enlarged nuclei with prominent nucleoli. Significantly increased incidences of hematopoietic cell proliferation were noted in 500 and 1,000 mg/L females [3/50 (1.0), 7/50 (1.1), 14/50 (1.0), 9/50 (1.1), Table B-3]. Hematopoietic cell proliferation was characterized by multifocal aggregates of multiple hematopoietic cell lineage precursors.

Spleen: Exposure concentration-related increased incidences of hematopoietic cell proliferation in females were observed, and the increases were significant at 500 and 1,000 mg/L (6/50 (1.8), 13/50 (2.4), 29/50 (2.1), 31/50 (2.1), Table B-3). Hematopoietic cell proliferation was characterized by multifocal poorly demarcated foci of erythroid and myeloid precursors associated with megakaryocytes within the red pulp.

## Rat Mammary Gland Adenocarcinoma qPCR Arrays

Within the mammary gland adenocarcinomas from the bromodichloroacetic acid exposed female F344/NTac rats, several genes involved in the Tgfβ pathway were overrepresented. Pairwise comparison analysis identified eight genes that were significantly upregulated in mammary gland adenocarcinomas from bromodichloroacetic acid-exposed female rats compared to the spontaneous mammary gland adenocarcinomas from unexposed female rats. Five of these eight genes are associated with Tgfβ pathway signaling, including its effects on matrix remodeling, mammary gland cancer progression, tumor invasion, and metastasis (Mmp9, Mmp2, Id1, Vegfa, and Thbs1; Table N-2).

## Mice

### Two-week Study

All mice survived to the end of the study (Table 15). Final mean body weights and body weight gains of exposed groups of male and female mice were similar to those of the controls. Water consumption by exposed and control groups was similar. Drinking water concentrations of 62.5, 125, 250, 500, and 1,000 mg/L resulted in average daily doses of approximately 10, 20, 41, 84, and 175 mg bromodichloroacetic acid/kg body weight to males and 11, 16, 40, 78, and 138 mg/kg to females. There were no clinical findings related to bromodichloroacetic acid exposure.

Table 15 Survival, Body Weights, and Water Consumption of Mice in the Two-week Drinking Water Study of Bromodichloroacetic Acid^a^

Concentration (mg/L) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Water Consumption Week 1 | Water Consumption Week 3
Male
0 | 5/5 | 23.4 ± 0.4 | 26.2 ± 0.4 | 2.9 ± 0.2 | | 4 | 5
62.5 | 5/5 | 23.2 ± 0.4 | 26.4 ± 0.5 | 3.3 ± 0.3 | 101 | 4 | 5
125 | 5/5 | 23.6 ± 0.3 | 25.9 ± 0.3 | 2.3 ± 0.3 | 99 | 4 | 5
250 | 5/5 | 23.1 ± 0.6 | 26.8 ± 0.8 | 3.7 ± 0.3 | 102 | 4 | 4
500 | 5/5 | 23.6 ± 0.5 | 26.9 ± 0.7 | 3.3 ± 0.5 | 102 | 4 | 5
1,000 | 5/5 | 22.6 ± 0.7 | 26.2 ± 0.5 | 3.6 ± 0.4 | 100 | 4 | 4
Female
0 | 5/5 | 18.9 ± 0.3 | 21.5 ± 0.4 | 2.6 ± 0.4 | | 3 | 4
62.5 | 5/5 | 18.4 ± 0.2 | 21.9 ± 0.4 | 3.4 ± 0.3 | 101 | 3 | 4
125 | 5/5 | 18.7 ± 0.6 | 20.9 ± 0.5 | 2.2 ± 0.4 | 97 | 3 | 4
250 | 5/5 | 18.7 ± 0.4 | 21.3 ± 0.4 | 2.6 ± 0.3 | 99 | 3 | 4
500 | 5/5 | 19.0 ± 0.3 | 21.3 ± 0.2 | 2.3 ± 0.3 | 99 | 3 | 4
1,000 | 5/5 | 18.7 ± 0.1 | 21.3 ± 0.2 | 2.6 ± 0.2 | 99 | 2 | 4

^a^ Weights and weight changes are given as mean ± standard error. Water consumption is expressed as grams per animal per day. Differences in weights and weight changes from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 16 days/number initially in group.

Significantly decreased acetyl-CoA hydrolase activities occurred in males exposed to 125, 250, or 500 mg/L, and significantly increased activities occurred in females administered 250 or 500 mg/L (Table G-2); these assays were not performed in the 3-month and 2-year studies.

Organ weights were unaffected by exposure to bromodichloroacetic acid (Table H-4). No chemical-related gross or microscopic lesions were observed.

Exposure Concentration Selection Rationale: Due to the lack of effects of bromodichloroacetic acid exposure in the 2-week study, exposure concentrations selected for the 3-month drinking water study in mice were 62.5, 125, 250, 500, and 1,000 mg/L.

### Three-month Study

All mice survived to the end of the study (Table 16). The final mean body weight of 1,000 mg/L females was somewhat less than that of controls, but the difference was not statistically significant (Table 16 and Figure 6). Water consumption by exposed groups was similar. Drinking water concentrations of 62.5, 125, 250, 500, and 1,000 mg/L resulted in average daily doses of approximately 7, 15, 30, 59, and 123 mg bromodichloroacetic acid/kg body weight per day to males and 9, 17, 36, 70, and 129 mg/kg to females. No chemical-related clinical findings were noted.

Table 16 Survival, Body Weights, and Water Consumption of Mice in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

Concentration (mg/L) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Water Consumption Week 1 | Water Consumption Week 13
Male
0 | 10/10 | 22.3 ± 0.3 | 39.3 ± 1.0 | 17.1 ± 0.8 | | 4 | 4
62.5 | 10/10 | 22.3 ± 0.4 | 40.0 ± 0.6 | 17.6 ± 0.6 | 102 | 4 | 3
125 | 10/10 | 22.2 ± 0.3 | 39.6 ± 0.8 | 17.4 ± 0.7 | 101 | 3 | 4
250 | 10/10 | 22.6 ± 0.2 | 40.1 ± 1.0 | 17.6 ± 0.9 | 102 | 4 | 4
500 | 10/10 | 22.4 ± 0.3 | 39.8 ± 0.8 | 17.4 ± 0.9 | 101 | 4 | 3
1,000 | 10/10 | 22.0 ± 0.4 | 36.8 ± 0.7 | 14.8 ± 0.9 | 94 | 4 | 3
Female
0 | 10/10 | 18.6 ± 0.2 | 33.8 ± 0.6 | 15.2 ± 0.6 | | 3 | 3
62.5 | 10/10 | 18.6 ± 0.3 | 32.8 ± 1.3 | 14.2 ± 1.2 | 97 | 3 | 3
125 | 10/10 | 18.5 ± 0.2 | 35.4 ± 0.7 | 16.9 ± 0.8 | 105 | 3 | 4
250 | 10/10 | 18.9 ± 0.2 | 32.6 ± 0.7 | 13.7 ± 0.8 | 96 | 4 | 4
500 | 10/10 | 18.8 ± 0.2 | 33.2 ± 0.9 | 14.4 ± 1.0 | 98 | 3 | 3
1,000 | 10/10 | 18.5 ± 0.3 | 30.7 ± 0.7 | 12.2 ± 0.7 | 91 | 4 | 3

^a^ Weights and weight changes are given as mean ± standard error. Water consumption is expressed as grams per animal per day. Differences in weights and weight changes from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 6

Growth Curves for Mice Exposed to Bromodichloroacetic Acid in Drinking Water for Three Months

There were no changes in hematology parameters attributable to bromodichloroacetic acid exposure (Table F-2).

The absolute and relative liver weights of 500 and 1,000 mg/L males were significantly greater than those of the concurrent controls (Table H-5). The absolute kidney weight of 1,000 mg/L males was significantly less than that of the controls.

B6C3F1/N mice did not display any findings suggestive of an effect of bromodichloroacetic acid on the male or female reproductive system (Table I-3 and Table I-4).

Exposure Concentration Selection Rationale: Based on the limited effects of bromodichloroacetic acid exposure observed in the 3-month study, the exposure concentrations selected for the 2-year drinking water study in mice were 250, 500, and 1,000 mg/L. Higher concentrations of bromodichloroacetic acid were not considered, based on the 2-year NTP study of bromochloroacetic acid,^19^ which used these exposure concentrations and resulted in clear evidence of carcinogenicity in mice.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 17 and in the Kaplan-Meier survival curves (Figure 7). Survival of the 500 and 1,000 mg/L males was significantly decreased, but survival was unaffected by exposure in females. The most common cause of early deaths in 500 mg/L males and 1,000 mg/L males and females appeared to be liver neoplasms.

Table 17 Survival of Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^a^ | 8 | 8 | 8 | 8
14-month interim evaluation^a^ | 8 | 8 | 8 | 7
Missing^a^ | 0 | 0 | 1 | 0
Moribund | 15 | 14 | 27 | 27
Natural deaths | 10 | 15 | 10 | 14
Animals surviving to study termination | 25 | 21 | 12 | 10
Percent probability of survival at end of study^b^ | 50 | 42 | 25 | 20
Mean survival (days)^c^ | 660 | 668 | 618 | 605
Survival analysis^d^ | P < 0.001 | P = 0.824 | P = 0.016 | P = 0.002
Female
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^a^ | 8 | 8 | 8 | 8
Fourteen-month interim evaluation^a^ | 8 | 8 | 8 | 8
Moribund | 9 | 9 | 8 | 11
Natural deaths | 11 | 8 | 13 | 12
Animals surviving to study termination | 30 | 33 | 29 | 27^e^
Percent probability of survival at end of study | 60 | 66 | 58 | 54
Mean survival (days) | 680 | 683 | 681 | 680
Survival analysis | P = 0.463 | P = 0.674N | P = 1.000 | P = 0.722

^a^ Censored from survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored and terminal kill).

^d^ The result of the life table trend test^105^ is in the control column, and the results of the life table pairwise comparisons^104^ with the controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

^e^ Includes one animal that died during the last week of the study.

Figure 7

Kaplan-Meier Survival Curves for Mice Exposed to Bromodichloroacetic Acid in Drinking Water for Two Years

### Body Weights, Water and Compound Consumption, Clinical Findings, and Organ Weights

Compared to those of controls, mean body weights were over 10% less in 500 mg/L males after week 73, in 1,000 mg/L males after week 57, in 250 and 500 mg/L females after week 89, and in 1,000 mg/L females after week 73 (Figure 8, Table 18, and Table 19). Water consumption by all exposed groups of males and 250 and 500 mg/L females was generally greater than that by controls during the second year of the study (Table K-3 and Table K-4). Drinking water concentrations of 250, 500, and 1,000 mg/L resulted in average daily doses of approximately 23, 52, and 108 mg bromodichloroacetic acid/kg body weight to males and approximately 17, 34, and 68 mg/kg to females. No clinical findings related to chemical exposure were observed. At the 6-month interim evaluation, absolute and relative left and right kidney weights of 1,000 mg/L males were significantly less than those of the controls (Table H-6).

Figure 8

Growth Curves for Mice Exposed to Bromodichloroacetic Acid in Drinking Water for Two Years

Table 18 Mean Body Weights and Survival of Male Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 23.5 | 66 | 23.5 | 100 | 66 | 23.5 | 100 | 66 | 23.5 | 100 | 66
29 | 30.1 | 66 | 30.1 | 100 | 66 | 29.9 | 99 | 66 | 28.8 | 96 | 66
57 | 37.2 | 66 | 37.1 | 100 | 66 | 36.5 | 98 | 66 | 35.2 | 95 | 66
85 | 42.3 | 66 | 42.5 | 100 | 66 | 41.6 | 98 | 66 | 39.6 | 94 | 66
113 | 46.6 | 66 | 46.3 | 99 | 66 | 46.2 | 99 | 66 | 44.5 | 96 | 66
141 | 48.4 | 66 | 48.3 | 100 | 66 | 48.3 | 100 | 66 | 47.2 | 97 | 66
169 | 49.7 | 66 | 49.5 | 100 | 66 | 49.9 | 100 | 66 | 49.3 | 99 | 66
197^a^ | 50.9 | 58 | 50.7 | 100 | 58 | 50.7 | 100 | 58 | 50.2 | 99 | 58
225 | 52.3 | 58 | 51.7 | 99 | 58 | 51.9 | 99 | 58 | 51.1 | 98 | 58
253 | 53.1 | 58 | 52.3 | 99 | 58 | 52.5 | 99 | 57 | 51.8 | 98 | 58
281 | 54.1 | 58 | 53.3 | 99 | 58 | 53.4 | 99 | 57 | 52.5 | 97 | 57
309 | 54.5 | 58 | 53.6 | 98 | 58 | 53.8 | 99 | 57 | 52.3 | 96 | 57
337 | 55.6 | 58 | 54.7 | 98 | 58 | 54.8 | 99 | 57 | 53.1 | 96 | 56
365 | 55.6 | 58 | 54.7 | 99 | 58 | 54.6 | 98 | 57 | 52.3 | 94 | 55
393 | 55.8 | 58 | 54.9 | 98 | 58 | 55.2 | 99 | 57 | 51.2 | 92 | 55
421^a^ | 55.9 | 50 | 55.3 | 99 | 50 | 54.7 | 98 | 49 | 50.4 | 90 | 47
449 | 55.9 | 48 | 54.6 | 98 | 48 | 53.4 | 96 | 49 | 47.8 | 86 | 47
477 | 55.3 | 47 | 53.4 | 97 | 48 | 51.2 | 93 | 48 | 44.2 | 80 | 44
505 | 55.2 | 46 | 53.3 | 97 | 47 | 50.9 | 92 | 41 | 42.8 | 78 | 43
533 | 54.9 | 44 | 53.4 | 97 | 43 | 47.3 | 86 | 40 | 39.6 | 72 | 40
561 | 54.6 | 43 | 52.3 | 96 | 43 | 44.8 | 82 | 37 | 38.3 | 70 | 36
589 | 54.7 | 37 | 51.2 | 94 | 42 | 44.0 | 80 | 32 | 36.8 | 67 | 31
617 | 54.3 | 35 | 49.5 | 91 | 39 | 41.4 | 76 | 27 | 34.2 | 63 | 28
645 | 52.9 | 31 | 47.8 | 91 | 34 | 38.8 | 73 | 21 | 32.2 | 61 | 20
673 | 50.1 | 29 | 45.1 | 90 | 34 | 37.4 | 75 | 17 | 31.7 | 63 | 16
701 | 48.1 | 26 | 43.1 | 90 | 27 | 35.7 | 74 | 14 | 30.9 | 64 | 13
Mean for Weeks
1–13 | 33.3 | | 33.3 | 100 | | 32.9 | 99 | | 31.8 | 96
14–52 | 51.7 | | 51.2 | 99 | | 51.3 | 99 | | 50.2 | 97
53–101 | 54.1 | | 51.4 | 95 | | 46.9 | 86 | | 41.0 | 75

^a^ Animals removed for interim evaluation during weeks 27 and 57.

Table 19 Mean Body Weights and Survival of Female Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 17.9 | 66 | 17.7 | 99 | 66 | 17.8 | 99 | 66 | 17.6 | 98 | 66
29 | 22.7 | 66 | 22.8 | 100 | 66 | 22.5 | 99 | 66 | 22.4 | 99 | 66
57 | 27.8 | 66 | 28.1 | 101 | 66 | 27.3 | 98 | 66 | 27.5 | 99 | 66
85 | 33.0 | 66 | 33.4 | 101 | 66 | 32.2 | 98 | 66 | 32.0 | 97 | 66
113 | 38.4 | 66 | 38.9 | 101 | 66 | 36.8 | 96 | 66 | 36.7 | 96 | 66
141 | 42.7 | 66 | 43.3 | 102 | 66 | 42.3 | 99 | 65 | 40.4 | 95 | 66
169 | 46.6 | 66 | 47.1 | 101 | 66 | 45.7 | 98 | 65 | 43.9 | 94 | 66
197^a^ | 50.1 | 58 | 50.0 | 100 | 58 | 49.5 | 99 | 57 | 46.9 | 94 | 58
225 | 53.2 | 58 | 52.6 | 99 | 58 | 52.2 | 98 | 57 | 49.7 | 93 | 58
253 | 54.5 | 58 | 53.2 | 98 | 58 | 53.2 | 98 | 57 | 50.9 | 93 | 58
281 | 56.3 | 57 | 55.7 | 99 | 58 | 55.5 | 99 | 57 | 53.8 | 96 | 57
309 | 57.2 | 57 | 56.5 | 99 | 57 | 56.3 | 98 | 56 | 54.8 | 96 | 57
337 | 58.5 | 57 | 57.8 | 99 | 57 | 57.5 | 98 | 56 | 56.1 | 96 | 57
365 | 59.5 | 57 | 59.0 | 99 | 57 | 58.4 | 98 | 56 | 56.5 | 95 | 57
393 | 60.7 | 57 | 59.7 | 98 | 56 | 59.3 | 98 | 56 | 57.8 | 95 | 57
421^a^ | 61.3 | 49 | 60.0 | 98 | 47 | 60.3 | 98 | 47 | 58.5 | 95 | 49
449 | 61.4 | 49 | 59.9 | 97 | 47 | 60.8 | 99 | 47 | 58.0 | 94 | 49
477 | 61.6 | 49 | 59.9 | 97 | 47 | 61.0 | 99 | 47 | 56.7 | 92 | 49
505 | 61.9 | 48 | 60.0 | 97 | 47 | 61.1 | 99 | 47 | 55.8 | 90 | 48
533 | 62.1 | 48 | 60.6 | 98 | 46 | 60.8 | 98 | 47 | 52.6 | 85 | 47
561 | 62.3 | 44 | 60.3 | 97 | 44 | 60.4 | 97 | 47 | 50.8 | 82 | 45
589 | 63.0 | 42 | 58.5 | 93 | 44 | 58.2 | 92 | 46 | 48.5 | 77 | 45
617 | 63.5 | 38 | 55.9 | 88 | 44 | 56.4 | 89 | 43 | 45.5 | 72 | 41
645 | 63.5 | 37 | 53.3 | 84 | 42 | 52.8 | 83 | 42 | 42.1 | 66 | 39
673 | 62.7 | 36 | 52.4 | 84 | 37 | 47.9 | 76 | 39 | 38.9 | 62 | 34
701 | 59.9 | 34 | 49.7 | 83 | 34 | 42.4 | 71 | 34 | 36.3 | 61 | 31
Mean for Weeks
1–13 | 25.4 | | 25.5 | 100 | | 25.0 | 99 | | 24.9 | 98
14–52 | 50.8 | | 50.6 | 100 | | 49.9 | 98 | | 48.1 | 95
53–101 | 61.8 | | 57.6 | 93 | | 56.9 | 92 | | 50.6 | 82

^a^ Animals removed for interim evaluation during weeks 27 and 58.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the liver, Harderian gland, testis, and epididymis. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Liver: At necropsy, larger numbers of liver nodules and masses were observed macroscopically in exposed mice than in control mice. These most often corresponded microscopically to hepatocellular adenoma, hepatocellular carcinoma, or hepatoblastoma. At 6 months, the average severity of hepatic glycogen depletion in exposed groups was greater than that of the controls in male and female mice and increased with increasing exposure concentration in males (Table 20). The lesion was characterized by a majority of hepatocytes containing lacy diaphanous cytoplasmic vacuoles, consistent with glycogen accumulation. The decrease in cytoplasmic vacuolization is consistent with glycogen depletion which can occur with stress and may be interpreted as the minimal change seen in the 1,000 mg/L groups.

Table 20 Incidences of Neoplasms and Nonneoplastic Lesions of the Liver in Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Six-month Interim Evaluation
Number Examined Microscopically | 8 | 8 | 8 | 8
Glycogen Depletion^a^ | 8 (1.0)^b^ | 8 (1.4) | 8 (2.0) | 8 (2.4)
Fourteen-month Interim Evaluation
Number Examined Microscopically | 7 | 8 | 8 | 7
Focus of Cellular Alteration, Atypical | 1 | 2 | 4 | 6*
Hepatocellular Adenoma | 0 | 2 | 1 | 1
Hepatoblastoma | 0 | 0 | 0 | 1
Two-year Study
Number Examined Microscopically | 50 | 50 | 49 | 51
Focus of Cellular Alteration, Atypical | 0 | 19** | 42** | 43**
Hepatocellular Adenoma, Multiple | 28 | 29 | 27 | 23
Hepatocellular Adenoma (includes multiple)^c^ | 39 | 41 | 42 | 40
Hepatocellular Carcinoma, Multiple | 4 | 12* | 10 | 17**
Hepatocellular Carcinoma (includes multiple)^d^
Overall rate^e^ | 12/50 (24%) | 22/50 (44%) | 27/49 (55%) | 39/51 (76%)
Adjusted rate^f^ | 29.3% | 49.5% | 66.1% | 87.1%
Terminal rate^g^ | 7/25 (28%) | 8/21 (38%) | 7/12 (58%) | 8/10 (80%)
First incidence (days) | 548 | 511 | 480 | 260
Poly-3 test^h^ | P < 0.001 | P = 0.041 | P < 0.001 | P < 0.001
Hepatoblastoma, Multiple | 1 | 6 | 12** | 12**
Hepatoblastoma (includes multiple)^i^
Overall rate | 4/50 (8%) | 24/50 (48%) | 40/49 (82%) | 34/51 (67%)
Adjusted rate | 10.1% | 53.6% | 87.1% | 77.5%
Terminal rate | 1/25 (4%) | 8/21 (38%) | 9/12 (75%) | 5/10 (50%)
First incidence (days) | 590 | 433 | 477 | 360
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma^j^
Overall rate | 42/50 (84%) | 50/50 (100%) | 48/49 (98%) | 49/51 (96%)
Adjusted rate | 91.2% | 100.0% | 98.0% | 99.1%
Terminal rate | 25/25 (100%) | 21/21 (100%) | 11/12 (92%) | 10/10 (100%)
First incidence (days) | 449 | 433 | 477 | 260
Poly-3 test | P = 0.036 | P = 0.015 | P = 0.110 | P = 0.034
Hepatocholangiocarcinoma^k^ | 0 | 0 | 2 | 2
Female
Six-month Interim Evaluation
Number Examined Microscopically | 8 | 8 | 8 | 8
Glycogen Depletion | 8 (1.7) | 8 (2.1) | 8 (2.9) | 8 (2.5)
Fourteen-month Interim Evaluation
Number Examined Microscopically | 8 | 8 | 8 | 8
Focus of Cellular Alteration, Atypical | 0 | 2 | 3 | 4*
Hepatocellular Adenoma | 0 | 0 | 1 | 1
Two-year Study
Number Examined Microscopically | 49 | 50 | 49 | 50
Eosinophilic Focus | 22 | 33** | 38** | 40**
Focus of Cellular Alteration, Atypical | 0 | 2 | 6* | 16**
Hepatocellular Adenoma, Multiple | 25 | 38* | 37 | 37*
Hepatocellular Adenoma (includes multiple)^l^
Overall rate | 33/49 (67%) | 42/50 (84%) | 42/49 (86%) | 44/50 (88%)
Adjusted rate | 75.3% | 90.7% | 92.5% | 93.0%
Terminal rate | 26/30 (87%) | 32/33 (97%) | 28/29 (97%) | 27/27 (100%)
First incidence (days) | 540 | 386 | 597 | 503
Poly-3 test | P = 0.009 | P = 0.030 | P = 0.015 | P = 0.010
Hepatocellular Carcinoma, Multiple | 0 | 5 | 6* | 13**
Hepatocellular Carcinoma (includes multiple)^m^
Overall rate | 9/49 (18%) | 17/50 (34%) | 22/49 (45%) | 26/50 (52%)
Adjusted rate | 21.1% | 37.9% | 49.8% | 59.1%
Terminal rate | 5/30 (17%) | 13/33 (39%) | 15/29 (52%) | 20/27 (74%)
First incidence (days) | 604 | 509 | 603 | 607
Poly-3 test | P < 0.001 | P = 0.065 | P = 0.004 | P < 0.001
Hepatoblastoma, Multiple | 0 | 0 | 1 | 2
Hepatoblastoma (includes multiple)^n^
Overall rate | 0/49 (0%) | 1/50 (2%) | 4/49 (8%) | 6/50 (12%)
Adjusted rate | 0.0% | 2.3% | 9.3% | 13.9%
Terminal rate | 0/30 (0%) | 0/33 (0%) | 3/29 (10%) | 3/27 (11%)
First incidence (days) | –^o^ | 688 | 716 | 636
Poly-3 test | P = 0.003 | P = 0.506 | P = 0.062 | P = 0.016
Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma^p^
Overall rate | 36/49 (73%) | 44/50 (88%) | 43/49 (88%) | 46/50 (92%)
Adjusted rate | 81.1% | 93.7% | 94.7% | 95.5%
Terminal rate | 26/30 (87%) | 33/33 (100%) | 29/29 (100%) | 27/27 (100%)
First incidence (days) | 540 | 386 | 597 | 503
Poly-3 test | P = 0.013 | P = 0.043 | P = 0.030 | P = 0.017
Hepatocholangiocarcinoma^q^ | 0 | 0 | 0 | 1

* Significantly different (P ≤ 0.05) from the control group by the Fisher exact test (interim evaluations) or the Poly-3 test (2-year study).

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year drinking water studies with control groups (mean ± standard deviation): 72/100 (72.0% ± 8.5%), range 66%–78%; all routes: 594/949 (62.6% ± 9.1%), range 48%–78%.

^d^ Historical incidence for drinking water studies: 38/100 (38.0% ± 19.8%), range 24%–52%; all routes: 348/949 (36.7% ± 11.4%), range 22%–56%.

^e^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^i^ Historical incidence for drinking water studies: 10/100 (10.0% ± 2.8%), range 8%–12%; all routes: 40/949 (4.2% ± 3.5%), range 0%–12%.

^j^ Historical incidence for drinking water studies: 87/100 (87.0% ± 4.2%), range 84%–90%; all routes: 746/949 (78.6% ± 7.2%), range 64%–90%.

^k^ Historical incidence for drinking water studies: 2/100 (2.0% ± 2.8%), range 0%–4%; all routes: 10/949 (1.1% ± 2.2%), range 0%–8%.

^l^ Historical incidence for drinking water studies: 71/98 (72.5% ± 7.2%), range 67%–78%; all routes: 378/948 (39.9% ± 18.7%), range 14%–78%.

^m^ Historical incidence for drinking water studies: 20/98 (20.4% ± 2.9%), range 18%–22%; all routes: 152/948 (16.0% ± 10.6%), range 4%–46%.

^n^ Historical incidence for drinking water studies: 1/98 (1.0% ± 1.44%), range 0%–2%; all routes: 4/948 (0.4% ± 0.8%), range 0%–2%.

^o^ Not applicable; no neoplasms in animal group.

^p^ Historical incidence for drinking water studies: 76/98 (77.6% ± 5.8%), range 73%–82%; all routes: 448/948 (47.3% ± 19.3%), range 20%–82%.

^q^ Historical incidence for drinking water studies: 0/98; all routes: 0/948.

At 14 months, hepatocellular adenomas were noted in exposed groups of males and in 500 and 1,000 mg/L females; none were seen in the controls (Table 20). Hepatocellular adenomas were characterized by well circumscribed nodules that compressed the adjacent parenchyma and often lacked the normal lobular architecture. Cells within adenomas usually consisted of a mixture of eosinophilic, basophilic, clear, or vacuolated cells, and hepatic cords in adenomas often intersected the cords of the adjacent normal parenchyma at an angle indicating autonomous growth.

Exposure concentration-related increased incidences of atypical focus of cellular alteration (i.e., eosinophilic cell focus and mixed cell focus) were noted in all exposed groups of male and female mice at 14 months, and the incidences in 1,000 mg/L males and females were significantly increased (Table 20). This change occurred as either single or multifocal nodules. The cells within the foci displayed marked cytomegaly and karyomegaly with intranuclear invaginations and multiple nucleoli in some cases.

A single case of hepatoblastoma at 14 months was noted in males exposed to 1,000 mg/L (Table 20). Histologically, the hepatoblastoma consisted of a variably demarcated mass composed of sheets of small, elongated, hyperchromatic cells that often formed rosettes or palisaded around vessels. The center portion of the mass was necrotic and contained focal areas of mineralization.

Compared to those of the control groups at 2 years, the incidences of hepatocellular adenoma in all exposed groups of females, hepatocellular carcinoma in all exposed groups of males and 500 and 1,000 mg/L females, and hepatoblastoma in all exposed groups of males and 1,000 mg/L females were significantly increased (Table 20, Table C-1, Table C-2, Table D-1, and Table D-2). The incidences of multiple hepatocellular carcinoma and multiple hepatoblastoma in males and females and multiple hepatocellular adenoma in females were generally increased in an exposure concentration-related manner. When combined, the incidences of hepatocellular adenoma, hepatocellular carcinoma, or hepatoblastoma were significantly increased in 250 and 1,000 mg/L males and all exposed groups of females.

There were sporadic cases of hepatocholangiocarcinoma in males exposed to 500 mg/L and males and females exposed to 1,000 mg/L.

The incidences of eosinophilic focus in exposed females and atypical focus of cellular alteration (i.e., eosinophilic cell focus and mixed cell focus) in exposed groups of males and females (except 250 mg/L) were significantly greater than controls (Table 20, Table C-4, and Table D-4).

Hepatocellular adenomas were characterized as well-circumscribed nodules that compressed the adjacent parenchyma and lacked the normal lobular architecture and portal triads. Cells within adenomas usually consisted of a mixture of eosinophilic, basophilic, clear, or vacuolated cells, and hepatic cords in adenomas often intersected the cords of the adjacent normal parenchyma at an angle indicating autonomous growth. Hepatocellular carcinomas were characterized by a fairly well demarcated mass composed of broad trabeculae (greater than three hepatocytes thick) that often rounded up or formed sheets of solid growth. These masses often compressed and/or invaded the adjacent hepatic parenchyma. Neoplastic hepatocytes exhibited features of cellular atypia and increased mitotic figures and the central portion of the masses often contained hemorrhage and necrosis. Hepatoblastomas were variably demarcated masses composed of sheets of small, elongated, hyperchromatic cells that often formed rosettes or palisaded around vessels (Figure 12). These masses were often necrotic in the center and/or consisted of a blood-filled spaces surrounded by neoplastic cells. Metastasis to different organs, such as the lungs (most commonly), mesentery, mesenteric lymph nodes, and skeletal muscle, were noted (Figure 13).

Eosinophilic focus consisted of a well-demarcated collection of hepatocytes with finely granular eosinophilic cytoplasm that blended imperceptibly into the adjacent hepatic parenchyma, while larger foci caused slight compression of surrounding hepatocytes. Atypical focus of cellular alteration occurred as single or multifocal nodular aggregates of enlarged hepatocytes that merged with the surrounding parenchyma, occasionally caused slight compression in other areas, and occasionally had irregular borders. Hepatocytes within the foci had either solid eosinophilic or mixed contents (i.e., distended by multiple small discrete lipid vacuoles—microvesicular vacuolation). The lesions resembled an eosinophilic focus of altered hepatocytes, but there was cellular atypia and hypertrophy. The cells within the foci displayed marked cytomegaly and karyomegaly with intracytoplasmic accumulation of pale globular eosinophilic material in some cases. Affected hepatocytes also contained numerous intranuclear invaginations and multiple prominent nucleoli (Figure 14 and Figure 15). There was no evidence for hyperplasia within the lesions.

Harderian Gland: In males, the incidences of epithelium hyperplasia, adenoma, and carcinoma occurred with positive trends, and the incidences of adenoma and adenoma or carcinoma (combined) in the 500 and 1,000 mg/L groups were significantly greater than those in the controls (Table 21, Table C-1, Table C-2, and Table C-4). Hyperplasia of the epithelium was seen as focal areas of cellular proliferation that did not distort the architecture of the gland and did not compress the surrounding parenchyma. The epithelial cells within hyperplastic lesions maintained a thickness of one cell layer and did not display cellular atypia (Figure 16). Adenoma was a well-demarcated proliferative lesion that compressed the adjacent parenchyma and altered the tissue architecture. Neoplastic cells generally maintained a thickness of one cell layer, but occasionally piled up to project into the acinar lumen (Figure 17). Carcinoma was seen as a large, poorly demarcated mass that distorted the glandular architecture (Figure 18). Neoplastic epithelial cells displayed cellular and nuclear pleomorphism and often piled up to three or four cell layers thick. The nuclear to cytoplasmic ratio was generally increased.

Table 21 Incidences of Neoplasms and Nonneoplastic Lesions of the Harderian Gland in Male Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Number Necropsied | 50 | 50 | 49 | 51
Epithelium, Hyperplasia^a^ | 1 (2.0)^b^ | 1 (1.0) | 3 (2.3) | 4 (2.0)
Adenoma^c^
Overall rate^d^ | 6/50 (12%) | 11/50 (22%) | 14/49 (29%) | 19/51 (37%)
Adjusted rate^e^ | 14.7% | 26.1% | 38.0% | 48.8%
Terminal rate^f^ | 2/25 (8%) | 4/21 (19%) | 5/12 (42%) | 3/10 (30%)
First incidence (days) | 548 | 533 | 491 | 458
Poly-3 test^g^ | P < 0.001 | P = 0.155 | P = 0.015 | P < 0.001
Carcinoma^h^ | 0 | 0 | 0 | 3
Adenoma or Carcinoma^i^
Overall rate | 6/50 (12%) | 11/50 (22%) | 14/49 (29%) | 20/51 (39%)
Adjusted rate | 14.7% | 26.1% | 38.0% | 51.4%
Terminal rate | 2/25 (8%) | 4/21 (19%) | 5/12 (42%) | 4/10 (40%)
First incidence (days) | 548 | 533 | 491 | 458
Poly-3 test | P < 0.001 | P = 0.155 | P = 0.015 | P < 0.001

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year drinking water studies with control groups (mean ± standard deviation): 11/100 (11.0% ± 1.4%), range 10%–12%; all routes: 119/950 (12.5% ± 4.8%), range 4%–22%.

^d^ Number of animals with neoplasm per number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Historical incidence for drinking water studies: 2/100 (2.0% ± 2.8%), range 0%–4%; all routes: 34/950 (3.6% ± 2.9%), range 0%–10%.

^i^ Historical incidence for drinking water studies: 13/100 (13.0% ± 1.4%), range 12%–14%; all routes: 153/950 (16.1% ± 4.9%), range 6%–24%.

Testis and Epididymis: The incidences and severities of atrophy of the testis increased with increasing exposure concentration, and the increases at 500 and 1,000 mg/L were significant (Table 22 and Table C-4). Atrophy was characterized by testicular tubular degeneration seen as reduced numbers of germinal epithelial cells within seminiferous tubules in comparison to normal tubules. Spermatozoa were often fewer or absent in affected tubular lumens.

Table 22 Incidences of Nonneoplastic Lesions of the Testis and Epididymis in Male Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Testes^a^ | (50) | (50) | (49) | (51)
Atrophy^b^ | 4 (1.3)^c^ | 6 (2.2) | 13** (2.4) | 23** (2.9)
Epididymis | (50) | (50) | (49) | (51)
Atrophy | 0 | 7* (1.9) | 10** (2.0) | 17** (2.1)
Hypospermia | 0 | 1 (2.0) | 0 | 17** (2.7)
Epithelium, Degeneration | 1 (3.0) | 1 (2.0) | 10** (1.6) | 6* (1.3)

* Significantly different (P ≤ 0.05) from the control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the epididymis, the incidences of atrophy in all exposed groups, hypospermia in the 1,000 mg/L group, and epithelium degeneration in the 500 and 1,000 mg/L groups were significantly increased compared to the control group incidences (Table 22 and Table C-4). Atrophy was characterized by a constellation of histologic changes including decreased size of tubules; condensation of the connective tissues surrounding the tubules, imparting a thicker appearance; and a reduction in the size of the epithelial cells lining the tubules. Hypospermia was characterized by reduced numbers of spermatozoa within tubular lumens when compared with normal epididymides. In some cases, although devoid of spermatozoa, tubular lumens were filled with sloughed epithelial cells, macrophages, or other cellular debris (Figure 19 and Figure 20). Epithelium degeneration was characterized by cellular changes affecting the epithelium lining the tubules of the epididymis including individual cell necrosis, sloughing of clusters of eosinophilic degenerative cells, excessive karyomegaly, disorganization of the epithelial layer, and flattening of abnormal cells (Figure 21).

#### Molecular Analysis of Mouse Hepatoblastoma and Hepatocellular Carcinoma

In bromodichloroacetic acid-exposed adjacent nontumor liver tissue, major oncogenic, metabolic, and hepatic function related pathways were altered compared to normal liver of control mice (Appendix O). In terms of oncogenic signaling, Ingenuity Pathway Analysis™ (IPA) showed that the top biological functions altered in adjacent nontumor liver compared to normal liver of control mice included genes involved in cancer, cellular function and maintenance, and cell morphology. The top toxicology functions perturbed in adjacent nontumor liver tissue samples included genes associated with liver injury, including liver necrosis/cell death, regeneration, and proliferation.

In bromodichloroacetic acid-exposed hepatocellular carcinoma, IPA indicated dysregulation of a variety of metabolic and cancer related pathways. Overrepresented pathways altered in bromodichloroacetic acid-exposed hepatocellular carcinoma included biological functions such as organismal function, cell movement, cancer signaling, cellular development, and cell growth and proliferation. The top overrepresented canonical pathways in hepatocellular carcinoma included fatty acid metabolism, xenobiotic signaling, cell cycle: G2/M DNA damage checkpoint regulation, aryl hydrocarbon receptor signaling, and apoptosis signaling. In bromodichloroacetic acid-exposed hepatocellular carcinoma, many of the top dysregulated cancer pathways included upregulation of oncogenes (Gpc3, Akr1c3, Plat, Itih5, Areg, Tff3, Afp) and downregulation of tumor suppressor genes (Dct, Gas1, Prlr, Socs2, Wnt5b) similar to that seen in human hepatocellular carcinoma.

Principal component analysis showed that hepatoblastoma samples clustered distinctly from hepatocellular carcinoma, adjacent nontumor liver tissue, and normal liver of control mice. Compared to adjacent nontumor liver tissue, there were 10,346 differentially expressed genes in hepatoblastoma. Genes involved in Wnt/Ctnnb1 pathway signaling were dysregulated in hepatoblastoma, including upregulation of various Wnt signaling genes (Wnt9a, Wnt10a, Wnt7a), genes involved in Wnt feedback-regulation (Axin2, Nkd1), positive effectors (Lef1, Dvl3), and Wnt antagonists (Dkk2, Dkk3, Wif1). Secondly, there was significant upregulation of a number of genes involved in genomic imprinting (Igf2, Peg1, Peg10, Bex1, Meg3, H19, Ndn), which are typically expressed in fetal liver. Finally, genes involved in embryonic stem cell pluripotency (T, Bmp4, Fzd6, Fzd10, Nog) and stem cell-related target genes (Sox9, Tbx3, Suz12) were upregulated, while Zfp42, Gata4, Fzd4, and Fzd8 were downregulated, indicating distinctive expression of hepatic stem/progenitor markers. Meta-analysis of hepatoblastoma using NextBio also revealed high concordance with embryonic mouse liver (E10.5 to 12.5). Gene network and pathway analysis using IPA revealed significant alterations in pathways involved in hepatic development, metabolic pathways, embryonic stem cell regulation, and genomic imprinting in hepatoblastoma compared to hepatocellular carcinoma.

Further, bromodichloroacetic acid-exposed hepatoblastoma and hepatocellular carcinoma showed relatively low incidence of H-ras mutation and high incidence of β-catenin mutation, compared to historical spontaneous hepatocellular carcinoma. Between hepatoblastoma and hepatocellular carcinoma from exposed mice, there was not much difference in the incidences of H-ras (7% and 13%, respectively) and β-catenin mutations (23% and 10%, respectively). Interestingly, for hepatoblastoma and its adjacent hepatocellular carcinoma, the mutation spectra were different and there was no mutation overlap for H-ras and β-catenin genes.

## Genetic Toxicology

Bromodichloroacetic acid was tested in two independent bacterial gene mutation assays. The first assay used a sample of the compound that had not been analytically characterized by the NTP; the second assay was conducted on the NTP-procured bioassay sample of bromodichloroacetic acid that had been extensively characterized. In the first assay, bromodichloroacetic acid (concentration range of 100 to 10,000 µg/plate) was judged to be weakly positive based on a pattern of responses seen in Salmonella typhimurium strain TA97 in the presence of various concentrations of induced rat or hamster S9 metabolic activation mix; an equivocal response was obtained in TA97 in the absence of S9, and no mutagenic activity was seen in S. typhimurium strains TA98, TA100, or TA1535 (Table E-1).

In the second assay, conducted with the same lot of bromodichloroacetic acid that was used in the 2-year bioassays, positive responses were seen in S. typhimurium strains, TA97, TA98, and TA100 and the Escherichia coli strain WP2 uvrA/pkM101 over a concentration range of 500 to 6,000 µg/plate in the absence of S9 (Table E-2). With S9, equivocal responses were seen with the three S. typhimurium strains and a positive response was observed in the E. coli strain. Thus, these two different samples of bromodichloroacetic acid gave different results in bacterial gene mutation assays, but the clearest indication of mutagenic activity was seen in the second assay conducted with the bioassay lot of bromodichloroacetic acid.

In vivo, no significant increases in the frequencies of micronucleated normochromatic In vivo, no significant increases in the frequencies of micronucleated normochromatic erythrocytes were observed in blood samples from male or femalerange of 62.5 to 1,000 mg/L) in drinking water for 3 months (Table E-3). Small increases were seen in the percentage of polychromatic erythrocytes (reticulocytes) among total red blood cells in the highest exposure concentration groups of male and female mice, but these were not statistically significant.

Figure 9

Malignant Mesothelioma Growing on the Epididymis of a Male F344/NTac Rat Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note the plump papillary projections of mesothelial cells (arrows) covering a fibrovascular core.

Figure 10

Bone Marrow Angiectasis in a Male F344/NTac Rat Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note the presence of multiple larger blood-filled areas that exceeded the normal vascular boundary (arrows).

Figure 11

Histiocytic Cell Infiltration in the Bone Marrow of a Male F344/NTac Rat Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note the collections of histiocytic cells (arrows) close to angiectatic cavities.

Figure 12

Hepatoblastoma in the Liver of a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note hepatoblastoma composed of sheets of small, elongate, hyperchromatic cells (arrows) that often formed rosettes or palisaded around vessels.

Figure 13

Metastatic Hepatoblastoma in the Lung of the Same Male B6C3F1/N Mouse Shown in Figure 12 (H&E)

Note the neoplastic hepatoblastoma cells within a pulmonary blood vessel (arrows).

Figure 14

Focus of Cellular Alteration, Atypical, in the Liver of a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years

Note nodular aggregates of enlarged hepatocytes that merge with the surrounding parenchyma and cause slight compression. The hepatocytes within the focus have solid eosinophilic and mixed contents (i.e., distended by multiple small discrete lipid vacuoles – microvesicular vacuolation - arrows), marked cytomegaly, and intranuclear invaginations and multiple prominent nucleoli.

Figure 15

Focus of Cellular Alteration, Atypical, in the Liver of a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note nodular aggregates of enlarged hepatocytes that merge with the surrounding parenchyma and cause slight compression. The hepatocytes within the focus have solid eosinophilic contents, marked cytomegaly, intranuclear invaginations (arrows), and multiple prominent nucleoli.

Figure 16

Hyperplasia in the Harderian Gland of a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note an area of cellular proliferation that did not distort the architecture of the gland and did not compress the surrounding parenchyma (arrows). The epithelial cells within hyperplastic lesions maintained one cell layer of thickness and did not display cellular atypia.

Figure 17

Adenoma in the Harderian Gland of a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note a well-demarcated proliferative lesion (arrows) that compresses the adjacent parenchyma and does not maintain tissue architecture.

Figure 18

Carcinoma in the Harderian Gland of a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note large, poorly demarcated, locally invading mass that distorted the glandular architecture.

Figure 19

Normal Contents of Spermatozoa in a Male Control B6C3F1/N Mouse from the Two-year Drinking Water Study of Bromodichloroacetic Acid (H&E)

Figure 20

Hypospermia in the Epididymis of a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note the reduced numbers of spermatozoa within tubular lumens when compared with a normal epididymis from a control mouse (Figure 19).

Figure 21

Epithelium Degeneration in the Epididymis of a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Bromodichloroacetic Acid in Drinking Water for Two Years (H&E)

Note the cellular changes affecting the epithelium lining the tubules of the epididymis (arrows) including individual cell necrosis, sloughing of clusters of eosinophilic degenerative cells, excessive karyomegaly, disorganization of the epithelial layer, and flattening of abnormal cells.