# Materials and Methods

## Procurement and Characterization of Bromodichloroacetic Acid

Bromodichloroacetic acid was obtained from Radian International, LLC (Austin, TX), in one lot (31542-80) and from Chemfinet Services, Inc. (Tarrytown, NY), in one lot (NJ 87-90/9/2005). Lot 31542-80 was used in the 2-week and 3-month studies, and lot NJ 87-90/9/2005 was used in the 2-year studies and in one of the genetic toxicology assays. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle Chemistry Support Services (Columbus, OH) and the study laboratories at Southern Research Institute (SRI) (Birmingham, AL) for the 2-week and 3-month studies and at Battelle Columbus Operations (Columbus, OH) for the 2-year studies. Karl Fischer titration was performed by Galbraith Laboratories (Knoxville, TN), and elemental analyses were performed by Prevalere Life Sciences, Inc. (Whitesboro, NY), and Elemental Analysis Corp. (Lexington, KY) (Appendix J). Reports on analyses performed in support of the bromodichloroacetic acid studies are on file at the National Institute of Environmental Health Sciences.

Both lots of the chemical, an off-white crystalline solid, were identified as bromodichloroacetic acid by the analytical chemistry laboratory using infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by the study laboratories using IR and NMR (SRI only) spectroscopy. For lot 31542-80, Karl Fischer titration indicated 440 ppm water. High-performance liquid chromatography with ultraviolet detection (HPLC/UV) indicated one major peak and no impurities greater than 0.1% of the total peak area. Ion chromatography indicated one major peak and four impurities, each greater than 0.1% of the total peak area, with a combined area of 1.2%. Titration of the acid functional group indicated a purity of 100%, assuming all titratable acid was present as bromodichloroacetic acid. The overall purity of lot 31542-80 was estimated to be approximately 99%. For lot NJ 87-90/9/2005, Karl Fischer titration indicated approximately 0.4% water; elemental analyses for carbon and hydrogen were in agreement with theoretical values; PIXE analysis indicated the presence of carbon (13%), hydrogen (0.5%), oxygen (17%), chlorine (31%), and bromine (38%), consistent with the theoretical values; no significant impurities were detected. HPLC/UV indicated one major peak with two impurities greater than 0.1% of the major peak area with a combined area of 0.6%. These two impurities were identified as monochloroacetic acid and dibromochloroacetic acid based on retention times matching to standards. Analysis by gas chromatography (GC) with flame ionization (FID) found two impurities. The larger peak was identified as dibromochloroacetic acid by GC/mass spectroscopy and was quantified at 2.7% by standard addition followed by GC/FID analysis. Functional group titration indicated a purity of approximately 95%, assuming all titratable acid was present as bromodichloroacetic acid. The overall purity of lot NJ87-90/9/2005 was determined to be greater than 97%.

To ensure stability, lot 31542-80 was stored at approximately −20°C in amber glass bottles with Teflon^®^-lined lids protected from light and moisture during the 2-week and 3-month studies. Prior to the 2-year study, a forced degradation study of a reference standard was performed by the study laboratory using HPLC/UV; no degradation occurred. For the 2-year studies, the bulk chemical was stored at −20°C in sealed amber glass bottles with Teflon^®^-lined lids, secured by tape, and placed in a sealed glove bag filled with nitrogen, or repackaged in sealed amber glass bottles under a nitrogen headspace. Periodic reanalyses of the test chemical were performed twice during the 3-month studies and at least every 6 months during the 2-year studies using HPLC/UV; no degradation of the test chemical was observed.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing bromodichloroacetic acid with tap water and stored in sealed Nalgene^®^ containers with a minimal headspace at 5°C for up to 40 (3-month studies) or 42 (2-week and 2-year studies) days (Table J-2).

Stability studies of the 62.5 mg/L dose formulation were performed by the analytical chemistry laboratory using HPLC/UV. Stability was confirmed for dose formulations stored in sealed amber glass or Nalgene^®^ high density polyethylene containers at 5°C for at least 42 days and for 7 days under simulated animal room conditions.

Periodic analyses of the dose formulations of bromodichloroacetic acid were conducted by the study laboratories using HPLC/UV. During the 2-week studies, the dose formulations were analyzed once; all five dose formulations for rats and mice were within 10% of the target concentrations (Table J-3). Animal room samples of these dose formulations were also analyzed; all five samples for rats and all five for mice were within 10% of the target concentrations. During the 3-month studies, the dose formulations were analyzed at the beginning, midpoint, and end of the studies; all 15 dose formulations for rats and mice were within 10% of the target concentrations (Table J-4). Animal room samples of these dose formulations were analyzed, and all 15 for rats and all 14 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 6 weeks, and all 63 dose formulations for rats and all 57 for mice were within 10% of the target concentrations (Table J-5). Animal room samples were also analyzed; all 12 for rats and all 12 for mice were within 10% of the target concentrations.

Tap water from the City of Columbus municipal supply was used as the vehicle. Samples of the tap water were taken within 30 days prior to the study start at 3-month intervals throughout the study, and within 30 days of the end of the in-life phase and analyzed by an NIEHS analytical contractor for total chlorates, trihalomethanes, and haloacetic acids. Bromodichloroacetic acid was measured in the tap water and was below the detection limit (approximately 0.6 µg/mL) in all samples analyzed. This detection limit was 100 times lower than the lowest concentration in the exposed animals in the 2-week and 3-month studies and 400 times lower than the lowest concentrations in the exposed animals in the 2-year studies. Note that in a nationwide study, bromodichloroacetic acid levels ranged from below detection limits to 15 µg/L^30^ and that the highest concentration reported is approximately 4,200 times lower than the lowest concentration used in the 2-week and 3-month studies and 16,666 times lower than the lowest concentration used in the 2-year studies.

## Animal Source

Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY), for the 2-week and 3-month studies. For the 2-year studies, male and female F344/NTac rats were obtained from the commercial colony at Taconic Farms, Inc., and the B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. The rationale for change of strain from F344/N to F344/NTac was a programmatic decision. For many years the NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N exhibited sporadic seizures and idiopathic chylothorax and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and the NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow the NTP time to evaluate different rat models. The F344/NTac was used in four subchronic and two chronic studies (cobalt metal and bromodichloroacetic acid) between 2005 and 2006.^95^

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-week Studies

The 2-week study was designed to determine the range of exposure levels for the 3-month study and to evaluate if bromodichloroacetic acid was a PPAR activator. On receipt, the rats and mice were 4 to 5 weeks old. Animals were quarantined for 12 (rats) or 14 (mice) days and were 5 to 6 (rats) or 6 to 7 (mice) weeks old on the first day of the studies. Groups of five male and five female rats and mice were exposed to 0, 62.5, 125, 250, 500, or 1,000 mg bromodichloroacetic acid/L drinking water for 16 days. The exposure concentrations were based on previous studies of dichloroacetic acid,^3,16,68,96^ dibromoacetic acid,^18^ and bromochloroacetic acid.^19^ Because bromochloroacetic acid is more potent than dichloroacetic acid based on mass, concentrations of bromodichloroacetic acid equivalent to those used in bromochloroacetic acid studies based on mass were selected. Groups of five male and five female special study rats and mice were exposed to the same concentrations for 17 days. Feed and water were available ad libitum. Rats and female mice were housed five per cage, and male mice were housed individually. Clinical findings were recorded daily for core study rats and mice. Water consumption was recorded twice weekly by cage on a 3-day/4-day schedule. The core study animals were weighed initially, on days 8 and 15, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 2.

Table 2 Experimental Design and Materials and Methods in the Drinking Water Studies of Bromodichloroacetic Acid

Two-week Studies | Three-month Studies | Two-year Studies
Study Laboratory
Southern Research Institute (Birmingham, AL) | Southern Research Institute (Birmingham, AL) | Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/N rats B6C3F1/N mice | F344/N rats B6C3F1/N mice | F344/NTac rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 12 days Mice: 14 days | Rats: 13 (males) or 14 (females) days Mice: 11 (females) or 12 (males) days | Rats: 14 (males) or 15 (females) days Mice: 11 (females) or 12 (males) days
Age Range When Studies Began
Rats: 5 to 6 weeks Mice: 6 to 7 weeks | Rats: 6 to 7 weeks Mice: 5 to 6 weeks | Rats: 5 to 6 (males) or 6 (females) weeks Mice: 5 to 6 (females) or 6 (males) weeks
Date of First Exposure
Rats: August 21, 2000 Mice: August 23, 2000 | Rats: November 14 (males) or 15 (females), 2000 Mice: November 12 (females) or 13 (males), 2000 | Rats: October 26 (males) or 27 (females), 2006 Mice: September 25 (females) or 26 (males), 2006
Duration of Exposure
16 (core study) or 17 (special study) days | 4 (clinical pathology) or 14 (core study) weeks | Rats: 104 weeks Mice: 105 weeks
Date of Last Exposure
Rats: September 5 (core study) or 6 (special study), 2000 Mice: September 7 (core study) or 8 (special study), 2000 | Rats: February 14 (males) or 15 (females), 2001 Mice: February 12 (females) or 13 (males), 2001 | Rats: October 21 (males) or 23 (females), 2008 Mice: September 24 (females) or 25 (males), 2008
Necropsy Dates
Rats: September 5, 2000 Mice: September 7, 2000 | Rats: February 14 (males) or 15 (females), 2001 Mice: February 12 (females) or 13 (males), 2001 | Core study rats: October 20 through 21 (males) or 22 through 23 (females), 2008 Core study mice: September 22 through 24 (females) or 24 through 25 (males), 2008
Age Range at Necropsy
Rats: 8 weeks Mice: 8 to 9 weeks | Rats: 19 to 20 weeks Mice: 18 to 19 weeks | Rats: 109 to 110 weeks Mice: 109 to 111 (females) or 110 to 111 (males) weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females | 6-month interim evaluation: 8 males and 8 females 13- (rats) or 14- (mice) month interim evaluation: 7 (1,000 mg/L mice) or 8 males and 8 females Core study: 50 or 51 (1,000 mg/L mice) males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies | Same as 2-week studies
Animals per Cage
Rats: 5 Mice: 1 (males) or 5 (females) | Rats: 5 Mice: 1 (males) or 5 (females) | Rats: 1 to 3 (males) or 1 to 5 (females) Mice: 1 (male) or 5 (study females)
Method of Animal Identification
Tail tattoo | Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as 2-week studies | Same as 2-week studies
Water
Tap water (Birmingham, AL, municipal supply) via amber glass water bottles with plastic screw caps with Teflon^®^ liners (Wheaton, Millville, NJ) and stainless steel double-ball sipper tubes (Allentown Caging, Allentown, NJ), available ad libitum; sipper tubes changed twice weekly | Same as 2-week studies | Tap water (Columbus, OH, municipal supply) via glass bottles (Allentown Caging, Allentown, NJ; VWR, Westchester, PA; or Qorpak, Bridgeville, PA) with bottle caps lined with Teflon^®^-coated septa (Qorpak or Supelco, Bellefonte, PA) and with stainless steel double-ball bearing sipper tubes (Ancare Corp., Bellmore, NY), available ad libitum and changed twice weekly
Cages
Solid bottom polycarbonate cages (Lab Products, Inc., Maywood, NJ), changed once (male mice) or twice weekly | Same as 2-week studies | Polycarbonate cages (Lab Products, Inc., Seaford, DE), changed twice weekly and rotated in racks every 2 weeks
Bedding
Irradiated hardwood chip bedding (P.J. Murphy Forest Products, Inc., Montville, NJ), changed once (male mice) or twice weekly | Same as 2-week studies | Irradiated Sani-Chips hardwood chip bedding (P.J. Murphy Forest Products, Inc., Montville, NJ), changed twice weekly
Rack Filters
Disposable Reemay^®^ spun-bonded polyester filter (Andico, Birmingham, AL), changed every 2 weeks | Same as 2-week studies | Spun-bonded polyester filter sheets (Snow Filtration Co. (Cincinnati, OH), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Maywood, NJ), changed every 2 weeks | Same as 2-week studies | Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Exposure Concentrations
0, 62.5, 125, 250, 500, or 1,000 mg/L drinking water, available ad libitum | 0, 62.5, 125, 250, 500, or 1,000 mg/L drinking water, available ad libitum | 0, 250, 500, or 1,000 mg/L drinking water, available ad libitum
Type and Frequency of Observation
Observed twice daily; core study animals were weighed initially, on days 8 and 15, and at the end of the studies; and clinical findings were recorded daily. Special study animals were weighed initially and at the end of the studies. Water consumption was recorded twice weekly by cage, on a 3-day/4-day schedule. | Observed twice daily. Core study animals were weighed initially, weekly, and at the end of the studies; special study animals were weighed initially and at terminal sacrifice. Clinical findings and water consumption were recorded weekly for core study animals. | Observed twice daily; animals were weighed initially; and animals were weighed and clinical findings were recorded every four weeks thereafter, beginning at week 5, and at the end of the studies. Water consumption was recorded one week per month beginning week 4.
Method of Kill
Carbon dioxide asphyxiation | Same as 2-week studies | Same as 2-week studies
Necropsy
Necropsies were performed on all core study animals; and the heart, right kidney, liver, lung, right testis, and thymus were weighed. | Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all animals. Organs weighed for 6-month interim evaluation rats and mice were kidneys (both left and right) and liver.
Clinical Pathology
None | Blood was collected from the retroorbital plexus of clinical pathology rats on days 3 and 21 and from retroorbital plexus of core study rats and the retroorbital sinus in mice at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit, hemoglobin concentration; erythrocyte, reticulocyte, platelet, and nucleated erythrocyte counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids
Histopathology
In addition to gross lesions and tissue masses, the following tissues were examined in controls, to a no-effect level in rats, and in 1,000 mg/L mice: colon, small intestine (duodenum, jejunum, ileum), kidney, liver, and stomach (forestomach and glandular). | Complete histopathology was performed on 0 and 1,000 mg/L core study animals. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, spleen, stomach (forestomach and glandular), testis (with epididymis and vaginal tunics), thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on all core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular, and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis and vaginal tunics, thymus, thyroid gland, tongue (rats), trachea, urinary bladder, and uterus. For the 6-month interim evaluation, the large intestine (rats only) and liver were examined. For the 13-month (rats) or 14-month (mice) interim evaluation, the large intestine (rats only), small intestine (rats only), testes (rats only), and liver (mice only) were examined.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, spermatid and sperm samples were collected from male animals in the 0, 250, 500, and 1,000 mg/L groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from females exposed to 0, 250, 500, or 1,000 mg/L. | None
Acetyl-CoA Hydrolase Activity
The livers of all special study animals were weighed, and acetyl-CoA hydrolase activity was measured. | None | None
Molecular Pathology Studies
Targeted qPCR Arrays on Rat Mammary Gland Adenocarcinoma
None | None | Four frozen mammary gland adenocarcinomas from female F344/NTac rats in the current study, five spontaneous mammary gland adenocarcinomas from unexposed F344/N rats from five other 2-year NTP studies, and laser capture microdissected mammary gland epithelium from five age- and sex-matched F344/N rats (obtained from the National Institute on Aging) were used for pathway specific breast cancer qPCR arrays.
Molecular Analysis of Mouse Hepatoblastoma and Hepatocellular Carcinoma
None | None | Frozen hepatoblastoma, associated hepatocellular carcinoma, and adjacent normal liver samples were obtained from B6C3F1/N mice using laser capture microdissection, and Affymetrix microarray analysis was performed to identify differentially expressed genes between sample groups. To study the comparative mutation profile in hepatoblastoma and associated hepatocellular carcinoma, H-ras codon 61 and exon 2 & 3 Ctnnb1 mutation spectra were analyzed in 30 formalin-fixed paraffin embedded hepatoblastoma and associated hepatocellular carcinoma tissues from mice.

Assays of the liver enzyme acetyl-CoA hydrolase were performed using the livers of special study animals at the end of the studies. The liver was perfused with buffer (pH 7.4) to stabilize the enzyme, removed, trimmed, rinsed in ice-cold saline, blotted dry, and weighed. Livers were stored frozen until homogenization, preparation of supernatants, and determination of acetyl-CoA hydrolase activity using the method of Nakanishi et al..^97^ Supernatant protein levels were determined using a modification of the Lowry et al.^98^ method and used to normalize enzyme activity.

Necropsies were performed on all core study rats and mice, and the heart, right kidney liver, lung, right testis, and thymus were weighed. Histopathology was performed on the colon, small intestine, kidney, liver, and stomach in all core study control and 1,000 mg/L rats and mice. These tissues were examined to a no-effect level in rats. Table 2 lists the tissues and organs examined.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to bromodichloroacetic acid and to determine the appropriate exposure concentrations to be used in the 2-year studies.

On receipt, the rats and mice were 4 to 5 weeks old. Animals were quarantined for 13 or 14 (rats) or 11 or 12 (mice) days and were 6 to 7 (rats) or 5 to 6 (mice) weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix M).

Groups of 10 male and 10 female rats and mice were exposed to 0, 62.5, 125, 250, 500, or 1,000 mg bromodichloroacetic acid/L drinking water for 14 weeks. In addition, groups of 10 male and 10 female clinical pathology study rats were exposed to the same concentrations for 4 weeks. Feed and water were available ad libitum. Rats and female mice were housed five per cage, and male mice were housed individually. Clinical findings were recorded weekly for core study rats and mice. Water consumption was recorded weekly by cage for all core study animals. The core study animals were weighed initially, weekly, and at the end of the studies; special study animals were weighed initially and at terminal sacrifice. Details of the study design and animal maintenance are summarized in Table 2.

Animals were anesthetized with a mixture of CO_2_/O_2_ prior to collection of blood samples. Blood was collected from the retroorbital plexus of clinical pathology rats on days 3 and 21 and from the retroorbital plexus of core study rats and the retroorbital sinus of mice at the end of the studies for hematology and clinical chemistry (rats only). Blood samples were collected into microcollection serum separator tubes, and serum was obtained by centrifugation for clinical chemistry. Blood was also collected into microcollection tubes containing potassium EDTA as the anticoagulant for hematology. Reagents (except those used for reticulocyte count) were obtained from Bayer, Inc. (Tustin, CA), R&D Systems (Minneapolis, MN), or Fisher Scientific, Inc. (Norcross, GA). Clinical chemistry parameters were measured using a Hitachi 911 chemistry analyzer (Boeringer Mannheim, Indianapolis, IN), and hematology parameters (except reticulocyte count) were measured using the Technicon H•1™ automated hematology analyzer (Bayer HealthCare LLC, Tarrytown, NY). Reticulocytes were counted using a Coulter Model XL flow cytometer (Coulter Corp., Miami, FL); the reagents were manufactured and supplied by Coulter Corp., Molecular Probes (Eugene, OR), or Aldrich Chemical Co. (Milwaukee, WI). Blood smears were prepared within approximately 2 hours of sample collection to evaluate platelet and erythrocyte morphologies by light microscopy. The parameters measured are listed in Table 2

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats and mice exposed to 0, 250, 500, and 1,000 mg /L. The parameters evaluated are listed in Table 2. For 12 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained with crystal violet. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals; and the heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were fixed in Davidson’s solution and testes in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin (H&E). Complete histopathology examinations were performed by the study laboratory pathologist on 0 and 1,000 mg/L core study rats and mice; tissues were examined to a no-effect level in the remaining exposure groups. Table 2 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^99^ and Boorman et al.^100^

## Two-year Studies

### Study Design

Groups of 66 male and 66 female rats and mice were exposed to 0, 250, 500, or 1,000 mg bromodichloroacetic acid/L drinking water ad libitum for up to 104 (rats) or 105 (mice) weeks. Seven or eight male and eight female rats and mice from each group were evaluated at 6 months, 13 months (rats), or 14 months (mice).

Rats were quarantined for 14 (males) or 15 (females) days and mice for 11 (females) or 12 (males) days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats and mice were 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix M).

Rats were housed one to three (males) or one to five (females) per cage and mice were housed individually (males) or one to five (females) per cage. Feed and water were available ad libitum. Water consumption was measured for a 7-day period every 4 weeks beginning week 4. Cages were changed twice weekly, and racks were rotated once every 2 weeks. Further details of animal maintenance are given in Table 2. Information on feed composition and contaminants is provided in Appendix L.

### Clinical Examinations and Pathology

All animals were observed twice daily. Body weights were recorded initially, and clinical findings and body weights were recorded every 4 weeks thereafter, beginning at week 5, and at the end of the studies.

At the 6-month interim evaluation, necropsies were performed on eight male and eight female rats and mice. Organ weights for kidney and liver were collected. The bladder; lungs; kidneys; spleen; a section of the left and median lobes of the liver; and a section of the proximal, medial, and distal colon were collected, fixed in 10 percent neutral buffered formalin, trimmed, and embedded in paraffin blocks. The remainder of the liver was frozen in liquid nitrogen and the remainder of the colon preserved in 10 percent neutral buffered formalin. Only the liver (rats and mice) and colon (rats only) were examined microscopically.

For the second interim evaluation, eight male and eight female rats (13 months) and seven male and eight female mice (14 months) were shipped live to Dr. Tony DeAngelo at the United States Environmental Protection Agency. One of the 14-month special study mice died prior to shipping, and the data from this mouse was included in the analysis of the 2-year study, resulting in 51 male mice used in the 2-year study. The colon and small intestines from all male and female rats were examined for potential neoplasms. Any neoplasms found were collected and processed to H&E slides and then evaluated microscopically. Additionally, the testes from all male rats were trimmed, processed, sectioned, and stained with H&E for microscopic evaluation. The slides of the rat testes (epididymis not present) were evaluated for possible hyperplasias and neoplasms, particularly of the mesothelium. Only the liver of mice was microscopically examined at this interim evaluation.

Following study termination at the end of the 2-year studies, complete necropsies and microscopic examinations were performed on all core study rats and mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes which were fixed in Davidson’s solution and testes in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with H&E for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 2. An extended evaluation of the male and female rat brains involved the examination of wet tissue for the presence of gross lesions of the brain and the histopathologic examination of an additional three sections of paraffin-embedded brain from the superficial, middle, and deep aspects of the original brain block, resulting in the examination of nine sections of brain not previously examined for most of the animals. In a few cases, the amount of tissue remaining in the block only provided for one or two additional sections.

At the end of the 2-year studies, microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent QA laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the liver of rats and mice; the bone marrow, brain, and spleen of rats; the epididymis, prostate gland, seminal vesicle, skin, stomach (forestomach and glandular), and testis of male rats; the mammary gland and pituitary gland of female rats; and the epididymis, Harderian gland, lung, and testis of male mice.

The QA report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^99^ and Boorman et al.^100^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^101^

### Molecular Pathology Studies

A collection of neoplasms for molecular biology analysis was triggered when a potential chemical-related response was noted in moribund animals or at terminal sacrifice. Tumors greater than 5 mm in diameter were sectioned in half; one half was flash frozen in liquid nitrogen, and the other half was placed in 10% neutral buffered formalin for histopathology examination. In this 2-year study, representative mammary gland neoplasm samples from F344/NTac rats and liver neoplasm samples from B6C3F1/N mice were collected in liquid nitrogen for molecular biology studies at study termination.

Targeted qPCR Arrays on Rat Mammary Gland Adenocarcinoma: Four frozen mammary gland adenocarcinomas from exposed female F344/NTac rats were evaluated in this study (Appendix N). No concurrent control normal mammary gland tissues or spontaneous mammary gland adenocarcinomas were collected in this study. However, normal mammary gland tissues from five age-matched female F344/N rats were obtained from the National Institute on Aging. The frozen spontaneous mammary gland adenocarcinomas were sourced from five age-matched F344/N vehicle controls from other NTP chronic studies. RNA was extracted from these laser capture microdissected (LCM) frozen samples. A rat-specific PCR array (PARN-131Z, SABiosciences, Frederick, MD) was used to identify differential expression of genes relevant for mammary gland tumorigenesis (84 genes represented).

Molecular Analysis of Mouse Hepatoblastoma and Hepatocellular Carcinoma: For the microarray studies, six each of frozen hepatoblastoma, hepatocellular carcinoma, and adjacent nontumor liver tissue samples were collected from the exposed mice (Appendix O). In addition, six age-matched normal liver samples from control mice were collected. RNA was extracted from the LCM frozen tissue samples, and microarray was performed using Affymetrix Mouse Genome 430 2.0 GeneChip^®^ arrays. Differentially expressed genes between sample groups were compared to examine the altered molecular pathways.

Mutation analysis was conducted on hotspot regions of the H-ras and Ctnnb1 (β-catenin) genes in the liver neoplasms resulting from chronic exposure to bromodichloroacetic acid. Each of the liver neoplasms selected for mutation analysis contained both the hepatoblastoma and the adjacent hepatocellular carcinoma. Representative hepatoblastoma and hepatocellular carcinoma samples were LCM from formalin fixed, paraffin embedded liver neoplasms (n = 30). DNA was extracted from the LCM samples and subjected to PCR amplification and sequencing using previously published methods.^102^

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^103^ and is presented in the form of graphs. Animals found dead of other than natural causes or missing were censored; animals dying from natural causes or possible treatment-related effects were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^104^ method for testing two groups for equality and Tarone’s^105^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-3, Table B-1, Table B-3, Table C-1, Table C-4, Table D-1, and Table D-4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^106-108^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^106^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^106^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1/N mice.^109^ Bailer and Portier^106^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^110^

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1−P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N). For neoplasms and nonneoplastic lesions detected at the interim evaluation, the Fisher exact test,^111^ a procedure based on the overall proportion of affected animals, was used.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^112^ and Williams.^113,114^ Hematology, clinical chemistry, acetyl-CoA hydrolase activity, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^115^ (as modified by Williams^116^) and Dunn.^117^ Jonckheere’s test^118^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^119^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the Fisher exact test.^111^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^120^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period.^121-123^ In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current mouse study. There are only two studies that used the F344/NTac rats in the historical control database, the current study and a cobalt metal study. The current study is a drinking water study in F344/NTac rats; the cobalt metal study was by inhalation. Therefore, only historical control incidences for all routes and all vehicles are presented for F344/NTac rats in this Technical Report.

## Quality Assurance Methods

The 2-week, 3-month, and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^124^ In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of bromodichloroacetic acid was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^125,126^ The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by the NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^127^ and the somatic mutation theory of cancer.^128,129^ However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^130^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^131,132^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test.^133,134^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^135^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.