# Introduction

Figure 1

Bromodichloroacetic Acid (CASRN 71133-14-7; Chemical Formula: C_2_HBrCl_2_O_2_; Molecular Weight: 207.84)

Synonyms: 2-Bromo-2,2-dichloroacetic acid; bromodichloroethanoic acid.

## Chemical and Physical Properties

Bromodichloroacetic acid is a crystalline compound with a melting point of 69° to 72°C.^22^ It is a moderately strong acid with an estimated pKa of 0.61.^23^ The pKa for dihaloacetic acids, including bromochloroacetic acid, dichloroacetic acid, and dibromoacetic acid, is approximately 1.3.^23,24^ Thus, under most conditions of exposure and in biological tissues, this chemical exists as the carboxylate anion. Bromodichloroacetic acid has an estimated water solubility of 4.9 × 10^3^ mg/L at 25°C and an estimated Henry’s Law constant of 7.9 × 10^−9^ atm-m^3^/mole at 25°C.^25^

## Formation, Occurrence, and Human Exposure

Bromodichloroacetic acid is a member of the haloacetic acid (HAA) family of chemicals. HAAs are formed when drinking water supplies containing natural organic matter (e.g., humic or fulvic acids) are disinfected with chlorine-containing oxidizing compounds such as chlorine gas, hypochlorous acid, and hypochlorite. If bromide is present in the source water, it may be oxidized to hypobromous acid-hypobromite ion, which can react with organic matter to form brominated organic compounds. The reaction of brominated and/or chlorinated oxidizing agents with natural organic matter produces mixed brominated and chlorinated compounds, including mono-, di-, and trichloroacetic acids; mono-, di-, and tribromoacetic acids; bromochloroacetic acid; bromodichloroacetic acid; and chlorodibromoacetic acid. The relative amount of brominated HAAs produced in chlorinated drinking water is a function of the bromide concentration in the source water and the initial bromine/chlorine ratio. Of the nine chlorinated and/or brominated HAAs, five (mono-, di-, and trichloroacetic acids and mono- and dibromoacetic acids) are regulated by the United States Environmental Protection Agency (USEPA) and four (bromochloro-, bromodichloro-, dibromochloro- and tribromoacetic acids) are unregulated.

HAAs are second to trihalomethanes as the most commonly detected class of disinfection by-products in surface drinking water supplies in the United States.^26^ The relative amounts of these two families of chemicals as well as other disinfection by-products produced in drinking water supplies are affected by the nature and concentration of the organic precursor materials, water temperature, pH, the type of disinfectant, the disinfectant dose, and contact time.^26,27^ For example, increasing the pH from 6 to 8 increases trihalomethane formation and decreases trihaloacetic acid formation, but has little effect on mono- and dihaloacetic acid levels.

Coagulation prior to chlorination removes much of the disinfection by-product precursors from source water and thereby reduces the amount of disinfection by-products formed during disinfection. Although possible reactions of HAAs in water are decarboxylation and nucleophilic substitution (hydrolysis), these processes are very slow in ambient water, and most decreases in concentrations of HAAs in drinking water distribution systems are likely due to biodegradation.^28^

Levels of HAAs in drinking water are regulated by the USEPA.^29^ Under the disinfection by-products rule, the sum of the concentrations of monochloroacetic acid, dichloroacetic acid, trichloroacetic acid, monobromoacetic acid, and dibromoacetic acid is limited to 60 µg/L (60 ppb). This level is believed to reduce risks from cancer as well as reproductive and developmental toxicity. However, bromodichloroacetic acid is not included in the five HAAs regulated by the USEPA under the current disinfection by-products rule. A nationwide study of disinfection by-product occurrence in diverse geographic regions of the United States was conducted between October 2000 and April 2002.^30^ In this study, 12 water treatment plants that had different source water quality and bromide levels and that employed the major disinfectants chlorine, chloramines, ozone, and chlorine dioxide were sampled quarterly. Concentrations of bromodichloroacetic acid in finished water samples and in the distribution systems ranged from less than 2 to 15 µg/L. Bromodichloroacetic acid’s portion of the total HAAs can range from 1% to 20%.^30^ The Environmental Working Group^31^ has developed a database of chemical analyses from 47,576 water suppliers, of which 938 have tested for bromodichloroacetic acid from 2004 to 2009. Similar to the study by Weinberg et al.,^30^ most facilities were below the detection limit of 2 µg/L; the highest yearly average level of bromodichloroacetic acid reported in drinking water from a single facility was 11.12 µg/L with a seasonal range of 7.22 to 16.85 µg/L.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

There are few studies on the fate of bromodichloroacetic acid in experimental animals, but much can be learned about the absorption, distribution, metabolism, and excretion of bromodichloroacetic acid from the data on other HAAs. Dihaloacetic acids are rapidly absorbed from the gastrointestinal tract of rats after oral exposure.^23,32^ In male F344 rats, bromodichloroacetic acid bioavailability was estimated at 96% following an oral exposure in an aqueous vehicle.^23^ Dihaloacetic acids exhibit low binding to rat plasma proteins. For example, in plasma obtained from dosed F344 rats, 93% of the measured bromochloroacetic acid was in the unbound fraction.^23^ In contrast, bromodichloroacetic acid exhibits higher binding to rat plasma proteins with approximately 49% unbound. Compared to dihaloacetic acids, where 1% to 3% of the dose is eliminated in the urine, trihaloacetic acids are readily excreted (30% to 58%) in the urine of rats following an oral exposure.^23^ In rats, dihaloacetic acids are minor metabolites of bromodichloroacetic acid or other trihaloacetic acids. Schultz et al.^23^ evaluated the toxicokinetics and oral bioavailability of a mixture of haloacetic acids, one of which was bromodichloroacetic acid. In this study, a mixture containing trichloroacetic acid, bromochloroacetic acid, bromodichloroacetic acid, and dibromoacetic acid was administered intravenously and by gavage to naïve rats. In the mixture, the half-life of trichloroacetic acid was approximately 8 hours, while bromodichloroacetic acid had a half-life of approximately 1.85 hours. Bromochloroacetic acid and dibromoacetic acid had half-lives of approximately 44 minutes when given intravenously. In a similar study, Saghir and Schultz^33^ examined the effects of glutathione depletion on the half-life of a mixture of haloacetic acids. Depletion of glutathione-s-transferase zeta decreased the half-life of bromodichloroacetic acid when given intravenously but had no effect when given by gavage. Oral bioavailability of bromodichloroacetic acid was approximately 80% to 95% in this mixture.

While there are no direct data on bioavailability of bromodichloroacetic acid in mice, following an exposure by oral gavage to bromodichloroacetic acid, over 90% of the radioactivity was recovered in the urine, carcass, and exhaled CO_2_, with only 10% of the chemical-derived radioactivity present in the feces.^34^ This study suggests that, following oral exposure, bromodichloroacetic acid is well absorbed in mice. In mice, 24 hours after an oral gavage exposure to [^14^C_1_]-bromodichloroacetic acid, approximately 10% of the radioactivity remains in the carcass, compared to approximately 30% of the radioactivity remaining in the carcass of mice treated with [^14^C_1,2_]- trichloroacetic acid or [^14^C_1,2_]-dichloroacetic acid. Approximately 40% to 50% of bromodichloroacetic acid is eliminated in the urine and 5% to 10% in the feces. A significant amount (25% to 30%) is eliminated as CO_2_ through respiration. Xu et al.^34^ proposed a metabolic scheme for bromodichloroacetic acid in mice (Figure 2). Approximately 30% of bromodichloroacetic acid is eliminated in the urine as oxalate. In contrast, less than 7% of dichloroacetic acid or trichloroacetic acid is eliminated as oxalate. These data suggest that bromodichloroacetic acid metabolism is different than that of di- or trichloroacetic acid and that little of the bromodichloroacetic acid is metabolized to dichloroacetic acid. Based on these metabolic differences, Xu and colleagues postulated that the toxicity of bromodichloroacetic acid may be different than that of trichloroacetic acid. The half-life of bromodichloroacetic acid in mice ranges from 1 to 2 hours and appears dose dependent with shorter half-lives at 5 mg/kg compared to 100 mg/kg.^35^

Figure 2

Proposed Scheme for the Biotransformation of Bromodichloroacetic Acid in Mice

Source: Xu et al., 1995.^34^

A comparison of the in vitro metabolism of bromodichloroacetic acid, chlorodibromoacetic acid, and tribromoacetic acid was conducted by Saghir et al.^36^ in mouse, rat, and human liver microsomes. In all three systems, intrinsic metabolic clearance was similar for tribromoacetic acid and chlorodibromoacetic acid, with the intrinsic clearance of bromodichloroacetic acid at about one half of that of the other haloacetic acids. The metabolism of bromodichloroacetic acid appeared to proceed by reductive debromination because the metabolic rates were greatest under nitrogen.

### Humans

There are no studies evaluating the absorption, distribution, metabolism, or elimination of bromodichloroacetic acid in humans. One study did evaluate the in vitro metabolism of chlorodibromoacetic acid using human microsomes and recombinant enzymes.^36^

## Toxicity

Very few data are available on the toxicity of bromodichloroacetic acid. There are no in vivo toxicity studies in which bromodichloroacetic acid is administered alone to experimental animals. Health effects data are available on other HAAs such as dichloroacetic acid, dibromoacetic acid, and bromochloroacetic acid. The results of toxicity studies on other HAAs may provide insight into the potential health effects of bromodichloroacetic acid. However, because of qualitative and quantitative differences in the metabolism of bromodichloroacetic acid compared to other HAAs, the toxic effects of mono- and dihalogenated acetic acids may be different than those produced by bromodichloroacetic acid.

### Experimental Animals

Studies comparing the effects of dichloroacetic acid in mouse liver with those of trichloroacetic acid indicate that these agents induce different spectra of hepatotoxicity. Both dichloroacetic acid and trichloroacetic acid increased the incidences of hyperplastic nodules and hepatocellular adenoma and carcinoma in male B6C3F1 mice following 52 weeks of exposure by drinking water.^4^ However, dichloroacetic acid caused hepatomegaly, cytomegaly, focal necrosis, and accumulation of glycogen in hepatocytes, while trichloroacetic acid caused marked accumulation of lipofuscin (indicator of lipid peroxidation), modest accumulation of glycogen, and no evidence of focal necrosis. Similar to dichloroacetic acid, bromochloroacetic acid and dibromoacetic acid caused glycogen accumulation in the liver of B6C3F1 mice.^37^ However, dibromoacetic acid, but not bromochloroacetic acid, produced transient increases (2 to 4 weeks) in liver cell replication rates and in peroxisomal acyl-CoA oxidase activity. Dibromoacetic acid and dichloroacetic acid also induced peroxisomal palmitoyl-CoA oxidase activity in primary rat hepatocyte cultures.^38^ Hepatocellular vacuolization was observed in F344/N rats (increased incidence) and B6C3F1 mice (increased severity) administered dibromoacetic acid in drinking water at concentrations ranging from 125 to 2,000 mg/L for 3 months.^18,39^ Similarly, bromochloroacetic acid produced hepatocellular vacuolization in female F344/N rats and male and female B6C3F1 mice following exposure in the drinking water for 3 months.^19^

The liver is clearly a target for haloacetic acids, but there are some differences in the hepatic effects of these chemicals. The hepatotoxic effects of dibromoacetic and dichloroacetic acid are thought to be mediated, in part, by PPARα activation. In contrast, there was no evidence of PPARα activation by bromochloroacetic acid. Two haloacetic acids, dibromo- and dichloroacetic acids, induce peripheral neurotoxicity in rats, but others in this class have not been evaluated.

Both dibromoacetic acid and dichloroacetic acid induce peripheral neurotoxicity. In adolescent male and female F344/NCR rats exposed to 0.2 to 1.5 g dibromoacetic acid/L drinking water for 6 months, a concentration-related neuromuscular toxicity occurred.^40^ Effects of exposure to dibromoacetic acid included decreased grip strength, mild gait abnormalities, and decreased sensorimotor responsiveness; neuropathologic findings included degeneration of spinal cord nerve fibers and spinal cord cellular vacuolization at the 0.6 and 1.5 g/L concentrations. Dichloroacetic acid exposure induced similar neuromuscular effects in F344/NCR rats.^41^

### Humans

No studies on the toxicity of bromodichloroacetic acid in humans were found in a review of the literature.

## Reproductive and Developmental Toxicity

### Experimental Animals

No in vivo studies examining the effects of bromodichloroacetic acid on reproductive and developmental toxicity are available. Inferences on the potential effects of bromodichloroacetic acid as a reproductive and developmental toxicant may be made from toxicity studies of the dihaloacetic acids. Spermatotoxicity in male rats has been identified as one of the most sensitive toxic endpoints following exposure to dihaloacetic acids. Initial studies evaluated the effects of dibromoacetic acid and dichloroacetic acid, while later studies also examined male reproductive toxicity of bromochloroacetic acid. Fewer studies have examined the effects of HAAs on the female reproductive system. In general, little has been observed in females, with the exception of dibromoacetic acid, which is reported to alter estrus cyclicity at exposures of 90 and 270 mg/kg per day by gavage.^42^

In male Sprague Dawley rats, exposure to bromochloroacetic acid for 14 days decreased epididymal sperm counts, decreased the number of motile sperm, increased the number of epididymal sperm with misshapen heads or tail defects, increased the number of atypical residual bodies in seminiferous tubules, and increased the number of Step 19 spermatids retained in Stages X and XI of the spermatogenic cycle.^43^ Dichloroacetic acid produces similar effects in Sprague Dawley rats^44^ as does dibromoacetic acid in Sprague Dawley rats^45-47^ and in F344/NTac rats and B6C3F1 mice.^18,39^ In spite of the changes in sperm quality caused by dibromoacetic acid at daily doses up to approximately 150 mg/kg, the germinal epithelium appeared intact, and there were no obvious changes in sperm production in exposed rats. At higher doses of dibromoacetic acid, germinal epithelial atrophy was induced in exposed rats.^39,47^

Juvenile and adult C57BL/6 male mice were exposed daily to 0, 8, 24, 72, or 216 mg/kg bromochloroacetic acid for 14 days and evaluated for reproductive performance in a 40-day continuous breeding assay.^48^ Juvenile mice, exposed from postnatal day 8 through postnatal day 21, were allowed to mature to 14 weeks of age and then entered into the 40-day mating study. No effects on reproductive parameters were observed in the juvenile study. Effects on fertility were observed only during the first 10 days of mating in mice exposed as adults. In the two highest adult exposure groups, the mean number of litters per male, the percentage of litters per female bred, and the total number of fetuses per male were reduced. In addition, histopathology evaluations of testes after the final dosing with bromochloroacetic acid revealed spermatids with abnormal head morphology and atypical residual bodies. Thus, diminished male fertility was attributed to disruption of spermatid differentiation by bromochloroacetic acid. Treatment with bromochloroacetic acid did not affect relative testis, epididymal, or seminal vesicle weights.

The fertility of cauda epididymal sperm evaluated by in utero insemination was reduced in male rats exposed to 8, 24, or 72 mg bromochloroacetic acid/kg body weight for 14 days.^43^ In male Sprague Dawley rats gavaged daily with up to 50 mg dibromoacetic acid/kg for up to 79 days, fertility was not altered; however, male fertility was compromised in rats treated for 15 days or longer with 250 mg/kg.^49^ The latter evaluation was made through natural breeding and after artificial insemination of female rats with sperm collected from exposed rats. In fertility assessments by intrauterine insemination, the ED_50_ for decreased fertility of cauda epididymal sperm collected from male Sprague Dawley rats receiving 2.7 mg/kg (15.6 µmol/kg) bromochloroacetic acid by gavage for 14 days was similar to the ED_50_ for dibromoacetic acid (3.5 mg/kg, 16.1 µmol/kg).^50^

In a short-term reproductive toxicity screen, male and female rats were exposed to 0, 60, 200, or 600 ppm (mg/L) bromochloroacetic acid in the drinking water during cohabitation and separated after mating.^51^ Treatment of dams continued until gestation day 20 when they were examined for fertility and pregnancy status. Treatment of males continued until 30 days after mating, at which time they were necropsied and examined for sperm counts, motility, and morphology; organ weights; and histopathologic changes in reproductive organs. In a concomitant developmental toxicity screen, pregnant rats were exposed to the same concentrations of bromochloroacetic acid in drinking water from gestation day 6 until onset of birth. Treatment-related findings included a significant decrease in total implants per litter and a significant decrease in the number of live fetuses per litter at 600 ppm (50 mg/kg per day). At 600 ppm, water consumption was decreased by 21% to 34% and the albumin/globulin ratios were increased, consistent with signs of dehydration. The 600 ppm concentration produced a consistent decrease in water consumption in both sexes, and the decreased water consumption may have affected reproductive function in females. From these data, bromochloroacetic acid is taste-aversive and a general toxicant in both sexes at 600 ppm and also a female reproductive toxicant at 600 ppm. Studies that observed an effect of bromochloroacetic acid on male reproductive organs^43,49,50^ used oral gavage doses equal to or higher than those used in the NTP drinking water study.^51^

Holtzman rats were administered dibromoacetic acid by gavage at doses ranging from 62.5 to 250 mg/kg per day during the first 8 days of pregnancy to determine if administration during early pregnancy would affect female reproduction.^52^ No effects were detected on the number of implantation sites, number of pups per litter, number of resorptions, or pup weights on day 20; however, serum levels of estradiol were elevated in dosed dams. In a follow-up study, gavage dosing of 90-day-old female Sprague Dawley rats with 10 to 270 mg dibromoacetic acid/kg for 14 days caused a dose-related alteration in estrous cyclicity, with a tendency toward longer periods of persistent estrus.^42^ In addition, in vitro exposure of preovulatory follicles to dibromoacetic acid (50 µg/mL for 24 hours) caused an elevation in estradiol release and suppression of progesterone secretion stimulated with human chorionic gonadotropin; thus, the disruption of estrous cyclicity by dibromoacetic acid was attributed to alteration of ovarian steroid production. Elevations in circulating estradiol in female rats exposed to dibromoacetic acid were attributed to suppression of estradiol catabolism because serum estradiol levels were elevated in ovariectomized rats implanted with estradiol-containing capsules and then treated with dibromoacetic acid.^53^

Daily exposure of female Dutch belted rabbits to approximately 1 to 50 mg dibromoacetic acid/kg body weight per day in drinking water beginning on gestation day 15 and continuing through 24 weeks did not produce any gross abnormalities of the reproductive tract or viscera but did reduce the number of primordial follicles in prepubertal and adult rabbits.^54^ This exposure covers the fetal and neonatal periods when the primordial follicle pool in rabbits is formed. Reduction in the population of primordial follicles could result in early reproductive senescence.

Exposure of Sprague Dawley rats to 4 to 800 ppm dibromoacetic acid in drinking water from gestation day 15 through adulthood induced delays in pubertal development (delayed preputial separation in males and delayed vaginal opening in females at 400 ppm) and decreases in the fertility of cauda epididymal sperm at 600 and 800 ppm.^55^ Altered steroidogenesis was suggested to be a contributor to the pubertal delays.

Dibromoacetic acid was administered to Sprague Dawley rats in drinking water at concentrations ranging from 125 to 1,000 ppm (mg/L) with exposures beginning 14 days before cohabitation and continuing through gestation and lactation.^56^ Exposure to dibromoacetic acid at concentrations of 250, 500, or 1,000 ppm reduced food and water consumption in the dams. The only reported reproductive and developmental effects were decreases in pup body weights at 250 ppm or greater, the severity of which was positively associated with the decreased food and water consumption in the dam.

In a two-generation reproductive toxicity study, Sprague Dawley rats were given dibromoacetic acid in drinking water at concentrations of 0, 250, 500, or 650 ppm.^57^ No effects on estrous cyclicity, mating, fertility, implantation sites, litter sizes, pup viability, or pup sex ratios were observed in the parental or F_1_ generation female rats. In parental and F_1_ generation male rats, increased incidences of delayed sperm production (retention of Step 19 spermatids in Stage IX and Stage X seminiferous tubules), atypical residual bodies in the testis, abnormal sperm shape, and epididymal abnormalities (atrophy, residual bodies, and hypospermia) were observed in the 250 or 650 ppm groups. Delays in preputial separation and vaginal opening were observed in 650 ppm groups of F_1_ generation rats. In contrast to the effect of dibromoacetic acid on follicular development in rabbits,^54^ no effect on ovarian follicular histology was observed in rats exposed to dibromoacetic acid. For this effect, the rabbit may be a more sensitive species.

Exposure of mouse whole embryo cultures to HAAs for up to 26 hours caused defects in neural tube closure, craniofacial abnormalities, prosencephalic and pharyngeal arch hypoplasia, deficient caudal growth, and eye and heart defects.^58,59^ Monohaloacetic acids tended to be more potent than dihaloacetic acids, which were more potent than trihaloacetic acids. Brominated acetic acids and mixed bromo/chloroacetic acids were more potent than their chlorinated analogs. In this model, bromodichloroacetic acid disrupted embryogenesis and altered morphogenesis.^60^

In order to study the potential toxic effects of whole disinfection by-product mixtures, the USEPA generated a concentrated chlorinated drinking water. The source water was obtained from East Fork Lake in Ohio, spiked with bromide and iodide, coagulated, chlorinated, and concentrated 136-fold.^61^ This water was used as the test article in a multigenerational rat bioassay.^62^ Endpoints evaluated were pup weight, prenatal loss, pregnancy rate, gestation length, puberty onset in males, growth, estrous cyclicity, hormone levels, immunologic, and neurodevelopmental parameters. Significant effects were observed for delayed puberty for F1 females, reduced caput epididymal sperm counts in F1 adult males, and increased incidences of thyroid gland follicular cell hypertrophy in adult females. While bromodichloroacetic acid was present, its role in the effects of this mixture, if any, is uncertain.

A number of haloacetic acids have been evaluated for potential reproductive toxicity in experimental animals. In general, the dihaloacetic acids are male reproductive toxicants in rats and mice. There are fewer studies on the potential for female reproductive toxicity of haloacetic acids and only dibromoacetic acid appears to have any effect on the female reproductive system.

### Humans

No studies have been reported on reproductive or developmental effects of bromodichloroacetic acid alone in humans. However, several studies have indicated an association between exposure to disinfection by-products and alterations in reproductive function or fetal development, including spontaneous abortions, stillbirths, low birth weights, and birth defects.^63^ Although associations between stillbirth risk and exposure to disinfection by-products have been demonstrated, no association was observed with HAAs after controlling for exposures to trihalomethanes.^64,65^ Associations between exposure to the five dihaloacetic acids regulated by the USEPA and impaired fetal growth have been reported,^66^ but these studies did not include bromodichloroacetic acid.

## Carcinogenicity

### Experimental Animals

No studies have been reported on the carcinogenicity of bromodichloroacetic acid in animals. However, several studies have shown that dichloroacetic acid administered in drinking water is carcinogenic to the liver of rats and mice. Hepatocellular adenomas and carcinomas were induced in male and female B6C3F1 mice exposed to up to 5 g dichloroacetic acid/L drinking water for at least 61 weeks^67^ and up to 104 weeks.^68,69^ When length of exposure was increased, a lower concentration of dichloroacetic acid was required to induce the hepatocarcinogenic response in mice; the liver tumor response was significantly increased at 0.5 g/L or greater after 104 weeks of exposure.^68^

Dichloroacetic acid is also carcinogenic to the liver of rats. Male F344/N rats were exposed to 0, 0.05, 0.5, or 1.6 g dichloroacetic acid/L drinking water for 100 weeks^3^. Mean daily doses of dichloroacetic acid were 3.6, 40, and 139 mg/kg body weight for the three exposed groups. The incidences of hepatocellular adenoma or carcinoma combined in rats that survived more than 78 weeks were 3% (1/33) in controls and 0% (0/26), 24.1% (7/29), and 28.6% (8/28) in the respective exposed groups. The liver tumor response was not associated with peroxisome proliferation, hepatocellular necrosis, or sustained hepatocyte proliferation.

Dibromoacetic acid was administered for 2 years to male and female F344/N rats and B6C3F1 mice in drinking water at concentrations of 0, 50, 500, or 1,000 mg/L.^18,39^ Incidences of exposure-related neoplasms were increased at multiple sites; these included mononuclear cell leukemia and abdominal cavity mesothelioma in rats, and liver and lung neoplasms in mice. The increased incidences of hepatocellular neoplasms in male mice were significant even in the 50 mg/L group, an exposure equivalent to an average daily dose of approximately 4 mg/kg.

Bromochloroacetic acid is also carcinogenic in rats and mice. Groups of 50 male and 50 female F344/N and B6C3F1 mice were exposed to drinking water containing 250, 500, or 1,000 mg/L for 2 years.^19^ Exposed male rats had increased rates of malignant mesothelioma. Adenomas of the large intestine were observed in both male and female rats administered the highest concentration of bromochloroacetic acid. Exposed female rats also had increased incidences of multiple fibroadenoma of the mammary gland. Slightly increased incidences of hepatocellular adenoma in exposed male and female rats and pancreatic islet adenoma in exposed male rats were also observed. Male and female mice administered bromochloroacetic acid had increased incidences of hepatocellular adenoma and carcinoma. Male mice also had an exposure concentration-dependent increase in the incidences of hepatoblastoma.

The results of carcinogenicity studies of trichloroacetic acid are not as consistent as those of the dihaloacetic acids. DeAngelo et al.^5^ did not observe increases in the incidences of liver tumors in male F344 rats exposed to up to 5 g/L trichloroacetic acid in drinking water for 104 weeks. In contrast, increased incidences of liver tumors (adenomas and carcinomas) have been observed in male and female B6C3F1 mice following chronic exposure to trichloroacetic acid in the drinking water at concentrations up to 2 g/L.^4,70^ It is possible that these differences represent species specific responses to trichloroacetic acid.

Mechanistic studies examining the potential modes of action of HAAs have focused on the liver. The roles of PPAR-α activation, DNA damage, oxidative stress and cytotoxicity, and regenerative proliferation in liver carcinogenicity of HAAs have been examined in several studies. Single gavage administration of HAAs induced lipid peroxidation and formation of 8-hydroxydeoxyguanosine adducts in nuclear DNA in the liver of male B6C3F1 mice; the relative potencies for these effects were dibromoacetic acid ≈ bromochloroacetic acid > dichloroacetic acid > trichloroacetic acid.^71^ These results suggest that DNA damage from oxidative stress induced by these agents may contribute to the hepatocarcinogenic process. In male B6C3F1 mice exposed to 2.0 g dichloroacetic acid/L drinking water, hepatocyte division rates were increased after 14 days of exposure; after 28 or 280 days of exposure, hepatocyte division rates were reduced in livers of dichloroacetic acid-treated mice compared to controls.^72^ Altered hepatic foci and liver tumors in dichloroacetic acid-treated mice showed higher immunoreactivity to the oncoproteins c-Jun and c-Fos and higher rates of cell division than the surrounding nonlesioned liver tissue. Increased cell replication rates in hepatic foci and tumors and decreased rates in normal hepatocytes of mice exposed to dichloroacetic acid provide a selective growth advantage to initiated cells. In a follow-up study, incubation of primary hepatocyte cultures from untreated male B6C3F1 mice with 0.5 to 2.0 mM dichloroacetic acid enhanced the formation of anchorage-independent colonies in soft agar.^73^ A fourfold increase in colony formation was measured when hepatocytes were obtained from mice pretreated with 0.5 g dichloroacetic acid/L drinking water for 2 weeks. Although dichloroacetic acid did not induce c-Jun expression in hepatocyte monolayers, the colonies promoted by dichloroacetic acid were immunoreactive with c-Jun antibody. These results suggest that dichloroacetic acid was selective for c-Jun^+^ subpopulations.

Gavage administration of 500 mg dichloroacetic acid/kg body weight to female B6C3F1 mice for 5 days caused decreased DNA methylation and increased mRNA expression of the c-myc proto-oncogene.^74^ Administration of 3.2 g dichloroacetic acid/L drinking water for 36 weeks increased the incidences and multiplicities of liver tumors but not kidney tumors in N-methyl-N-nitrosourea-initiated mice. Thus, hypomethylation of c-myc and increased expression of this gene may be involved in the promotion of liver tumors by dichloroacetic acid. Exposure of female B6C3F1 mice and male F344/N rats to 1,000 or 2,000 mg dibromoacetic acid/L drinking water for 28 days caused a decrease in the 5-methylcytosine content of DNA and increased mRNA expression of the c-myc and insulin-like growth factor II genes.^75^ Dibromoacetic acid and dichloroacetic acid also caused hypomethylation of DNA in kidneys of male B6C3F1 mice and male F344 rats exposed to these agents via the drinking water.^76^ Treatment with dibromoacetic acid also caused glycogen accumulation and peroxisome proliferation in the mouse and rat liver. Thus, dibromoacetic acid and dichloroacetic acid appear to induce similar biochemical and molecular effects.

The mutational spectrum at codon 61 of the H-ras gene was different in liver tumors obtained from male B6C3F1 mice exposed to 500 mg dichloroacetic acid/L drinking water for 76 weeks compared to liver tumors from control mice.^77^ The frequency of liver tumors with H-ras codon 61 dichloroacetic acid-treated mice had increased CAA → CTA and decreased CAA → AAA mutations. Hence, base-substitution mutations may be involved in the hepatocarcinogenicity of dichloroacetic acid.

The di- and trihaloacetic acids that have been tested are carcinogenic in rodents. Target tissues are liver in mice, mesothelium in male rats, and mammary gland in female rats. Other tumors in rats, such as hepatocellular adenomas and pancreatic islet cell adenomas, have been observed, but not consistently, across chemicals.

### Humans

No studies have been reported on the carcinogenicity of bromodichloroacetic acid in humans. However, several studies have examined cancer risks associated with exposure to disinfection by-products. A meta-analysis of epidemiology studies published before 1989 on cancer and chlorination by-products in drinking water yielded a relative risk estimate of 1.21 [95% confidence interval (CI): 1.09 to 1.34] for bladder cancer and 1.38 (95% CI: 1.01 to 1.87) for rectal cancer.^78^ A population-based case-control study in Colorado also found an association between prolonged exposures to chlorinated surface water and increased bladder cancer risk in men and women for both smokers and nonsmokers.^79^ An elevation in brain cancer risk was also associated with exposure to chlorinated surface water.^80^

A more recent meta-analysis of studies on chlorinated drinking water reported long-term drinking of chlorinated water was associated with an increased risk of bladder cancer.^81^ This study was followed up by a posterior pooled analysis of six case-control studies of bladder cancer that confirmed an increased risk of bladder cancer associated with exposure to disinfection by-products.^82^ In addition to drinking chlorinated water, exposure to disinfection by-products also occurs from activities such as bathing, showering, and swimming pool attendance.^83^ In the Spanish bladder cancer study, exposure to disinfection by-products from ingestion or dermal contact resulted in an increased risk of bladder cancer, particularly for the dermal route.^83^ One of the challenges to interpreting these studies is the difficulty in attributing the risk to individual chemicals. Disinfection by-products consist of a variety of chemical classes for which one or more representatives have been shown to induce cancer in rodents.^1^

## Genetic Toxicity

There is very little information about the genotoxicity of bromodichloroacetic acid or mixed trihaloacetic acids in general. Only one study was found in the literature that reported on the genotoxicity of bromodichloroacetic acid. In this class study, twelve haloacetic acids were tested for induction of DNA damage using the comet assay in Chinese hamster ovary cells.^84^ Bromodichloroacetic acid gave negative results at concentrations up to 30 mM, whereas chlorodibromoacetic acid gave positive results at a concentration of 14 mM. However, chlorodibromoacetic acid was the least potent compound among the nine haloacetic acids that were positive in the comet assay and potencies ranged by 1,000-fold.

The genotoxicity of dichloroacetic acid is of interest as dichloroacetic acid is one of the metabolic products of bromodichloroacetic acid in mice,^34^ and dichloroacetic acid is carcinogenic in mice.^4,67,68^ Dichloroacetic acid has been tested in bacterial mutagenicity assays, in vitro mammalian cell assays, and in vivo mutagenesis and micronucleus assays. Dichloroacetic acid was positive in Salmonella typhimurium strains TA100, TA98, and RSJ100 (a derivative of TA1535 that expresses the Phase II metabolic enzyme, GST1-1, from rat) in the absence of metabolic activation,^85-87^ whether the exposure was by vapor or in solution. Mixed results were obtained in the presence of rat liver S9 microsomal fraction (S9 mix). Dichloroacetic acid shifted the mutational spectrum in TA100 by increasing G:C to A:T transitions.^85^ One study found that dichloroacetic acid induced the Escherichia coli PQ37 SOS repair system at a concentration of 500 µL/mL, but the effect did not occur in the presence of S9 mix.^86^ Conversely, in a prophage induction assay, dichloroacetic acid was a weak positive at a concentration of 2 mg/mL only in the presence of S9 mix.^85^

With regard to in vitro mammalian cell assays, dichloroacetic acid has been tested in the comet assay and the mouse lymphoma assay. Dichloroacetic acid did not induce DNA damage, measured by the comet assay, in Chinese hamster ovary cells^88^ or in freshly isolated rat or mouse hepatocytes exposed to the chemical for 4 hours at concentrations as high as 10 mM.^89^ However, in the same study, dichloroacetic acid induced DNA damage in a human lymphoblastoid cell line (CCRF-CEM) at a concentration of 1 mM. Dichloroacetic acid was positive in the mouse lymphoma L5178Y/tk^+/−^ assay in the absence of S9 mix at a concentration of 300 µg/mL.^90^

Dichloroacetic acid has been tested for genotoxic effects in vivo using the comet assay and the micronucleus assay, and in transgenic mice carrying lambda shuttle vectors for mutational analyses. With regard to the comet assay, Chang et al.^89^ obtained negative results in B6C3F1 mice and Fischer 344 rats given single doses of dichloroacetic acid (10 mM/kg) by gavage or multiple exposures in drinking water (up to 5 g/L for mice and up to 2 g/L for rats). The tissues that were assessed for damage after single doses included stomach, duodenum, liver, and spleen. Only liver was assessed after multiple exposures to dichloroacetic acid.^89^ Fuscoe et al.^91^ also observed no increase in DNA damage, measured by the comet assay, in blood leukocytes of B6C3F1 mice exposed to dichloroacetic acid in drinking water for 28 days at concentrations up to 3.5 g/L. However, Nelson and Bull^92^ obtained positive results in the comet assay in liver samples from B6C3F1 mice and Sprague Dawley rats exposed to a single dose of dichloroacetic acid (10 mmol/kg) by gavage. Parrish et al.^93^ examined whether dichloroacetic acid increased oxidative damage to DNA. Levels of 8-oxo-2′-deoxyguanosine were not increased in DNA from the livers of B6C3F1 mice exposed to dichloroacetic acid in drinking water for 3 or 10 weeks (doses of 3 g/L or 2 g/L, respectively). With regard to the micronucleus assay, micronucleated polychromatic erythrocytes (MN-PCE) in peripheral blood were increased in B6C3F1 mice exposed to dichloroacetic acid for 9 days in drinking water at a concentration of 3.5 g/L.^91^ Furthermore, the same study showed increases in micronucleated normochromatic erythrocytes (MN-NCE) after 10, 26, or 31 weeks of exposure to 3.5 g/L dichloroacetic acid. However, in studies conducted by the NTP using p53^+/−^ mice or Tg.AC mice (mice carrying one copy of a mutant v-Ha-Ras oncogene), no increases in micronucleated erythrocytes were detected in peripheral blood after 3 months of exposure to dichloroacetic acid (highest concentration of 2 g/L).^16^ Lastly, although dichloroacetic acid did not increase the frequency of mutations at the transgenic lacI locus in Big Blue^®^ B6C3F1 mice (liver) after 4 or 10 weeks of exposure through drinking water, the mutant frequency was 2.3-fold greater than the control after 60 weeks of exposure at a concentration of 3.5 g/L.^94^ Also, the mutation spectrum shifted, with increased mutagenesis at T:A base pairs compared to controls.

The mixed dihaloacetic acid, bromochloroacetic acid was positive in S. typhimurium strain TA100, in tests conducted with and without exogenous metabolic activation enzymes (S9); no mutagenicity was detected in strain TA98 or in E. coli WP2 uvrA/pKM101, with or without S9. No significant increases in the frequencies of micronucleated erythrocytes were observed in blood samples of male or female mice exposed to bromochloroacetic acid for 3 months in drinking water, indicating no induction of chromosomal damage in proerythrocytes under these conditions in mice.^19^

Taken together, although there is little published information on the genotoxicity of bromodichloroacetic acid, one of its metabolites, dichloroacetic acid, is consistently positive in bacterial mutagenicity assays in the absence of metabolic activation, gives mixed results in DNA damage (comet) assays, and shows signs of in vivo mutagenicity and effects on chromosomal stability in rodents after long-term exposures at high doses.

## Study Rationale

Bromodichloroacetic acid was nominated to the NTP by the American Water Works Association Research Foundation and the USEPA for toxicity and carcinogenicity studies in rats and mice because of widespread human exposure to this water disinfection by-product and because related dihaloacetic acids were found to be carcinogenic in rats and mice. In addition, this study is part of a series of NTP studies to provide data on di- and trihaloacetic acids and to compare the toxicity and carcinogenicity of chlorinated, brominated, and mixed chloro/bromo acetic acids. Drinking water was selected as the route of exposure to mimic human exposure to this chemical.