# Appendix P Summary of Peer Review Panel Comments

On May 22, 2014, the draft Technical Report on the toxicology and carbcinogenesis studies of bromodichloroacetic acid received public review by the National Toxicology Program’s Technical Report Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. M.J. DeVito, NIEHS, introduced the toxicology and carcinogenesis studies of bromodichloroacetic acid by describing its occurrence as a water disinfection by-product and the resulting widespread human exposure through drinking water, the structural similarity of bromodichloroacetic acid to other haloacetic acids that are carcinogenic in rodents, and a lack of toxicity and carcinogenicity data. The proposed conclusions were clear evidence of carcinogenic activity of bromodichloroacetic acid in male and female F344/NTac rats and in male and female B6C3F1/N mice. Genetic toxicity studies found that bromodichloroacetic acid was mutagenic in Salmonella typhimurium and Escherichia coli WP2 uvrA/pkM101.

Dr. Carpenter said there were no written or oral public comments concerning this report.

Dr. Conner, the first primary reviewer, agreed in general that there was clear evidence of carcinogenicity of bromodichloroacetic acid in the two species. He questioned the calls of carcinogenicity on certain tumor types in his written comments, but he did not want to change the overall conclusions. He asked if the low survival in the female rats in the high dose group had an impact on some of the assessments. He questioned whether the low survival in some groups could impede the interpretation of the study. For numerous places in the report, he questioned claims that biological differences were found that did not reach statistical significance. He also questioned comparisons of bromodichloroacetic acid to other compounds in the chemical class, particularly a discussion about the reproductive effects of halogenated acetic acids and related compounds. He recommended adding a table comparing and contrasting the effects of the various related compounds in each type of assay, because the discussion in the report was lengthy and hard to follow. He disagreed with the conclusion regarding intestinal adenomas in male rats, recommending the call be changed from equivocal evidence to no evidence, because of a lack of statistical significance in the data.

Dr. DeVito noted he could put the incidence numbers of the tumors in the report when there were mentions of biological difference that did not reach statistical significance, and he could indicate the differences were not significant. He noted the challenge in this study of the low-incidence tumors, and confirmed they had been classified as equivocal evidence, which means they may or may not have been related to the exposure. Dr. J.R. Bucher, NIEHS, addressed the issue of study length and survival. He said the survival-adjusted statistics used by NTP are designed to account for when survival is different among dose groups; a weighted statistical assessment is used. Dr. G.E. Kissling, NIEHS, said the statistics are survival adjusted, helping to equalize the risk period across dose groups. Dr. Conner asked whether that approach still worked well in extremes of survival. Dr. Kissling said that depends on when the survival starts falling off.

Dr. Mahrt, the second primary reviewer, agreed with most of the conclusions, but noted some of the conclusions labeled some evidence could easily be called equivocal.

Dr. Fanucchi, the third primary reviewer, asked for the addition of a table to Appendix J to compare the characterization of the different lots of bromodichloroacetic acid for the multiple studies. Dr. DeVito said he could add the table.

Dr. Carpenter asked for a motion upon consideration of the proposed conclusions.

Dr. Mahrt moved to change the some evidence conclusion in male rats on gliomas (brain) and squamous cell papillomas (oral cavity) to equivocal evidence. Dr. Conner seconded.

For the extended evaluation conducted for brain tumors, Dr. Regan asked whether the historical controls had the same evaluation. Dr. Kissling said the historical controls were based only on the original sections.

Dr. R.C. Sills, NIEHS, said it is important to remember that brain tumors are rare in rodents, and the gliomas seen in NTP studies are similar to human brain tumors. He noted the adult rat is generally insensitive to neurocarcinogens, resulting in a low incidence of tumors. He supported the some evidence conclusion.

The vote was taken on the motion, which was restricted to the conclusions on male rats. The vote was unanimous in favor of the motion.

Dr. Conner moved that the conclusion regarding increased incidences of gliomas in female rats be downgraded from some evidence to equivocal evidence. Dr. Mirsalis seconded the motion. The vote was unanimous in favor of the motion.

Dr. Mirsalis moved that the conclusions regarding the male and female mice be accepted as written. Dr. Conner seconded. The vote was unanimous in favor of the motion.