# Appendix N Involvement of Tgfβ Signaling in Mammary Gland Adenocarcinomas in F344/NTAC Rats Exposed to Bromodichloroacetic Acid in Drinking Water for Two Years

## N.1 Introduction

While mammary gland fibroadenomas are one of the most common background neoplasms in female F344/N rats, occurring at an incidence of about 51% in the National Toxicology Program (NTP) historical control database (all routes, all vehicles), adenocarcinomas of the mammary gland are fairly uncommon, occurring at an incidence of less than 4% in NTP studies. The concurrent NTP 2-year bioassay indicated significantly increased incidences of mammary gland proliferative lesions, including hyperplasia, fibroadenoma, and adenocarcinoma in female F344/NTac rats exposed to bromodichloroacetic acid in drinking water. The NTP has identified 51 chemicals that have been associated with the induction of mammary gland neoplasms in rodents, with 24 of these exhibiting clear evidence of carcinogenicity in either the F344/N rat or B6C3F1 mouse,^142^ including another drinking water disinfection by-product, bromochloroacetic acid, which showed clear evidence of mammary gland carcinogenesis in male and female B6C3F1 mice and F344/N rats.^19^ The molecular mechanisms underlying the pathogenesis of these lesions are poorly understood, and the effects of bromodichloroacetic acid exposure on the mammary gland in the context of tumorigenesis have not been explored. In addition, separation of background spontaneous tumors from treatment-related tumors can be difficult, particularly when a tumor response to chemical exposure is not robust. Thus, the identification of target pathways that inform on mechanisms of tumorigenesis as well as differentiate between spontaneous and chemically induced tumors is of critical importance. In the current study, real-time quantitative polymerase chain reaction (qPCR) arrays targeting pathways relevant for mammary gland tumorigenesis were employed to investigate differential gene expression between mammary gland adenocarcinomas arising in bromodichloroacetic acid-exposed animals compared to those occurring in vehicle and naïve controls.

## N.2 Materials and Methods

### N.2.1 Animals and Tumor Sampling

Four frozen mammary gland adenocarcinomas from female F344/NTac rats exposed to bromodichloroacetic acid were available for analysis from the concurrent 2-year drinking water study of bromodichloroacetic acid (Table N-1). Collection of tumors for molecular biology analysis occurred during the in-life phase of the 2-year study and was triggered when a potential chemical-related response was noted in moribund animals or at terminal kill. Tumors of sufficient size were sectioned in half; one half was flash frozen in liquid nitrogen, and the other half was placed in 10% neutral buffered formalin for histopathology examination. Low numbers of frozen tumors relative to histologically diagnosed adenocarcinomas from bromodichloroacetic acid exposed animals and the lack of frozen tumors from the concurrent vehicle treated animals may be due to small size (less than 0.5 cm) of tumors or the lack of an apparent chemical-related effect until scheduled terminal kill of the exposed groups. Because the primary components of mammary gland adenocarcinomas are epithelial, to obtain appropriate age-matched naïve control samples, mammary gland epithelium was laser-capture microdissected from frozen mammary gland samples (embedded in optimal cutting temperature medium) from five age-matched female F344/N rats obtained from the National Institute on Aging. Because frozen spontaneous adenocarcinomas were not available from vehicle control animals from the concurrent 2-year study of bromodichloroacetic acid, five spontaneous tumors were obtained from age-matched vehicle control female rats from four other 2-year NTP studies available in the NTP frozen tissue repository. Two mammary gland tumors from female F344/N rats were obtained from the vehicle controls from the 2,2-bis(bromomethyl)-1,3-propanediol feed study.^143^ One mammary gland tumor from one female F344/N rat was obtained from the vehicle controls from the inhalation study of nickel sulfate hexahydrate,^144^ and one from the vehicle controls from the D&C Yellow No. #11 feed study.^145^ One mammary gland tumor from one female Sprague Dawley rat was obtained from the vehicle control group from the 3,3′,4,4′-tetrachloroazobenzene gavage study.^146^ For the purposes of this report, these are described as vehicle control tumors (Table N-1).

### N.2.2 Real Time qPCR Arrays and Data Analysis

RNA was extracted from five laser-captured samples of mammary gland epithelium from vehicle control, age-matched female mammary glands, five spontaneous adenocarcinomas from vehicle control females, and four adenocarcinomas from bromodichloroacetic acid-exposed females using the TRIzol^®^ kit (Invitrogen Corporation, Carlsbad, CA). Fold changes in gene expression were determined by cDNA quantification of spontaneous and bromodichloroacetic acid-exposed adenocarcinoma relative to vehicle control mammary gland epithelium from age-matched naïve control rats. The 18s RNA gene was used for the endogenous control for normalization of RNA levels.

A rat-specific PCR array (PARN-131Z, SABiosciences, Frederick, MD) was used to identify differential expression of genes relevant for mammary gland tumorigenesis (84 genes represented) between mammary gland adenocarcinomas in vehicle control and bromodichloroacetic acid-exposed animals. Quantitative differential gene expression changes were identified using arrays containing corresponding PCR primers and SABiosciences’ SYBR^®^ Green qPCR master mix, and the reactions were run on an ABI PRISM^®^ 7900HT Sequence Detection System (Applied BioSystems, Inc., Foster City, CA) using the manufacturer’s protocols. Gene expression was normalized to beta-actin (Actb), and fold changes were calculated using the ΔΔCt method.^147^ To identify significant gene expression changes between spontaneous and bromodichloroacetic acid-exposed adenocarcinomas, pairwise comparisons were performed using a residual bootstrap-based methodology^148^ to compute p values using 10,000 bootstrap samples and controlling the false discovery rate at 5%. Pairwise comparisons were performed using ORIOGEN, version 4.01.^149-151^ These statistical methods have been reviewed and approved by the NTP Board of Scientific Counselors during the 2012 Biostatistics Branch Board Review.

## N.3 Results

The Tgfβ pathway and its downstream mediators are overrepresented in mammary gland adenocarcinomas from bromodichloroacetic acid-exposed female F344/NTac rats. Using a pairwise comparison analysis to identify differential gene expression between mammary gland adenocarcinomas from vehicle control and bromodichloroacetic acid-exposed female F344/NTac rats, of the 84 genes present on the PCR array relevant to mammary gland carcinogenesis, eight were identified as significantly (P < 0.05) upregulated in mammary gland adenocarcinomas from rats exposed to bromodichloroacetic acid compared to spontaneous adenocarcinomas in vehicle control rats (Table N-1). These genes included Mmp9, Mmp2, inhibitor of differentiation (Id1), Hic1, Adam23, vascular endothelial growth factor a (Vegfa), thrombospondin 1 (Thbs1), and Cdh13. Five of these eight genes are associated with Tgfβ pathway signaling, including its effects on matrix remodeling, mammary gland cancer progression, tumor invasion, and metastasis (Mmp9, Mmp2, Id1, Vegfa, and Thbs1) (Table N-2).

## N.4 Discussion

The Tgfβ gene and downstream signaling pathway is known to play a significant role in a variety of biologic processes, including cell differentiation, inflammation, autoimmunity, and carcinogenesis in a variety of tissues.^152^ The differential expression of this gene has been associated with tumor suppression early in the course of mammary gland carcinogenesis, while late in the course of disease it is known to promote invasion and metastasis.^153,154^ Not only is it overexpressed in mammary gland carcinogenesis, it is also associated with increased angiogenesis, epithelial-mesenchymal transition, and increased tumor cell invasion and proliferation, tumor progression, and evasion of apoptosis.^155,156^

Tgfβ regulates the expression of a large number of downstream mediators, including growth and differentiation factors, apoptosis mediators, cytokines, and matrix metalloproteinases. Two matrix metalloproteinases found significantly upregulated in adenocarcinomas from rats exposed to bromodichloroacetic acid (compared to spontaneous adenocarcinomas) included Mmp2 and Mmp9. The expression of these metalloproteinases is regulated by upstream expression of Tgfβ^157^, and they function to degrade extracellular matrix components such as type IV collagen, the primary collagen in the basement membrane.^158^ Conversely, these mediators also activate various growth factors, cleave adhesion molecules, and act to activate Tgfβ^159^. Overexpression of Mmp2 and Mmp9 is also associated with mammary gland cancer cell growth, migration, and invasion.^160^

Id1, another gene regulated by Tgfβ^161^, was also shown to be significantly upregulated in mammary gland adenocarcinomas from rats exposed to bromodichloroacetic acid. Overexpression of this gene in mammary gland cancer is associated with an invasive phenotype including the process of epithelial-to-mesenchymal transition.^162^ Thbs1 is a member of a group of mediators that act to modulate cell differentiation and matrix structure during tissue development and remodeling; it has been shown to interact with a variety of other mediators in the tumor microenvironment to increase Tgfβ expression,^163^ and it is also secreted in response to Tgfβ stimulation. Thbs1 is overexpressed in various types of cancers, including mammary gland cancer.^164^

Members of the Vegf family have a critical role in the regulation of angiogenesis, which is very important in the pathogenesis of neoplasia. Angiogenesis is also regulated by a number of secreted growth factors, including members of the Tgfβ family,^165^ and the induction of Vegf during tumor angiogenesis is mediated in part through Tgfβ stimulation.^166^ Vegfa is released by tumor cells to promote tumor angiogenesis, and it is also released from the extracellular matrix during tissue remodeling by Mmp9 to induce the angiogenesis that promotes tumor progression.^167^

The overrepresentation of Tgfβ mediators that were significantly upregulated in mammary gland adenocarcinomas from bromodichloroacetic acid-exposed female F344/NTac rats compared to spontaneous mammary gland adenocarcinomas may suggest a correlation between this pathway and the increased incidences of proliferative mammary gland lesions observed in the females. These data suggest that mammary gland carcinogenesis in animals exposed to bromodichloroacetic acid may be influenced in part by Tgfβ-dependent mechanisms.

Table N-1 Frozen Mammary Gland and Adenocarcinoma Samples from Control and Bromodichloroacetic Acid-exposed Female Rats

Animal Number | Histology Number | Frozen ID | Chemical | Dose | Diagnosis | Collection
1 | NA | Control-1LCM | NA | Control | Normal mammary gland | Frozen - LCM
2 | NA | Control-2LCM | NA | Control | Normal mammary gland | Frozen - LCM
3 | NA | Control-3LCM | NA | Control | Normal mammary gland | Frozen - LCM
4 | NA | Control-4LCM | NA | Control | Normal mammary gland | Frozen - LCM
5 | NA | Control-5LCM | NA | Control | Normal mammary gland | Frozen - LCM
DF401 | 91-57762 | SO905 | 2,2-Bis(bromomethyl)-1,3-propanediol | Control | Adenocarcinoma | Frozen
250 | 500250 | BC12350 | 3,3′,4,4′-Tetrachloroazo-benzene | Control | Adenocarcinoma | Frozen
LF325 | 92-61871 | SO1427 | D&C Yellow #11 | Control | Adenocarcinoma | Frozen
I033 | rz107-i033 | DV272 | Nickel sulfate hexahydrate | Control | Adenocarcinoma | Frozen
DF427 | 91-57771 | SO889 | 2,2-Bis(bromomethyl)-1,3-propanediol | Control | Adenocarcinoma | Frozen
649 | 0801003-14 | BC18860 | Bromodichloroacetic acid | 500 mg/L | Adenocarcinoma | Frozen
718 | 0801038-13 | BC18877 | Bromodichloroacetic acid | 1,000 mg/L | Adenocarcinoma | Frozen
708 | 0801028-13 | BC18846 | Bromodichloroacetic acid | 1,000 mg/L | Adenocarcinoma | Frozen
559 | 0800947-13 | BC18879 | Bromodichloroacetic acid | 250 mg/L | Adenocarcinoma | Frozen

NA = not applicable; LCM = laser-capture microdissected.

Table N-2 Upregulated Genes Associated with Tgfβ Signaling, Breast Cancer Growth, Invasion, and Metastasis in Mammary Gland Adenocarcinomas from Exposed F344/NTac Female Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

Gene | Fold Change | P Value | Function | Role in Cancer | References
Mmp9 | 11.232 | 0.0164 | Extracellular matrix remodeling | Cancer growth, migration, invasion | Cupić et al. 2011^160^
Mmp2 | 4.69 | 0.0110 | Extracellular matrix remodeling | Cancer growth, migration, invasion | Cupić et al. 2011^160^
Id1 | 3.055 | 0.0154 | Inhibition of differentiation | Tumor invasion, metastasis, EMT | Tobin et al. 2011^162^
Vegfa | 2.4 | 0.0381 | Proangiogenic factor | Cancer growth and metastasis | Breier et al. 2002^166^
Thbs1 | 2.04 | 0.0307 | Extracellular matrix remodeling | Tumor growth and metastasis | Roberts 1996^164^

EMT = epithelial-mesenchymal transition.