# Appendix M Sentinel Animal Program

## M.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) animals or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and sent to BioReliance Corporation, Rockville, MD, or Research Animal Diagnostic Laboratory, University of Missouri, Columbia, MO, for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Table M-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Three-month Study
ELISA
PVM (pneumonia virus of mice) | Study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study termination
Sendai | Study termination
Immunofluorescence Assay
Parvovirus | Study termination
Two-year Study
ELISA
Mycoplasma arthritidis | 12 months
M. pulmonis | 12 months
PVM | Study start, 1, 6, and 12 months
RCV/SDA | Study start, 1, 6, and 12 months
Sendai | Study start, 1, 6, and 12 months
Immunofluorescence Assay
Parvovirus | Study start, 1, 6, and 12 months
PVM | 1 month
RCV/SDA | 1 month
Sendai | 1 month
Multiplex Fluorescent Immunoassay
H1 (Toolan’s H-1 virus) | 18 months, study termination
KRV (Kilham’s rat virus) | 18 months, study termination
M. pulmonis | 18 months, study termination
Parvovirus NS-1 | 18 months, study termination
PVM | 18 months, study termination
RCV/SDA | 18 months, study termination
RMV (rat minute virus) | 18 months, study termination
RPV (rat parvovirus) | 18 months, study termination
RTV (rat theilovirus) | 18 months, study termination
Sendai | 18 months, study termination
TMEV (Theiler’s murine encephalomyelitis virus) | 18 months, study termination
Polymerase Chain Reaction
Helicobacter species | 12 months
Mice
Three-month Study
ELISA
Ectromelia virus | Study termination
EDIM (epizootic diarrhea of infant mice) | Study termination
GDVII (mouse encephalomyelitis virus) | Study termination
LCM (lymphocytic choriomeningitis virus) | Study termination
Mouse adenoma virus-FL | Study termination
MHV (mouse hepatitis virus) | Study termination
PVM | Study termination
Reovirus 3 | Study termination
Sendai | Study termination
Immunofluorescence Assay
Parvovirus | Study termination
Two-year Study
ELISA
Ectromelia virus | Study start, 1, 6, and 12 months
EDIM | Study start, 1, 6, and 12 months
GDVII | Study start, 1, 6, and 12 months
LCM | Study start, 1, 6, and 12 months
Mouse adenoma virus-1 | Study start, 1, 6, and 12 months
MHV | Study start, 1, 6, and 12 months
MPV VP2 (mouse parvovirus viral protein 2) | Study start, 1, 6, and 12 months
MVM VP2 (minute virus of mice viral protein 2) | Study start, 1, 6, and 12 months
M. arthritidis | 12 months
M. pulmonis | 12 months
PVM | Study start, 1, 6, and 12 months
Reovirus 3 | Study start, 1, 6, and 12 months
Sendai | Study start, 1, 6, and 12 months
Immunofluorescence Assay
EDIM | 6 months
Mouse adenoma virus-1 | 6 months
Multiplex Fluorescent Immunoassay
Ectromelia virus | 18 months, study termination
EDIM | 18 months, study termination
LCM | 18 months, study termination
MHV | 18 months, study termination
MNV (mouse norovirus) | 18 months, study termination
MPV | 18 months, study termination
MVM | 18 months, study termination
M. pulmonis | 18 months, study termination
Parvovirus NS-1 | 18 months, study termination
PVM | 18 months, study termination
Reovirus 3 | 18 months, study termination
TMEV GDVII | 18 months, study termination
Sendai | 18 months, study termination
Polymerase Chain Reaction
Helicobacter species | 12 and 18 months

## M.2 Results

All test results were negative.