# Appendix K Water and Compound Consumption in the Two-year Drinking Studies of Bromodichloroacetic Acid

Table K-1 Water and Compound Consumption by Male F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
5 | 18.5 | 211 | 18.3 | 206 | 22.2 | 17.7 | 205 | 43.3 | 16.8 | 201 | 83.7
9 | 18.0 | 282 | 17.7 | 276 | 16.0 | 17.1 | 270 | 31.7 | 16.5 | 267 | 61.9
13 | 17.6 | 330 | 17.2 | 321 | 13.4 | 16.1 | 312 | 25.8 | 15.9 | 309 | 51.4
17 | 17.7 | 365 | 18.2 | 356 | 12.8 | 16.7 | 345 | 24.2 | 16.3 | 342 | 47.7
21 | 18.0 | 395 | 18.5 | 382 | 12.1 | 17.2 | 370 | 23.2 | 16.7 | 367 | 45.5
25 | 18.8 | 420 | 18.0 | 405 | 11.1 | 17.3 | 393 | 22.0 | 16.4 | 387 | 42.4
29 | 19.1 | 431 | 19.1 | 420 | 11.4 | 18.5 | 407 | 22.7 | 18.0 | 400 | 45.0
33 | 17.4 | 449 | 17.5 | 438 | 10.0 | 16.7 | 425 | 19.6 | 16.0 | 417 | 38.4
37 | 18.6 | 464 | 17.8 | 449 | 9.9 | 17.0 | 438 | 19.4 | 17.2 | 430 | 40.0
41 | 19.3 | 478 | 18.8 | 464 | 10.1 | 18.2 | 452 | 20.1 | 17.8 | 440 | 40.5
45 | 18.9 | 490 | 18.4 | 474 | 9.7 | 17.7 | 462 | 19.2 | 17.8 | 451 | 39.5
49 | 18.7 | 500 | 19.1 | 486 | 9.8 | 18.1 | 474 | 19.1 | 17.5 | 457 | 38.3
53 | 19.6 | 510 | 19.0 | 491 | 9.7 | 18.0 | 479 | 18.8 | 17.9 | 463 | 38.7
57 | 19.8 | 517 | 19.0 | 498 | 9.5 | 18.4 | 484 | 19.0 | 17.8 | 470 | 37.9
61 | 19.2 | 520 | 18.9 | 502 | 9.4 | 18.5 | 486 | 19.0 | 17.6 | 472 | 37.3
65 | 20.4 | 524 | 19.5 | 505 | 9.7 | 18.7 | 490 | 19.1 | 18.6 | 472 | 39.4
69 | 20.6 | 527 | 20.0 | 506 | 9.9 | 19.3 | 492 | 19.6 | 19.3 | 473 | 40.8
73 | 20.7 | 526 | 20.1 | 511 | 9.8 | 19.9 | 497 | 20.0 | 18.8 | 473 | 39.8
77 | 21.8 | 528 | 19.7 | 512 | 9.6 | 19.6 | 500 | 19.6 | 18.9 | 470 | 40.2
81 | 21.9 | 517 | 20.2 | 507 | 10.0 | 19.5 | 496 | 19.7 | 18.5 | 470 | 39.4
85 | 21.2 | 508 | 20.3 | 504 | 10.1 | 20.4 | 496 | 20.6 | 19.1 | 470 | 40.7
89 | 22.7 | 505 | 21.8 | 503 | 10.8 | 20.7 | 491 | 21.1 | 20.0 | 468 | 42.8
93 | 21.8 | 512 | 22.3 | 498 | 11.2 | 21.0 | 482 | 21.8 | 20.1 | 457 | 43.9
97 | 23.1 | 494 | 23.3 | 479 | 12.1 | 21.9 | 474 | 23.1 | 20.0 | 445 | 44.9
101 | 23.8 | 486 | 22.7 | 465 | 12.2 | 21.7 | 468 | 23.2 | 20.5 | 434 | 47.2
Mean for Weeks
1–13 | 18.0 | 274 | 17.7 | 268 | 17.2 | 17.0 | 262 | 33.6 | 16.4 | 259 | 65.7
14–52 | 18.5 | 444 | 18.4 | 430 | 10.8 | 17.5 | 418 | 21.1 | 17.1 | 410 | 41.9
53–101 | 21.3 | 513 | 20.5 | 499 | 10.3 | 19.8 | 487 | 20.4 | 19.0 | 464 | 41.0

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of bromodichloroacetic acid consumed per kilogram body weight per day.

Table K-2 Water and Compound Consumption by Female F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
5 | 14.0 | 147 | 13.6 | 145 | 23.4 | 13.6 | 143 | 47.5 | 10.8 | 138 | 78.4
9 | 13.2 | 175 | 12.3 | 171 | 18.0 | 12.8 | 167 | 38.3 | 10.1 | 159 | 63.5
13 | 12.0 | 189 | 11.6 | 184 | 15.7 | 12.2 | 180 | 33.9 | 9.8 | 171 | 57.5
17 | 12.9 | 202 | 12.1 | 195 | 15.5 | 12.2 | 191 | 32.0 | 10.1 | 178 | 56.9
21 | 12.7 | 213 | 12.0 | 204 | 14.7 | 12.4 | 198 | 31.3 | 10.2 | 186 | 54.9
25 | 12.8 | 223 | 11.2 | 212 | 13.2 | 11.3 | 206 | 27.5 | 9.3 | 191 | 48.7
29 | 12.5 | 231 | 12.2 | 220 | 13.9 | 12.1 | 212 | 28.6 | 10.5 | 197 | 53.4
33 | 11.9 | 241 | 11.6 | 229 | 12.7 | 12.2 | 221 | 27.6 | 10.5 | 204 | 51.5
37 | 12.6 | 250 | 12.6 | 238 | 13.2 | 12.7 | 227 | 28.0 | 11.4 | 210 | 54.4
41 | 12.6 | 258 | 12.7 | 246 | 12.9 | 12.9 | 235 | 27.5 | 11.8 | 214 | 55.1
45 | 13.0 | 266 | 13.2 | 255 | 13.0 | 13.7 | 241 | 28.4 | 12.3 | 218 | 56.5
49 | 13.0 | 277 | 12.9 | 263 | 12.3 | 13.9 | 252 | 27.6 | 12.5 | 224 | 55.7
53 | 13.3 | 285 | 13.4 | 272 | 12.3 | 13.9 | 258 | 27.0 | 12.9 | 229 | 56.4
57 | 13.9 | 295 | 13.2 | 282 | 11.7 | 14.3 | 269 | 26.6 | 13.2 | 238 | 55.4
61 | 14.0 | 304 | 14.1 | 293 | 12.0 | 14.6 | 276 | 26.4 | 13.8 | 244 | 56.5
65 | 14.2 | 313 | 14.3 | 300 | 11.9 | 14.7 | 280 | 26.3 | 14.6 | 247 | 59.1
69 | 15.2 | 321 | 14.5 | 306 | 11.9 | 15.7 | 290 | 27.1 | 15.1 | 251 | 60.2
73 | 14.9 | 327 | 15.4 | 314 | 12.3 | 16.0 | 294 | 27.2 | 15.1 | 256 | 59.1
77 | 15.1 | 334 | 14.9 | 320 | 11.6 | 15.3 | 300 | 25.5 | 14.7 | 260 | 56.6
81 | 14.1 | 340 | 15.6 | 327 | 11.9 | 16.0 | 304 | 26.3 | 14.8 | 265 | 56.0
85 | 14.8 | 344 | 15.2 | 328 | 11.6 | 15.8 | 307 | 25.7 | 15.2 | 272 | 55.8
89 | 16.2 | 349 | 16.5 | 335 | 12.3 | 16.1 | 313 | 25.7 | 15.4 | 266 | 58.0
93 | 16.9 | 352 | 17.9 | 336 | 13.3 | 16.5 | 311 | 26.5 | 19.1 | 268 | 71.2
97 | 17.3 | 350 | 18.8 | 340 | 13.8 | 17.2 | 306 | 28.1 | 23.5 | 266 | 88.4
101 | 19.3 | 348 | 18.6 | 342 | 13.6 | 16.9 | 312 | 27.1 | 18.4 | 265 | 69.4
Mean for Weeks
1–13 | 13.1 | 170 | 12.5 | 167 | 19.0 | 12.9 | 163 | 39.9 | 10.2 | 156 | 66.5
14–52 | 12.7 | 240 | 12.3 | 229 | 13.5 | 12.6 | 220 | 28.7 | 11.0 | 202 | 54.1
53–101 | 15.3 | 328 | 15.6 | 315 | 12.3 | 15.6 | 294 | 26.6 | 15.8 | 256 | 61.7

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of bromodichloroacetic acid consumed per kilogram body weight per day.

Table K-3 Water and Compound Consumption by Male Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
5 | 3.4 | 30.1 | 3.3 | 30.1 | 27.4 | 3.3 | 29.9 | 55.2 | 3.2 | 28.8 | 110.9
9 | 3.5 | 37.2 | 3.4 | 37.1 | 22.9 | 3.3 | 36.5 | 45.2 | 3.4 | 35.2 | 96.7
13 | 3.4 | 42.3 | 3.5 | 42.5 | 20.6 | 3.3 | 41.6 | 39.6 | 3.2 | 39.6 | 80.8
17 | 3.3 | 46.6 | 3.2 | 46.3 | 17.3 | 3.2 | 46.2 | 34.6 | 3.1 | 44.5 | 69.6
21 | 3.7 | 48.4 | 3.6 | 48.3 | 18.6 | 3.5 | 48.3 | 36.2 | 3.3 | 47.2 | 70.0
25 | 3.8 | 49.7 | 3.8 | 49.5 | 19.2 | 3.6 | 49.9 | 36.1 | 3.3 | 49.3 | 67.0
29 | 4.0 | 50.9 | 3.7 | 50.7 | 18.2 | 3.6 | 50.7 | 35.5 | 3.2 | 50.2 | 63.7
33 | 4.4 | 52.3 | 4.3 | 51.7 | 20.8 | 4.0 | 51.9 | 38.6 | 3.7 | 51.1 | 72.4
37 | 4.0 | 53.1 | 3.9 | 52.3 | 18.6 | 3.8 | 52.5 | 36.2 | 3.5 | 51.8 | 67.6
41 | 4.3 | 54.1 | 4.2 | 53.3 | 19.7 | 4.1 | 53.4 | 38.4 | 3.9 | 52.5 | 74.3
45 | 4.3 | 54.5 | 4.2 | 53.6 | 19.6 | 4.0 | 53.8 | 37.2 | 3.8 | 52.3 | 72.6
49 | 4.9 | 55.6 | 4.7 | 54.7 | 21.5 | 4.5 | 54.8 | 41.0 | 4.5 | 53.1 | 84.8
53 | 4.2 | 55.6 | 4.3 | 54.7 | 19.6 | 4.2 | 54.6 | 38.4 | 4.1 | 52.3 | 78.5
57 | 5.0 | 55.8 | 5.1 | 54.9 | 23.2 | 4.9 | 55.2 | 44.4 | 4.9 | 51.2 | 95.7
61 | 4.8 | 55.9 | 4.9 | 55.3 | 22.2 | 5.0 | 54.7 | 45.7 | 4.9 | 50.4 | 97.2
65 | 5.0 | 55.4 | 5.0 | 54.6 | 22.9 | 5.0 | 53.4 | 46.8 | 5.4 | 47.8 | 112.9
69 | 5.4 | 55.3 | 5.2 | 53.3 | 24.4 | 5.4 | 51.1 | 52.8 | 5.2 | 44.2 | 117.8
73 | 5.2 | 55.2 | 5.4 | 53.3 | 25.3 | 5.4 | 50.8 | 53.2 | 5.8 | 42.8 | 135.5
77 | 5.5 | 54.9 | 5.9 | 53.4 | 27.6 | 7.4 | 47.3 | 78.2 | 6.3 | 39.6 | 159.1
81 | 5.2 | 54.6 | 6.3 | 52.3 | 30.1 | 7.5 | 44.8 | 83.7 | 6.5 | 38.3 | 169.8
85 | 5.3 | 54.7 | 6.0 | 51.2 | 29.3 | 7.0 | 44.0 | 79.6 | 6.0 | 36.8 | 163.3
89 | 5.2 | 54.3 | 6.2 | 49.5 | 31.3 | 6.6 | 41.4 | 79.8 | 5.8 | 34.2 | 169.8
93 | 4.9 | 52.9 | 5.8 | 47.8 | 30.3 | 6.9 | 38.8 | 88.9 | 5.9 | 32.2 | 183.5
97 | 5.2 | 50.1 | 6.8 | 45.1 | 37.7 | 6.6 | 37.3 | 88.5 | 6.3 | 31.7 | 198.6
101 | 5.5 | 48.1 | 6.2 | 43.1 | 35.9 | 6.1 | 35.7 | 85.3 | 5.9 | 30.3 | 194.4
Mean for Weeks
1–13 | 3.4 | 36.5 | 3.4 | 36.6 | 23.6 | 3.3 | 36.0 | 46.7 | 3.3 | 34.5 | 96.1
14–52 | 4.1 | 51.7 | 4.0 | 51.2 | 19.3 | 3.8 | 51.3 | 37.1 | 3.6 | 50.2 | 71.3
53–101 | 5.1 | 54.1 | 5.6 | 51.4 | 27.7 | 6.0 | 46.9 | 66.6 | 5.6 | 40.9 | 144.3

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of bromodichloroacetic acid consumed per kilogram body weight per day.

Table K-4 Water and Compound Consumption by Female Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
5 | 2.6 | 22.7 | 2.6 | 22.8 | 28.6 | 2.6 | 22.5 | 57.7 | 2.4 | 22.4 | 106.9
9 | 2.7 | 27.8 | 2.7 | 28.1 | 24.0 | 2.7 | 27.3 | 49.4 | 2.6 | 27.5 | 94.7
13 | 2.7 | 33.0 | 2.6 | 33.4 | 19.4 | 2.5 | 32.2 | 38.8 | 2.5 | 32.0 | 78.2
17 | 2.5 | 38.4 | 2.5 | 38.9 | 16.1 | 2.5 | 36.8 | 34.0 | 2.4 | 36.7 | 65.4
21 | 2.4 | 42.7 | 2.5 | 43.3 | 14.4 | 2.6 | 42.3 | 30.7 | 2.4 | 40.4 | 59.4
25 | 2.6 | 46.6 | 2.6 | 47.1 | 13.8 | 2.6 | 45.7 | 28.5 | 2.5 | 43.9 | 57.0
29 | 2.4 | 50.1 | 2.3 | 50.0 | 11.5 | 2.5 | 49.5 | 25.2 | 2.3 | 46.9 | 49.0
33 | 2.7 | 53.2 | 2.8 | 52.6 | 13.3 | 2.8 | 52.2 | 26.8 | 2.6 | 49.7 | 52.4
37 | 2.3 | 54.5 | 2.3 | 53.2 | 10.8 | 2.3 | 53.2 | 21.6 | 2.1 | 50.9 | 41.3
41 | 2.4 | 56.3 | 2.7 | 55.7 | 12.1 | 2.5 | 55.5 | 22.5 | 2.4 | 53.8 | 44.6
45 | 2.8 | 57.2 | 2.9 | 56.5 | 12.8 | 2.7 | 56.3 | 24.0 | 2.6 | 54.8 | 47.4
49 | 2.7 | 58.5 | 2.9 | 57.8 | 12.5 | 2.7 | 57.5 | 23.5 | 2.6 | 56.1 | 46.4
53 | 2.6 | 59.5 | 2.8 | 59.0 | 11.9 | 2.6 | 58.4 | 22.3 | 2.4 | 56.5 | 42.5
57 | 2.8 | 60.7 | 3.0 | 59.7 | 12.6 | 2.7 | 59.3 | 22.8 | 2.6 | 57.8 | 45.0
61 | 2.9 | 61.3 | 3.0 | 60.0 | 12.5 | 2.8 | 60.3 | 23.2 | 2.5 | 58.5 | 42.8
65 | 2.7 | 61.4 | 3.0 | 59.9 | 12.5 | 2.8 | 60.8 | 23.0 | 2.6 | 58.0 | 44.8
69 | 3.2 | 61.6 | 3.4 | 59.9 | 14.2 | 3.1 | 61.0 | 25.4 | 3.0 | 56.7 | 52.9
73 | 3.3 | 61.9 | 3.8 | 60.0 | 15.8 | 3.1 | 61.1 | 25.4 | 3.3 | 55.8 | 59.1
77 | 3.8 | 62.1 | 3.8 | 60.6 | 15.7 | 3.5 | 60.8 | 28.8 | 3.7 | 52.6 | 70.4
81 | 4.0 | 62.3 | 4.3 | 60.3 | 17.8 | 4.3 | 60.4 | 35.6 | 4.1 | 50.8 | 80.7
85 | 4.1 | 63.0 | 5.2 | 58.5 | 22.2 | 4.3 | 58.2 | 36.9 | 3.9 | 48.5 | 80.4
89 | 3.8 | 63.5 | 6.4 | 55.9 | 28.6 | 4.9 | 56.4 | 43.4 | 3.9 | 45.5 | 85.6
93 | 4.6 | 63.5 | 6.5 | 53.3 | 30.5 | 5.5 | 52.8 | 52.1 | 4.3 | 42.1 | 102.2
97 | 4.6 | 62.5 | 5.9 | 51.8 | 28.5 | 6.1 | 47.9 | 63.7 | 4.7 | 38.6 | 121.8
101 | 5.4 | 59.5 | 5.4 | 49.6 | 27.2 | 6.9 | 42.4 | 81.5 | 4.8 | 36.3 | 132.1
Mean for Weeks
1–13 | 2.7 | 27.8 | 2.6 | 28.1 | 24.0 | 2.6 | 27.3 | 48.6 | 2.5 | 27.3 | 93.3
14–52 | 2.5 | 50.8 | 2.6 | 50.6 | 13.0 | 2.6 | 49.9 | 26.3 | 2.4 | 48.1 | 51.4
53–101 | 3.7 | 61.8 | 4.3 | 57.6 | 19.2 | 4.0 | 56.9 | 37.2 | 3.5 | 50.6 | 73.9

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of bromodichloroacetic acid consumed per kilogram body weight per day.