# Appendix J Chemical Characterization and Dose Formulation Studies

## J.1 Procurement and Characterization of Bromodichloroacetic Acid

Bromodichloroacetic acid was obtained from Radian International, LLC (Austin, TX), in one lot (31542-80) and from Chemfinet Services, Inc. (Tarrytown, NY), in one lot (NJ 87-90/9/2005). Lot 31542-80 was used in the 2-week and 3-month studies, and lot NJ 87-90/9/2005 was used in the 2-year studies and in one genetic toxicology assay. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle Chemistry Support Services (Columbus, OH) and the study laboratories at Southern Research Institute (SRI) (Birmingham, AL) for the 2-week and 3-month studies and at Battelle Columbus Operations (Columbus, OH) for the 2-year studies. Karl Fischer titration was performed by Galbraith Laboratories (Knoxville, TN), and elemental analyses were performed by Prevalere Life Sciences, Inc. (Whitesboro, NY) and Elemental Analysis Corp. (Lexington, KY). Reports on analyses performed in support of the bromodichloroacetic acid studies are on file at the National Institute of Environmental Health Sciences. Both lots of the chemical, an off-white crystalline solid, were identified as bromodichloroacetic acid by the analytical chemistry laboratory using infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by the study laboratories using IR and NMR (SRI only) spectroscopy. All spectra were consistent with the literature spectra^141^ and for the structure of bromodichloroacetic acid. Representative IR and proton NMR spectra are presented in Figure J-1 and Figure J-2, respectively.

For lot 31542-80, purity was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection by system A (Table J-1) and ion chromatography (IC) by a system including a Dionex Ionpac AS11 (4 × 250 mm) reverse phase column (Thermo Scientific Inc., Bannockburn, IL) with suppressed conductivity detection, a mobile phase of A) 3 mM NaOH, and B) 50 mM NaOH, beginning with 100% A for 9 minutes (1.5 mL/minute flow rate), then to 0% A in 15 minutes (2 mL/minute flow rate), held for 31.9 minutes, then to 100% A in 0.1 minute, held for 5 minutes (flow rate 1.5 mL/minute). Titration of the acid functional group was performed using a Brinkman (Westbury, NY) Metrohm 702 M Titrino automatic titrator with a Metrohm combined pH glass electrode, titrated with NaOH (0.1 N).

For lot NJ 87-90/9/2005, elemental analyses were performed for carbon and hydrogen content using a LECO CHNS-932 analyzer (St. Joseph, MI). Elements from sodium through uranium (72 elements) were determined by the analytical chemistry laboratory using PIXE spectroscopy on a system including a General Ionex (Bellaire, MI) 4 MV tandem accelerator. The purity was determined using HPLC/UV by system A, gas chromatography (GC) with flame ionization detection (FID) by the method described below, and titration of the acid functional group by the method previously described.

GC/FID system (Agilent Technologies, Inc., Palo Alto, CA) included a Stabilwax DA, 30 m × 0.32 mm, 1.0 µm film (Restek, Bellefonte, PA) column, an oven temperature program beginning with 50°C held for 2 minutes, then 10°C/minute to 250°C, held for 2 minutes, and helium carrier gas at a flow rate of 2 mL/minute.

For lot 31542-80, Karl Fischer titration indicated 440 ppm water. HPLC/UV indicated one major peak and no impurities greater than 0.1% of the total peak area. IC indicated one major peak and four impurities, each greater than 0.1% of the total peak area, with a combined area of 1.2%. Titration of the acid functional group indicated a purity of 100%, assuming all titratable acid was present as bromodichloroacetic acid. The overall purity of lot 31542-80 was estimated to be approximately 99%.

For lot NJ 87-90/9/2005, Karl Fischer titration indicated approximately 0.4% water; elemental analyses for carbon and hydrogen were in agreement with the theoretical values; PIXE analysis indicated the presence of carbon (13%), hydrogen (0.5%), oxygen (17%), chlorine (31%), and bromine (38%), consistent with the theoretical values; no significant impurities were detected. HPLC/UV indicated one major peak with two impurities greater than 0.1% of the major peak area with a combined area of 0.6% (retention times 5.75 and 12.02 minutes). GC/FID indicated one major peak and two impurities with areas greater than 0.1% of the total peak area, with a combined area of 1.3% (retention times 11.17 and 12.29 minutes). Functional group titration indicated a purity of approximately 95%, assuming all titratable acid was present as bromodichloroacetic acid.

In an attempt to identify the impurities, commercially obtained standards of bromodichloroacetic acid, dibromochloroacetic acid, monochloroacetic acid, dichloroacetic acid, trichloroacetic acid, tribromoacetic acid, monobromoacetic acid, and dibromoacetic acid were analyzed using HPLC/UV by system A and GC/FID by the system previously described. Using HPLC spectra, the two impurities were identified as monochloroacetic acid (impurity one) and dibromochloroacetic acid (impurity two) by matching the retention times of the impurities to those of the standards. Spectra obtained using the GC/FID method detected only bromodichloroacetic acid (the test chemical) and dibromochloroacetic acid (impurity two); an additional impurity (impurity three) was detected at 12.29 minutes. Standard addition was used to quantitate the amount of dibromochloroacetic acid (impurity two) in the test chemical using the same GC/FID method; the amount present was determined to be 2.7%. Using the GC method previously described except with mass spectrometry detection, spectra were obtained of the test chemical and of commercially obtained standards for bromodichloroacetic acid and dibromochloroacetic acid and these spectra were compared to the National Institute of Standards and Technology library for mass spectrometry; results supported the tentative identity of impurity two as dibromochloroacetic acid; impurity three could not be identified because the peak was too small to give a useful mass spectrum. The overall purity of lot NJ 87-90/9/2005 was determined to be greater than 97%.

To ensure stability, the test chemical was stored at approximately −20°C in amber glass bottles sealed with Teflon®-lined lids protected from light and moisture for the 2-week and 3-month studies. Prior to the 2-year study, the physical appearance of a frozen reference standard of the test chemical kept at room temperature and exposed to air for approximately 3 days changed from “off white crystals” to a “very pale yellow liquid.” A forced degradation study of a frozen reference standard was performed by the study laboratory (Battelle Columbus Operations) using HPLC/UV by system B; no degradation occurred; the physical change was attributed to the hygroscopic nature of the test chemical. For the 2-year studies, the bulk chemical was stored at −20°C in sealed amber glass bottles with Teflon®-lined lids, secured by tape, and placed in a sealed glove bag filled with nitrogen, or repackaged in sealed amber glass bottles under a nitrogen headspace. Periodic reanalyses of the test chemical were performed twice during the 3-month studies and at least every 6 months during the 2-year studies using HPLC/UV by systems B or C; no degradation of the test chemical was observed.

## J.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared once during the 2-week studies, four times during the 3-month studies, and approximately every 6 weeks during the 2-year studies. The dose formulations were prepared by mixing bromodichloroacetic acid with tap water (Table J-2) and stored in sealed Nalgene^®^ containers with a minimal headspace at 5°C for up to 40 (3-month studies) or 42 (2-week and 2-year studies) days.

Stability studies of the 62.5 mg/L dose formulation were performed by the analytical chemistry laboratory using HPLC/UV by system C (Table J-1). Stability was confirmed for dose formulations stored in sealed amber glass or Nalgene^®^ high density polyethylene containers at 5°C for at least 42 days and for 7 days under simulated animal room conditions.

Periodic analyses of the dose formulations of bromodichloroacetic acid were conducted by the study laboratories using HPLC/UV by system D (2-week and 3-month studies) or system B (2-year studies). During the 2-week studies, the dose formulations were analyzed once; all five dose formulations for rats and mice were within 10% of the target concentrations (Table J-3). Animal room samples of these dose formulations were also analyzed; all five samples for rats and all five for mice were within 10% of the target concentrations. During the 3-month studies, the dose formulations were analyzed at the beginning, midpoint, and end of the studies; all 15 dose formulations for rats and mice were within 10% of the target concentrations (Table J-4). Animal room samples of these dose formulations were analyzed, and all 15 for rats and all 14 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 6 weeks, and all 63 dose formulations for rats and all 57 for mice were within 10% of the target concentrations (Table J-5). Animal room samples were also analyzed; all 12 for rats and all 12 for mice were within 10% of the target concentrations.

Tap water from the City of Columbus municipal supply was used as the vehicle. Samples of the tap water were taken within 30 days prior to the study start at 3-month intervals throughout the study and within 30 days of the end of the in-life phase and analyzed by an NIEHS analytical contractor for total chlorates, trihalomethanes, and haloacetic acids. Bromodichloroacetic acid was measured in the tap water and was found below the detection limit (approximately 0.6 µg/mL) in all samples analyzed. This detection limit was 100 times lower than the lowest concentration in the exposed animals in the 2-week and 3-month studies and 400 times lower than the lowest concentrations in the exposed animals in the 2-year studies. Note that in a nationwide study, bromodichloroacetic acid levels ranged from below detection limits to 15 ng/mL^30^ and that the highest concentration reported is approximately 4,200 times lower than the lowest concentration used in the 2-week and 3-month studies and 16,666 times lower than the lowest concentration used in the 2-year studies.

Table J-1 High-Performance Liquid Chromatography Systems Used in the Drinking Water Studies of Bromodichloroacetic Acid^a^

Detection System | Column | Solvent System
System A
Ultraviolet (220 nm) light | Prodigy-5 ODS-3, 150 mm × 4.6 mm, 5.0 µm (Phenomenex, Torrance, CA) | A) 15 mM phosphoric acid and B) 1:1 30 mM phosphoric acid:acetonitrile, linear gradient from 100% A to 0% A in 20 minutes, held for 15 minutes, linear gradient to 100% A in 5 minutes, held for 10 (2-week and 3-month studies) or 25 (2-year studies) minutes; flow rate 1.0 mL/minute
System B
Ultraviolet (220 nm) light | Aqua C_18_, 150 mm × 4.6 mm, 3.0 µm (Phenomenex) | A) 80:20 0.1 M phosphoric acid:acetonitrile B) 10:90 0.1 M phosphoric acid:acetonitrile, beginning with 100% A, held for 2 minutes, linear gradient to 80% A in 2 minutes, held for 11 minutes, linear gradient to 100% A in 5 minutes; flow rate 1.0 mL/minute
System C
Ultraviolet (220 nm) light | Aqua C_18_, 150 mm × 4.6 mm, 5.0 µm (Phenomenex) | A) 80:20 0.1 M phosphoric acid:acetonitrile B) 10:90 0.1 M phosphoric acid:acetonitrile, beginning with 100% A, held for 2 minutes, linear gradient to 0% A in 4 minutes, held for 9 minutes, linear gradient to 100% A in 5 minutes, held 5 minutes; flow rate 1.0 mL/minute
System D
Ultraviolet (220 nm) light | Aqua C_18_, 150 mm × 4.6 mm, 3.0 µm (Phenomenex) | 80:20 0.1 M phosphoric acid:acetonitrile, isocratic; flow rate 1.0 mL/minute

^a^ The high-performance liquid chromatographs were manufactured by Waters Corporation (Milford, MA).

Table J-2 Preparation and Storage of Dose Formulations in the Drinking Water Studies of Bromodichloroacetic Acid

Two-week Studies | Three-month Studies | Two-year Studies
Preparation
The appropriate amount of bromodichloroacetic acid was weighed in a graduated flask or beaker, tap water was added and stirred with a stir-bar until in solution, then transferred with five tap-water rinses to a mixing container filled to 2/3 volume with tap water, mixed for approximately 2 minutes with a stir bar, filled to final volume and mixed for at least 5 minutes; the pH was determined and, if necessary, adjusted to pH 5 using NaOH or HCl, then mixed an additional 10 minutes. Formulations were prepared once during the 2-week studies. | Same as 2-week studies. Formulations were prepared four times during the 3-month studies. | Bromodichloroacetic acid was removed from the freezer the day before and allowed to equilibrate to room temperature. The appropriate amount of bromodichloroacetic acid was weighed and transferred with three tap-water rinses to a calibrated Nalgene^®^ container half-filled with tap water, filled to 90% volume and stirred with an overhead drum stirrer for approximately 10 minutes; the pH was determined and, if necessary, adjusted with NaOH to a pH between 6 and 7.5, diluted to final volume, and stirred for approximately 5 minutes. Formulations were prepared approximately every 6 weeks during the 2-year studies.
Chemical Lot Number
31542-80 | 31542-80 | NJ 87-90/9/2005
Maximum Storage Time
42 days | 40 days | 42 days
Storage Conditions
Stored in Nalgene^®^ carboys, protected from light at approximately 5°C. | Stored in Nalgene^®^ carboys, protected from light at approximately 5°C. | Stored in Nalgene^®^ carboys, protected from light at approximately 5°C.
Study Laboratory
Southern Research Institute (Birmingham, AL) | Southern Research Institute (Birmingham, AL) | Battelle Columbus Operations (Columbus, OH)

Table J-3 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Two-week Drinking Water Studies of Bromodichloroacetic Acid

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
Rats and Mice
August 15, 2000 | August 16, 2000 | 62.5 | 62.7 ± 1.0 | 0
| | 125 | 123 ± 0.9 | −2
| | 250 | 242 ± 2.9 | −3
| | 500 | 498 ± 14 | 0
| | 1,000 | 997 ± 21 | 0
Animal Room Samples
Rats
August 15, 2000 | September 8, 2000 | 62.5 | 61.4 ± 0.8 | −2
| | 125 | 123 ± 1.5 | −2
| | 250 | 239 ± 3.0 | −4
| | 500 | 488 ± 2.4 | −2
| | 1,000 | 989 ± 7.5 | −1
Mice
August 15, 2000 | September 8, 2000 | 62.5 | 61.1 ± 0.2 | −2
| | 125 | 124 ± 0.4 | −1
| | 250 | 242 ± 2.3 | −3
| | 500 | 498 ± 2.1 | 0
| | 1,000 | 999 ± 6.6 | 0

^a^ Results of duplicate analyses.

Table J-4 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Drinking Water Studies of Bromodichloroacetic Acid

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
November 2, 2000 | November 3, 2000 | 62.5 | 60.1 ± 0.7 | −4
| | 125 | 120 ± 2.2 | −4
| | 250 | 246 ± 2.4 | −2
| | 500 | 493 ± 7.9 | −1
| | 1,000 | 981 ± 10.5 | −2
| December 5, 2000^b^ | 62.5 | 61.0 ± 0.6 | −2
| | 125 | 120 ± 1.0 | −4
| | 250 | 246 ± 0.2 | −2
| | 500 | 495 ± 3.8 | −1
| | 1,000 | 978 ± 2.3 | −2
November 30, 2000 | December 1, 2000 | 62.5 | 61.3 ± 0.3 | −2
| | 125 | 129 ± 1.1 | +3
| | 250 | 246 ± 1.1 | −2
| | 500 | 497 ± 1.6 | −1
| | 1,000 | 998 ± 5.8 | 0
| January 9, 2001^b^ | 62.5 | 60.7 ± 0.6 | −3
| | 125 | 128 ± 0.5 | +2
| | 250 | 244 ± 2.5 | −2
| | 500 | 495 ± 3.2 | −1
| | 1,000 | 994 ± 5.4 | −1
January 25, 2001 | January 26, 2001 | 62.5 | 59.2 ± 0.5 | −5
| | 125 | 122 ± 0.3 | −2
| | 250 | 239 ± 2.7 | −4
| | 500 | 480 ± 0.7 | −4
| | 1,000 | 973 ± 14.1 | −3
| February 15–16, 2001^b^ | 62.5 | 63.2 ± 0.1 | +1
| | 125 | 124 ± 1.3 | −1
| | 250 | 245 ± 1.7 | −2
| | 500 | 492 ± 2.8 | −2
| | 1,000 | 994 ± 3.7 | −1
Mice
November 2, 2000 | November 3, 2000 | 62.5 | 60.1 ± 0.7 | −4
| | 125 | 120 ± 2.2 | −4
| | 250 | 246 ± 2.4 | −2
| | 500 | 493 ± 7.9 | −1
| | 1,000 | 981 ± 10.5 | −2
| December 5, 2000^b^ | 62.5 | 61.0 ± 0.4 | −2
| | 125 | 122 ± 0.8 | −2
| | 250 | 249 ± 4.0 | 0
| | 500 | 501 ± 0.4 | 0
November 30, 2000 | December 1, 2000 | 62.5 | 61.3 ± 0.3 | −2
| | 125 | 129 ± 1.1 | +3
| | 250 | 246 ± 1.1 | −2
| | 500 | 497 ± 1.6 | −1
| | 1,000 | 998 ± 5.8 | 0
| January 9, 2001^b^ | 62.5 | 60.6 ± 0.8 | −3
| | 125 | 127 ± 0.5 | +2
| | 250 | 244 ± 1.7 | −2
| | 500 | 493 ± 3.0 | −1
| | 1,000 | 987 ± 6.5 | −1
January 25, 2001 | January 26, 2001 | 62.5 | 59.2 ± 0.5 | −5
| | 125 | 122 ± 0.3 | −2
| | 250 | 239 ± 2.7 | −4
| | 500 | 480 ± 0.7 | −4
| | 1,000 | 973 ± 14.1 | −3
| February 15–16, 2001^b^ | 62.5 | 62.0 ± 0.2 | −1
| | 125 | 123 ± 3.1 | −2
| | 250 | 248 ± 2.4 | −1
| | 500 | 494 ± 15.8 | −1
| | 1,000 | 985 ± 17.3 | −2

^a^ Results of duplicate analyses.

^b^ Animal room samples.

Table J-5 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Two-year Drinking Water Studies of Bromodichloroacetic Acid

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
Rats
September 19, 2006 | September 19, 2006 | 250 | 248 ± 0 | −1
| | 500 | 482 ± 1 | −4
| | 1,000 | 1,000 ± 0 | 0
| November 2, 2006^b^ | 250 | 243 ± 1 | −3
| | 500 | 479 ± 1 | −4
| | 1,000 | 989 ± 0 | −1
November 21, 2006 | November 21, 2006 | 250 | 252 ± 0 | +1
| | 250 | 245 ± 0 | −2
| | 500 | 498 ± 2 | 0
| | 500 | 503 ± 0 | +1
| | 1,000 | 1,020 ± 0 | +2
| | 1,000 | 1,000 ± 0 | 0
February 13, 2007 | February 15, 2007 | 250 | 252 ± 0 | +1
| | 250 | 253 ± 1 | +1
| | 500 | 505 ± 1 | +1
| | 500 | 508 ± 0 | +2
| | 1,000 | 1,020 ± 0 | +2
| | 1,000 | 1,030 ± 0 | +3
May 8, 2007 | May 9, 2007 | 250 | 247 ± 0 | −1
| | 250 | 248 ± 0 | −1
| | 500 | 488 ± 1 | −2
| | 500 | 496 ± 1 | −1
| | 1,000 | 1,010 ± 0 | +1
| | 1,000 | 1,000 ± 0 | 0
| June 20, 2007^b^ | 250 | 259 ± 2 | +4
| | 500 | 509 ± 1 | +2
| | 1,000 | 1,020 ± 0 | +2
July 31, 2007 | August 2, 2007 | 250 | 254 ± 1 | +2
| | 250 | 252 ± 1 | +1
| | 500 | 505 ± 3 | +1
| | 500 | 501 ± 0 | 0
| | 1,000 | 1,080 ± 40 | +8
| | 1,000 | 1,040 ± 0 | +4
September 25, 2007 | September 28, 2007 | 250 | 252 ± 1 | +1
| | 250 | 252 ± 1 | +1
| | 500 | 512 ± 2 | +2
| | 500 | 498 ± 1 | 0
| | 1,000 | 1,040 ± 0 | +4
| | 1,000 | 1,030 ± 0 | +3
December 18, 2007 | December 19, 2007 | 250 | 254 ± 1 | +2
| | 250 | 250 ± 1 | 0
| | 500 | 504 ± 2 | +1
| | 500 | 497 ± 2 | −1
| | 1,000 | 1,040 ± 10 | +4
| | 1,000 | 1,030 ± 0 | +3
December 18, 2007 | January 29, 2008^b^ | 250 | 247 ± 3 | −1
| | 500 | 493 ± 0 | −1
| | 1,000 | 1,030 ± 0 | +3
March 11, 2008 | March 12, 2008 | 250 | 253 ± 1 | +1
| | 250 | 250 ± 1 | 0
| | 500 | 503 ± 2 | +1
| | 500 | 507 ± 1 | +1
| | 1,000 | 1,030 ± 10 | +3
| | 1,000 | 1,020 ± 0 | +2
June 3, 2008 | June 3, 2008 | 250 | 260 ± 1 | +4
| | 250 | 257 ± 1 | +3
| | 500 | 518 ± 0 | +4
| | 500 | 523 ± 1 | +5
| | 1,000 | 1,070 ± 0 | +7
| | 1,000 | 1,060 ± 0 | +6
| July 17, 2008^b^ | 250 | 250 ± 1 | 0
| | 500 | 504 ± 1 | +1
| | 1,000 | 1,030 ± 20 | +3
July 29, 2008 | July 31, 2008 | 250 | 254 ± 1 | +2
| | 250 | 247 ± 1 | −1
| | 500 | 508 ± 0 | +2
| | 500 | 496 ± 0 | −1
| | 1,000 | 1,050 ± 0 | +5
| | 1,000 | 1,030 ± 0 | +3
September 23, 2008 | September 24, 2008 | 250 | 251 ± 0 | 0
| | 250 | 249 ± 1 | 0
| | 500 | 508 ± 2 | +2
| | 500 | 498 ± 1 | 0
| | 1,000 | 1,040 ± 10 | +4
| | 1,000 | 1,020 ± 0 | +2
Mice
September 19, 2006 | September 19, 2006 | 250 | 248 ± 0 | −1
| | 500 | 482 ± 1 | −4
| | 1,000 | 1,000 ± 0 | 0
| November 2, 2006^b^ | 250 | 245 ± 1 | −2
| | 500 | 479 ± 1 | −4
| | 1,000 | 988 ± 20 | −1
November 21, 2006 | November 21, 2006 | 250 | 252 ± 0 | +1
| | 250 | 245 ± 0 | −2
| | 500 | 498 ± 2 | 0
| | 500 | 503 ± 0 | +1
| | 1,000 | 1,020 ± 0 | +2
| | 1,000 | 1,000 ± 0 | 0
February 13, 2007 | February 15, 2007 | 250 | 252 ± 0 | +1
| | 250 | 253 ± 1 | +1
| | 500 | 505 ± 1 | +1
| | 500 | 508 ± 0 | +2
| | 1,000 | 1,020 ± 0 | +2
| | 1,000 | 1,030 ± 0 | +3
May 8, 2007 | May 9, 2007 | 250 | 247 ± 0 | −1
| | 250 | 248 ± 0 | −1
| | 500 | 488 ± 1 | −2
| | 500 | 496 ± 1 | −1
| | 1,000 | 1,010 ± 0 | +1
| | 1,000 | 1,000 ± 0 | 0
| June 20, 2007^b^ | 250 | 255 ± 1 | +2
| | 500 | 508 ± 0 | +2
| | 1,000 | 1,030 ± 30 | +3
July 31, 2007 | August 2, 2007 | 250 | 254 ± 1 | +2
| | 250 | 252 ± 1 | +1
| | 500 | 505 ± 3 | +1
| | 500 | 501 ± 0 | 0
| | 1,000 | 1,080 ± 40 | +8
| | 1,000 | 1,040 ± 0 | +4
September 25, 2007 | September 28, 2007 | 250 | 252 ± 1 | +1
| | 250 | 252 ± 1 | +1
| | 500 | 512 ± 2 | +2
| | 500 | 498 ± 1 | 0
| | 1,000 | 1,040 ± 0 | +4
| | 1,000 | 1,030 ± 0 | +3
December 18, 2007 | December 19, 2007 | 250 | 254 ± 1 | +2
| | 250 | 250 ± 1 | 0
| | 500 | 504 ± 2 | +1
| | 500 | 497 ± 2 | −1
| | 1,000 | 1,040 ± 10 | +4
| | 1,000 | 1,030 ± 0 | +3
| January 29, 2008^b^ | 250 | 248 ± 1 | −1
| | 500 | 493 ± 2 | −1
| | 1,000 | 1,020 ± 10 | +2
March 11, 2008 | March 12, 2008 | 250 | 253 ± 1 | +1
| | 250 | 250 ± 1 | 0
| | 500 | 503 ± 2 | +1
| | 500 | 507 ± 1 | +1
| | 1,000 | 1,030 ± 10 | +3
| | 1,000 | 1,020 ± 0 | +2
June 3, 2008 | June 3, 2008 | 250 | 260 ± 1 | +4
| | 250 | 257 ± 1 | +3
| | 500 | 518 ± 0 | +4
| | 500 | 523 ± 1 | +5
| | 1,000 | 1,070 ± 0 | +7
| | 1,000 | 1,060 ± 0 | +6
June 3, 2008 | July 17, 2008^b^ | 250 | 249 ± 1 | 0
| | 500 | 505 ± 1 | +1
| | 1,000 | 1,030 ± 0 | +3
July 29, 2008 | July 31, 2008 | 250 | 254 ± 1 | +2
| | 250 | 247 ± 1 | −1
| | 500 | 508 ± 0 | +2
| | 500 | 496 ± 0 | −1
| | 1,000 | 1,050 ± 0 | +5
| | 1,000 | 1,030 ± 0 | +3

^a^ Results of duplicate analyses.

^b^ Animal room samples.

Figure J-1

Infrared Absorption Spectrum of Bromodichloroacetic Acid

Figure J-2

Proton Nuclear Magnetic Resonance Spectrum of Bromodichloroacetic Acid