# Appendix I Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table I-1 Summary of Reproductive Tissue Evaluations for Male F344/N Rats in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt. | 341 ± 5 | 356 ± 5 | 350 ± 6 | 336 ± 6
L. Cauda epididymis wt. | 0.1984 ± 0.0051 | 0.2054 ± 0.0059 | 0.1985 ± 0.0063 | 0.1927 ± 0.0059
L. Epididymis | 0.4881 ± 0.0131 | 0.4901 ± 0.0105 | 0.4812 ± 0.0077 | 0.4659 ± 0.0092
L. Testis | 1.5659 ± 0.0309 | 1.5448 ± 0.0236 | 1.4900 ± 0.0204 | 1.4853 ± 0.0145*
Spermatid measurements
Spermatid heads (10^6^/testis) | 188.00 ± 6.63 | 189.69 ± 5.84 | 186.75 ± 5.73 | 179.50 ± 5.81
Spermatid heads (10^6^/g testis) | 132.7 ± 4.3 | 134.9 ± 4.8 | 136.4 ± 3.7 | 132.4 ± 4.5
Epididymal spermatozoal measurements
Sperm motility (%) | 74.3 ± 0.9 | 71.0 ± 1.4 | 71.0 ± 1.1 | 70.8 ± 1.5
Sperm (10^6^/cauda epididymis) | 92.65 ± 5.89 | 102.89 ± 2.98 | 98.66 ± 5.43 | 95.64 ± 4.51
Sperm (10^6^/g cauda epididymis) | 467 ± 26 | 504 ± 20 | 499 ± 27 | 502 ± 31

* Significantly different (P ≤ 0.05) from the control group by Dunnett’s test.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body, cauda epididymis, and epididymis weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table I-2 Estrous Cycle Characterization for Female F344/N Rats in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Number weighed at necropsy | 9 | 10 | 10 | 10
Necropsy body wt. (g) | 194 ± 3 | 193 ± 3 | 197 ± 2 | 184 ± 2*
Proportion of regular cycling females^b^ | 6/9 | 6/10 | 7/10 | 6/10
Estrous cycle length (days) | 4.78 ± 0.28 | 5.33 ± 0.48^c^ | 4.85 ± 0.18 | 4.65 ± 0.25
Estrous stages (% of cycle)
Diestrus | 48.1 | 35.8 | 46.7 | 36.7
Proestrus | 3.7 | 5.8 | 6.7 | 5.0
Estrus | 32.4 | 44.2 | 30.0 | 40.8
Metestrus | 15.7 | 14.2 | 16.7 | 17.5

* Significantly different (P ≤ 0.05) from the control group by Dunnett’s test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the control group are not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the control group and each exposed group indicated that 250 mg/L females had a higher probability of extended estrus than did the controls.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

Table I-3 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt. | 39.3 ± 1.0 | 40.1 ± 1.0 | 39.8 ± 0.8 | 36.8 ± 0.7
L. Cauda epididymis wt. | 0.0281 ± 0.0027 | 0.0272 ± 0.0017 | 0.0236 ± 0.0013 | 0.0265 ± 0.0017
L. Epididymis | 0.0609 ± 0.0032 | 0.0590 ± 0.0019 | 0.0585 ± 0.0024 | 0.0559 ± 0.0015
L. Testis | 0.1228 ± 0.0018 | 0.1251 ± 0.0042 | 0.1251 ± 0.0017 | 0.1190 ± 0.0024
Spermatid measurements
Spermatid heads (10^6^/testis) | 21.17 ± 1.14 | 21.88 ± 0.92 | 22.01 ± 1.32 | 20.88 ± 0.97
Spermatid heads (10^6^/g testis) | 189.8 ± 10.6 | 200.0 ± 10.1 | 200.4 ± 10.3 | 192.6 ± 7.8
Epididymal spermatozoal measurements
Sperm motility (%) | 69.3 ± 1.4 | 71.0 ± 1.1 | 62.0 ± 5.2 | 68.9 ± 1.8
Sperm (10^6^/cauda epididymis) | 18.40 ± 0.99 | 21.04 ± 0.85 | 17.57 ± 2.30 | 17.65 ± 0.79
Sperm (10^6^/g cauda epididymis) | 698 ± 60 | 803 ± 63 | 777 ± 119 | 682 ± 41

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table I-4 Estrous Cycle Characterization for Female Mice in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt. (g) | 33.8 ± 0.6 | 32.6 ± 0.7 | 33.2 ± 0.9 | 30.7 ± 0.7*
Proportion of regular cycling females^b^ | 2/10 | 1/10 | 2/10 | 4/10
Estrous cycle length (days) | 5.22 ± 0.68^c^ | 5.94 ± 0.59^d^ | 4.16 ± 0.19 | 4.83 ± 0.52^d^
Estrous stages (% of cycle)
Diestrus | 25.8 | 27.5 | 25.0 | 27.5
Proestrus | 0.0 | 1.7 | 2.5 | 0.8
Estrus | 60.8 | 56.7 | 55.0 | 54.2
Metestrus | 13.3 | 14.2 | 17.5 | 17.5

* Significantly different (P ≤ 0.05) from the control group by Dunnett’s test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the control group are not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the control group and each exposed group indicated that exposed females did not have extended estrus or diestrus.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

^d^ Estrous cycle was longer than 12 days or unclear in 2 of 10 animals.