# Appendix H Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table H-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the Two-week Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt. | 163 ± 5 | 170 ± 4 | 165 ± 4 | 170 ± 7 | 158 ± 5 | 164 ± 3
Heart
Absolute | 0.59 ± 0.02 | 0.59 ± 0.01 | 0.58 ± 0.02 | 0.62 ± 0.03 | 0.57 ± 0.02 | 0.60 ± 0.02
Relative | 3.612 ± 0.074 | 3.462 ± 0.082 | 3.534 ± 0.048 | 3.642 ± 0.076 | 3.589 ± 0.043 | 3.679 ± 0.09
R. Kidney
Absolute | 0.72 ± 0.03 | 0.74 ± 0.02 | 0.71 ± 0.04 | 0.74 ± 0.02 | 0.70 ± 0.01 | 0.74 ± 0.02
Relative | 4.440 ± 0.072 | 4.339 ± 0.092 | 4.287 ± 0.136 | 4.359 ± 0.072 | 4.460 ± 0.053 | 4.507 ± 0.033
Liver
Absolute | 7.74 ± 0.37 | 8.25 ± 0.19 | 7.96 ± 0.29 | 8.18 ± 0.35 | 7.60 ± 0.39 | 8.31 ± 0.31
Relative | 47.451 ± 1.121 | 48.500 ± 0.503 | 48.148 ± 0.564 | 48.046 ± 0.379 | 48.139 ± 1.051 | 50.608 ± 1.196
Lung
Absolute | 0.97 ± 0.05 | 0.88 ± 0.02 | 0.98 ± 0.1^b^ | 1.01 ± 0.04 | 0.90 ± 0.04 | 0.94 ± 0.05
Relative | 5.938 ± 0.205 | 5.18 ± 0.129 | 5.857 ± 0.434^b^ | 5.945 ± 0.144 | 5.686 ± 0.157 | 5.723 ± 0.266
R. Testis
Absolute | 0.962 ± 0.021 | 1.014 ± 0.036 | 1.031 ± 0.020 | 1.015 ± 0.022 | 0.810 ± 0.074* | 0.974 ± 0.027
Relative | 5.918 ± 0.071 | 5.965 ± 0.192 | 6.257 ± 0.172 | 5.988 ± 0.152 | 5.130 ± 0.428 | 5.935 ± 0.084
Thymus
Absolute | 0.410 ± 0.016 | 0.409 ± 0.008 | 0.402 ± 0.042 | 0.400 ± 0.014 | 0.385 ± 0.026 | 0.361 ± 0.022
Relative | 2.527 ± 0.126 | 2.410 ± 0.082 | 2.419 ± 0.213 | 2.373 ± 0.141 | 2.446 ± 0.159 | 2.195 ± 0.103
Female
Necropsy body wt. | 124 ± 2 | 125 ± 3 | 124 ± 2 | 123 ± 2 | 118 ± 3 | 120 ± 3
Heart
Absolute | 0.45 ± 0.01 | 0.47 ± 0.01 | 0.47 ± 0.01 | 0.43 ± 0.01 | 0.44 ± 0.01 | 0.43 ± 0.01
Relative | 3.632 ± 0.048 | 3.716 ± 0.078 | 3.766 ± 0.052 | 3.468 ± 0.035 | 3.709 ± 0.094 | 3.57 ± 0.092
R. Kidney
Absolute | 0.55 ± 0.01 | 0.57 ± 0.03 | 0.57 ± 0.01 | 0.54 ± 0.01 | 0.55 ± 0.02 | 0.55 ± 0.03
Relative | 4.459 ± 0.074 | 4.571 ± 0.144 | 4.596 ± 0.086 | 4.383 ± 0.103 | 4.662 ± 0.045 | 4.581 ± 0.147
Liver
Absolute | 4.95 ± 0.09 | 5.21 ± 0.19 | 5.17 ± 0.12 | 5.01 ± 0.14 | 4.98 ± 0.20 | 5.23 ± 0.21
Relative | 39.985 ± 0.607 | 41.515 ± 0.963 | 41.792 ± 0.411 | 40.726 ± 0.711 | 42.077 ± 0.599 | 43.559 ± 0.695**
Lung
Absolute | 0.83 ± 0.06 | 0.79 ± 0.02 | 0.83 ± 0.04 | 0.75 ± 0.02 | 0.75 ± 0.04 | 0.74 ± 0.04
Relative | 6.691 ± 0.502 | 6.301 ± 0.107 | 6.740 ± 0.362 | 6.122 ± 0.118 | 6.328 ± 0.283 | 6.144 ± 0.299
Thymus
Absolute | 0.356 ± 0.011 | 0.339 ± 0.024 | 0.344 ± 0.003 | 0.349 ± 0.009 | 0.319 ± 0.015 | 0.305 ± 0.004*
Relative | 2.881 ± 0.098 | 2.691 ± 0.144 | 2.785 ± 0.054 | 2.844 ± 0.077 | 2.699 ± 0.102 | 2.548 ± 0.064

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 4.

Table H-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt. | 341 ± 5 | 349 ± 8 | 349 ± 6 | 356 ± 5 | 350 ± 6 | 336 ± 6
Heart
Absolute | 0.89 ± 0.01 | 0.9 ± 0.02 | 0.89 ± 0.03 | 0.92 ± 0.02 | 0.89 ± 0.02 | 0.89 ± 0.01
Relative | 2.60 ± 0.03 | 2.59 ± 0.02 | 2.56 ± 0.04 | 2.59 ± 0.03 | 2.55 ± 0.04 | 2.65 ± 0.03
R. Kidney
Absolute | 0.98 ± 0.03 | 1.01 ± 0.02 | 1.00 ± 0.03 | 1.00 ± 0.02 | 0.95 ± 0.02 | 0.95 ± 0.02
Relative | 2.86 ± 0.04 | 2.90 ± 0.03 | 2.86 ± 0.04 | 2.80 ± 0.02 | 2.71 ± 0.04* | 2.83 ± 0.03
Liver
Absolute | 10.60 ± 0.34 | 11.01 ± 0.30 | 10.79 ± 0.19 | 11.25 ± 0.28 | 10.91 ± 0.24 | 11.33 ± 0.33
Relative | 31.05 ± 0.57 | 31.53 ± 0.45 | 30.99 ± 0.36 | 31.59 ± 0.42 | 31.20 ± 0.66 | 33.73 ± 0.69**
Lung
Absolute | 1.43 ± 0.04 | 1.60 ± 0.05 | 1.55 ± 0.04 | 1.57 ± 0.06 | 1.56 ± 0.09 | 1.48 ± 0.08
Relative | 4.19 ± 0.08 | 4.59 ± 0.09 | 4.47 ± 0.19 | 4.40 ± 0.13 | 4.47 ± 0.26 | 4.41 ± 0.21
R. Testis
Absolute | 1.446 ± 0.022 | 1.476 ± 0.019 | 1.475 ± 0.026 | 1.461 ± 0.027 | 1.403 ± 0.022 | 1.391 ± 0.012
Relative | 4.249 ± 0.073 | 4.236 ± 0.049 | 4.239 ± 0.071 | 4.108 ± 0.051 | 4.013 ± 0.053* | 4.151 ± 0.062
Thymus
Absolute | 0.244 ± 0.009 | 0.241 ± 0.007 | 0.240 ± 0.006 | 0.261 ± 0.012 | 0.241 ± 0.010 | 0.235 ± 0.007
Relative | 0.718 ± 0.026 | 0.694 ± 0.023 | 0.691 ± 0.019 | 0.733 ± 0.031 | 0.690 ± 0.026 | 0.699 ± 0.023
Female
n | 9 | 10 | 10 | 10 | 10 | 10
Necropsy body wt. | 194 ± 3 | 206 ± 3 | 203 ± 2 | 193 ± 3 | 197 ± 2 | 184 ± 2**
Heart
Absolute | 0.58 ± 0.01 | 0.60 ± 0.02 | 0.62 ± 0.03 | 0.57 ± 0.01 | 0.58 ± 0.01 | 0.56 ± 0.01
Relative | 3.01 ± 0.04 | 2.91 ± 0.08 | 3.06 ± 0.15 | 2.96 ± 0.04 | 2.95 ± 0.03 | 3.05 ± 0.05
R. Kidney
Absolute | 0.61 ± 0.01 | 0.67 ± 0.01* | 0.65 ± 0.01 | 0.65 ± 0.01 | 0.65 ± 0.02 | 0.66 ± 0.02*
Relative | 3.15 ± 0.05 | 3.24 ± 0.06 | 3.23 ± 0.04 | 3.36 ± 0.03* | 3.31 ± 0.07* | 3.62 ± 0.09**
Liver
Absolute | 5.85 ± 0.20 | 6.29 ± 0.07 | 6.12 ± 0.12 | 5.70 ± 0.10 | 6.13 ± 0.17 | 5.77 ± 0.15
Relative | 30.16 ± 0.81 | 30.61 ± 0.51 | 30.30 ± 0.78 | 29.57 ± 0.45 | 31.16 ± 0.72 | 31.43 ± 0.64
Lung
Absolute | 1.03 ± 0.03 | 1.12 ± 0.06 | 1.11 ± 0.05 | 1.06 ± 0.03 | 1.13 ± 0.02 | 1.08 ± 0.03
Relative | 5.32 ± 0.08 | 5.43 ± 0.30 | 5.52 ± 0.29 | 5.49 ± 0.17 | 5.73 ± 0.13 | 5.87 ± 0.17
Thymus
Absolute | 0.205 ± 0.008 | 0.212 ± 0.008 | 0.220 ± 0.007 | 0.200 ± 0.006 | 0.214 ± 0.005 | 0.210 ± 0.006
Relative | 1.060 ± 0.040 | 1.031 ± 0.039 | 1.086 ± 0.031 | 1.037 ± 0.028 | 1.091 ± 0.035 | 1.144 ± 0.031

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table H-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/NTac Rats at the Six-month Interim Evaluation in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 8 | 8 | 8 | 8
Male
Necropsy body wt. | 454 ± 6 | 425 ± 7** | 411 ± 7** | 398 ± 3**
L. Kidney
Absolute | 1.381 ± 0.024 | 1.273 ± 0.030** | 1.221 ± 0.022** | 1.184 ± 0.011**
Relative | 3.04 ± 0.04 | 2.99 ± 0.05 | 2.97 ± 0.04 | 2.98 ± 0.04
R. Kidney
Absolute | 1.35 ± 0.03 | 1.24 ± 0.02** | 1.18 ± 0.03** | 1.13 ± 0.02**
Relative | 2.96 ± 0.04 | 2.91 ± 0.04 | 2.87 ± 0.06 | 2.85 ± 0.03
Liver
Absolute | 18.57 ± 0.42 | 16.87 ± 0.49* | 17.03 ± 0.42* | 16.70 ± 0.32**
Relative | 40.90 ± 0.49 | 39.67 ± 0.74 | 41.43 ± 0.43 | 41.93 ± 0.68
Female
Necropsy body wt. | 230 ± 5 | 213 ± 5** | 217 ± 3** | 192 ± 2**
L. Kidney
Absolute | 0.749 ± 0.014 | 0.737 ± 0.011 | 0.778 ± 0.018 | 0.746 ± 0.018
Relative | 3.25 ± 0.05 | 3.47 ± 0.05* | 3.59 ± 0.08** | 3.87 ± 0.08**
R. Kidney
Absolute | 0.73 ± 0.02 | 0.74 ± 0.01 | 0.76 ± 0.02 | 0.72 ± 0.01
Relative | 3.19 ± 0.07 | 3.47 ± 0.07** | 3.49 ± 0.08** | 3.76 ± 0.05**
Liver
Absolute | 8.12 ± 0.21 | 7.88 ± 0.19 | 8.83 ± 0.19* | 7.65 ± 0.20
Relative | 35.28 ± 0.80 | 37.10 ± 0.65 | 40.71 ± 0.76** | 39.72 ± 0.77**

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table H-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt. | 26.2 ± 0.4 | 26.4 ± 0.5 | 25.9 ± 0.3 | 25.9 ± 0.9 | 26.9 ± 0.7 | 26.2 ± 0.5
Heart
Absolute | 0.13 ± 0.01 | 0.12 ± 0.00 | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.01
Relative | 4.880 ± 0.183 | 4.470 ± 0.122 | 4.935 ± 0.132 | 4.898 ± 0.269 | 4.620 ± 0.124 | 4.422 ± 0.140
R. Kidney
Absolute | 0.26 ± 0.00 | 0.26 ± 0.01 | 0.26 ± 0.01 | 0.27 ± 0.01 | 0.25 ± 0.01 | 0.26 ± 0.00
Relative | 9.920 ± 0.169 | 9.979 ± 0.134 | 10.101 ± 0.260 | 10.442 ± 0.179 | 9.374 ± 0.239 | 9.858 ± 0.187
Liver
Absolute | 1.39 ± 0.05 | 1.40 ± 0.04 | 1.35 ± 0.05 | 1.42 ± 0.06 | 1.53 ± 0.06 | 1.57 ± 0.06
Relative | 52.920 ± 0.942 | 52.796 ± 1.057 | 52.013 ± 1.697 | 54.681 ± 1.497 | 56.745 ± 0.857 | 59.683 ± 1.246**
Lung
Absolute | 0.16 ± 0.00 | 0.15 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.15 ± 0.00
Relative | 6.101 ± 0.119 | 5.830 ± 0.207 | 6.013 ± 0.179 | 6.265 ± 0.253 | 5.810 ± 0.140 | 5.875 ± 0.059
R. Testis
Absolute | 0.104 ± 0.001 | 0.105 ± 0.004 | 0.104 ± 0.001 | 0.109 ± 0.004 | 0.099 ± 0.004 | 0.095 ± 0.003
Relative | 3.983 ± 0.064 | 3.977 ± 0.104 | 4.011 ± 0.065 | 4.217 ± 0.115 | 3.698 ± 0.081 | 3.638 ± 0.139
Thymus
Absolute | 0.042 ± 0.003 | 0.048 ± 0.002 | 0.041 ± 0.002 | 0.040 ± 0.003 | 0.042 ± 0.005 | 0.039 ± 0.002
Relative | 1.624 ± 0.149 | 1.808 ± 0.071 | 1.584 ± 0.086 | 1.558 ± 0.076 | 1.555 ± 0.155 | 1.502 ± 0.087
Female
Necropsy body wt. | 21.5 ± 0.4 | 21.9 ± 0.4 | 20.9 ± 0.5 | 21.3 ± 0.4 | 21.3 ± 0.2 | 21.3 ± 0.2
Heart
Absolute | 0.11 ± 0.00 | 0.11 ± 0.00 | 0.10 ± 0.00 | 0.11 ± 0.00 | 0.11 ± 0.01 | 0.10 ± 0.00
Relative | 5.109 ± 0.139 | 4.852 ± 0.121 | 4.883 ± 0.112 | 5.176 ± 0.197 | 5.067 ± 0.202 | 4.874 ± 0.187
R. Kidney
Absolute | 0.17 ± 0.00 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.00 | 0.17 ± 0.00
Relative | 7.898 ± 0.155 | 7.500 ± 0.174 | 7.748 ± 0.222 | 7.807 ± 0.360 | 7.605 ± 0.154 | 7.784 ± 0.225
Liver
Absolute | 1.02 ± 0.02 | 1.00 ± 0.04 | 0.95 ± 0.03 | 0.99 ± 0.03 | 1.06 ± 0.03 | 1.09 ± 0.02
Relative | 47.533 ± 0.370 | 45.523 ± 1.275 | 45.580 ± 0.585 | 46.354 ± 0.517 | 49.754 ± 1.180 | 50.964 ± 0.694*
Lung
Absolute | 0.16 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.01
Relative | 7.344 ± 0.340 | 6.956 ± 0.258 | 6.982 ± 0.261 | 7.171 ± 0.450 | 6.944 ± 0.239 | 6.938 ± 0.286
Thymus
Absolute | 0.055 ± 0.005 | 0.064 ± 0.003 | 0.059 ± 0.004 | 0.057 ± 0.004 | 0.063 ± 0.002 | 0.062 ± 0.003
Relative | 2.558 ± 0.257 | 2.944 ± 0.103 | 2.810 ± 0.161 | 2.685 ± 0.189 | 2.959 ± 0.107 | 2.898 ± 0.127

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table H-5 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 39.3 ± 1.0 | 40.0 ± 0.6 | 39.6 ± 0.8 | 40.1 ± 1.0 | 39.8 ± 0.8 | 36.8 ± 0.7
Heart
Absolute | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.15 ± 0.01
Relative | 3.94 ± 0.07 | 4.01 ± 0.14 | 4.03 ± 0.19 | 4.00 ± 0.18 | 4.00 ± 0.09 | 4.16 ± 0.15
R. Kidney
Absolute | 0.29 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.29 ± 0.01 | 0.27 ± 0.00 | 0.26 ± 0.00**
Relative | 7.28 ± 0.07 | 7.01 ± 0.11 | 7.08 ± 0.16 | 7.12 ± 0.19 | 6.88 ± 0.15 | 7.10 ± 0.14
Liver
Absolute | 1.53 ± 0.07 | 1.61 ± 0.07 | 1.61 ± 0.06 | 1.68 ± 0.03 | 1.79 ± 0.05** | 1.74 ± 0.03**
Relative | 38.60 ± 1.04 | 40.28 ± 1.41 | 40.75 ± 1.01 | 42.07 ± 1.15* | 45.05 ± 0.98** | 47.41 ± 1.16**
Lung
Absolute | 0.28 ± 0.01 | 0.29 ± 0.01 | 0.27 ± 0.01 | 0.29 ± 0.02 | 0.27 ± 0.01 | 0.27 ± 0.01
Relative | 7.07 ± 0.34 | 7.30 ± 0.25 | 6.92 ± 0.19 | 7.18 ± 0.49 | 6.74 ± 0.33 | 7.46 ± 0.30
R. Testis
Absolute | 0.123 ± 0.002 | 0.123 ± 0.002 | 0.119 ± 0.002 | 0.128 ± 0.003 | 0.124 ± 0.002 | 0.120 ± 0.002
Relative | 3.137 ± 0.068 | 3.081 ± 0.081 | 3.022 ± 0.079 | 3.209 ± 0.121 | 3.119 ± 0.068 | 3.256 ± 0.082
Thymus
Absolute | 0.038 ± 0.002 | 0.040 ± 0.001 | 0.037 ± 0.002 | 0.038 ± 0.002 | 0.041 ± 0.002 | 0.040 ± 0.002
Relative | 0.971 ± 0.039 | 0.999 ± 0.023 | 0.934 ± 0.065 | 0.946 ± 0.044 | 1.026 ± 0.028 | 1.096 ± 0.064
Female
Necropsy body wt. | 33.8 ± 0.6 | 32.8 ± 1.3 | 35.4 ± 0.7 | 32.6 ± 0.7 | 33.2 ± 0.9 | 30.7 ± 0.7
Heart
Absolute | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.00
Relative | 3.83 ± 0.11 | 4.07 ± 0.16 | 3.50 ± 0.12 | 3.88 ± 0.10 | 3.76 ± 0.12 | 4.01 ± 0.10
R. Kidney
Absolute | 0.18 ± 0.00 | 0.19 ± 0.01 | 0.18 ± 0.00 | 0.18 ± 0.01 | 0.18 ± 0.00 | 0.18 ± 0.00
Relative | 5.37 ± 0.09 | 5.77 ± 0.16 | 5.16 ± 0.13 | 5.57 ± 0.13 | 5.39 ± 0.17 | 6.00 ± 0.07**
Liver
Absolute | 1.32 ± 0.04 | 1.29 ± 0.05 | 1.38 ± 0.02 | 1.28 ± 0.05 | 1.31 ± 0.03 | 1.29 ± 0.05
Relative | 39.08 ± 0.79 | 39.43 ± 1.45 | 39.14 ± 0.95 | 39.29 ± 0.72 | 39.52 ± 1.03 | 41.78 ± 0.78
Lung
Absolute | 0.21 ± 0.02 | 0.19 ± 0.01 | 0.19 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.01
Relative | 6.22 ± 0.42 | 5.91 ± 0.43 | 5.41 ± 0.31 | 5.85 ± 0.36 | 5.55 ± 0.42 | 5.88 ± 0.23
Thymus
Absolute | 0.044 ± 0.002 | 0.048 ± 0.003 | 0.048 ± 0.003 | 0.044 ± 0.002 | 0.044 ± 0.002 | 0.047 ± 0.002
Relative | 1.319 ± 0.058 | 1.455 ± 0.066 | 1.345 ± 0.072 | 1.358 ± 0.058 | 1.337 ± 0.052 | 1.540 ± 0.064

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table H-6 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice at the Six-month Interim Evaluation in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 8 | 8 | 8 | 8
Male
Necropsy body wt. | 50.9 ± 0.9 | 50.4 ± 1.0 | 49.5 ± 1.1 | 49.5 ± 0.5
L. Kidney
Absolute | 0.405 ± 0.013 | 0.418 ± 0.011 | 0.373 ± 0.011 | 0.354 ± 0.011**
Relative | 7.96 ± 0.21 | 8.29 ± 0.13 | 7.52 ± 0.16 | 7.16 ± 0.23**
R. Kidney
Absolute | 0.43 ± 0.01 | 0.45 ± 0.02 | 0.40 ± 0.01 | 0.37 ± 0.01**
Relative | 8.42 ± 0.11 | 8.97 ± 0.15 | 8.09 ± 0.15 | 7.47 ± 0.14**
Liver
Absolute | 3.19 ± 0.22 | 3.06 ± 0.20 | 2.86 ± 0.15 | 2.95 ± 0.09
Relative | 62.29 ± 3.10 | 60.46 ± 2.59 | 57.49 ± 2.06 | 59.50 ± 1.43
Female
Necropsy body wt. | 50.4 ± 1.1 | 47.0 ± 1.7 | 44.9 ± 1.3* | 43.6 ± 2.0**
L. Kidney
Absolute | 0.210 ± 0.005 | 0.209 ± 0.008 | 0.205 ± 0.005 | 0.195 ± 0.005
Relative | 4.19 ± 0.10 | 4.47 ± 0.14 | 4.60 ± 0.19 | 4.52 ± 0.15
R. Kidney
Absolute | 0.22 ± 0.01 | 0.23 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.01
Relative | 4.37 ± 0.10 | 4.81 ± 0.15 | 4.81 ± 0.17 | 4.99 ± 0.17**
Liver
Absolute | 1.79 ± 0.06 | 1.70 ± 0.12 | 1.65 ± 0.05 | 1.83 ± 0.08
Relative | 35.59 ± 0.80 | 35.95 ± 1.62 | 36.77 ± 0.80 | 42.05 ± 1.25**

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).