# Appendix G Hepatic Acetyl-CoA Hydrolase Activity

## G.1 Introduction

Activation of PPARα is one of the hypotheses of the mechanism of hepatic carcinogenicity of haloacetic acids. Hepatic acetyl-CoA hydrolase activity is inducible by PPARα activators.^97^ To evaluate the role of PPAR in the potential hepatocarcinogenicity of bromodichloroacetic acid, hepatic acetyl-CoA hydrolase activity was evaluated at the end of the 2-week studies.

## G.2 Results

No increases in acetyl-CoA hydrolase activities were observed in either male or female rats, although there were exposure concentration-dependent decreases in acetyl-CoA hydrolase activities in both males and females (Table G-1). Significantly decreased acetyl-CoA hydrolase activities occurred in male mice exposed to 125, 250, or 500 mg/L, and significantly increased activities occurred in females exposed to 125 or 500 mg/L (Table G-2). These data suggest that bromodichloroacetic acid generally does not activate PPARα, and these assays were not performed in the 3-month and 2-year studies.

Table G-1 Hepatic Acetyl-CoA Hydrolase Activity in F344/N Rats in the Two-week Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Acetyl-CoA hydrolase (nmol/mg protein per minute) | 52.1 ± 4.3 | 40.0 ± 2.1 | 37.2 ± 2.3 | 33.5 ± 2.1** | 33.3 ± 2.1** | 47.0 ± 4.5
Female
Acetyl-CoA hydrolase (nmol/mg protein per minute) | 29.2 ± 2.5 | 27.5 ± 1.0 | 32.7 ± 1.3 | 27.7 ± 2.4 | 21.0 ± 1.8* | 14.0 ± 1.1**

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error.

Table G-2 Hepatic Acetyl-CoA Hydrolase Activity in Mice in the Two-week Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Acetyl-CoA hydrolase (nmol/mg protein per minute) | 23.2 ± 2.1 | 18.2 ± 1.5 | 7.5 ± 0.7** | 8.7 ± 1.1* | 7.8 ± 1.2** | 16.5 ± 1.5
Female
Acetyl-CoA hydrolase (nmol/mg protein per minute) | 5.5 ± 0.4 | 5.4 ± 0.9 | 15.7 ± 1.6** | 9.7 ± 0.8 | 11.5 ± 0.7* | 6.5 ± 0.8

* Significantly different (P ≤ 0.05) from the control group by Dunn’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error.