# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for F344/N Rats in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Hematology
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 21 | 9 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
Day 3 | 46.5 ± 1.1 | 45.5 ± 0.6 | 44.3 ± 0.7 | 45.2 ± 0.4 | 46.2 ± 0.5 | 45.8 ± 0.8
Day 21 | 46.8 ± 0.5 | 45.9 ± 0.6 | 45.7 ± 0.5 | 46.3 ± 0.6 | 48.3 ± 0.7 | 46.3 ± 0.5
Week 14 | 44.9 ± 0.5 | 45.2 ± 0.6 | 44.8 ± 0.5 | 44.6 ± 0.4 | 44.2 ± 0.5 | 44.7 ± 0.5
Hematocrit (spun) (%)
Day 3 | 45.4 ± 1.0 | 44.2 ± 0.6 | 43.3 ± 0.6 | 43.7 ± 0.4 | 45.2 ± 0.6 | 45.0 ± 0.7
Day 21 | 47.3 ± 0.5 | 45.6 ± 0.6 | 45.7 ± 0.2 | 46.3 ± 0.6 | 48.5 ± 0.7 | 45.9 ± 0.5
Week 14 | 45.4 ± 0.4 | 45.5 ± 0.5 | 44.7 ± 0.5 | 45.0 ± 0.5 | 44.6 ± 0.4 | 44.7 ± 0.5
Hemoglobin (g/dL)
Day 3 | 15.4 ± 0.3 | 15.1 ± 0.2 | 14.8 ± 0.2 | 15.0 ± 0.2 | 15.4 ± 0.2 | 15.2 ± 0.2
Day 21 | 14.8 ± 0.2 | 14.6 ± 0.2 | 14.6 ± 0.1 | 14.8 ± 0.2 | 15.5 ± 0.3 | 14.8 ± 0.1
Week 14 | 15.3 ± 0.1 | 15.2 ± 0.2 | 15.1 ± 0.1 | 15.0 ± 0.1 | 15.1 ± 0.2 | 15.1 ± 0.2
Erythrocytes (10^6^/µL)
Day 3 | 7.77 ± 0.18 | 7.52 ± 0.10 | 7.41 ± 0.12 | 7.51 ± 0.06 | 7.69 ± 0.10 | 7.70 ± 0.12
Day 21 | 7.87 ± 0.12 | 7.65 ± 0.11 | 7.69 ± 0.12 | 7.71 ± 0.12 | 8.17 ± 0.16 | 7.83 ± 0.09
Week 14 | 9.00 ± 0.08 | 9.06 ± 0.11 | 9.03 ± 0.10 | 8.90 ± 0.07 | 8.87 ± 0.10 | 9.00 ± 0.08
Reticulocytes (10^5^/µL)
Day 3 | 6.9 ± 0.2 | 7.1 ± 0.2 | 6.7 ± 0.2 | 6.8 ± 0.2 | 6.4 ± 0.2 | 6.8 ± 0.2
Day 21 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.1 ± 0.1 | 4.1 ± 0.1 | 3.7 ± 0.1 | 4.0 ± 0.1
Week 14 | 3.0 ± 0.1 | 3.0 ± 0.1 | 3.0 ± 0.1 | 3.0 ± 0.1 | 2.8 ± 0.1 | 2.8 ± 0.1
Nucleated erythrocytes/100 leukocytes
Day 3 | 1.7 ± 0.5 | 1.3 ± 0.4 | 1.2 ± 0.4 | 0.5 ± 0.3 | 0.6 ± 0.2 | 2.2 ± 0.5
Day 21 | 0.1 ± 0.1 | 0.2 ± 0.1 | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.1 ± 0.1 | 0.1 ± 0.1
Week 14 | 0.1 ± 0.1 | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.2 ± 0.1 | 0.0 ± 0.0 | 0.0 ± 0.0
Mean cell volume (fL)
Day 3 | 59.8 ± 0.3 | 60.6 ± 0.3 | 59.9 ± 0.3 | 60.2 ± 0.3 | 60.2 ± 0.4 | 59.5 ± 0.2
Day 21 | 59.6 ± 0.5 | 60.0 ± 0.4 | 59.5 ± 0.4 | 60.1 ± 0.3 | 59.2 ± 0.4 | 59.1 ± 0.3
Week 14 | 49.8 ± 0.2 | 49.9 ± 0.1 | 49.5 ± 0.2 | 50.1 ± 0.2 | 49.8 ± 0.2 | 49.6 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 19.8 ± 0.2 | 20.0 ± 0.1 | 20.0 ± 0.2 | 20.0 ± 0.2 | 20.1 ± 0.1 | 19.7 ± 0.1
Day 21 | 18.8 ± 0.1 | 19.0 ± 0.1 | 19.0 ± 0.2 | 19.2 ± 0.2 | 19.0 ± 0.1 | 18.9 ± 0.1
Week 14 | 17.0 ± 0.1 | 16.8 ± 0.1 | 16.7 ± 0.1 | 16.8 ± 0.1 | 17.0 ± 0.1 | 16.8 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 33.1 ± 0.2 | 33.1 ± 0.2 | 33.4 ± 0.3 | 33.2 ± 0.2 | 33.4 ± 0.2 | 33.2 ± 0.2
Day 21 | 31.7 ± 0.2 | 31.7 ± 0.1 | 31.9 ± 0.2 | 31.9 ± 0.2 | 32.1 ± 0.2 | 32.0 ± 0.2
Week 14 | 34.0 ± 0.2 | 33.7 ± 0.2 | 33.7 ± 0.2 | 33.6 ± 0.2 | 34.1 ± 0.2 | 33.8 ± 0.1
Platelets (10^3^/µL)
Day 3 | 833 ± 22 | 859 ± 15 | 877 ± 20 | 836 ± 27 | 794 ± 30 | 839 ± 14
Day 21 | 666 ± 14 | 717 ± 14* | 721 ± 20 | 694 ± 14 | 691 ± 12 | 716 ± 6*
Week 14 | 574 ± 13 | 600 ± 18 | 590 ± 42 | 616 ± 13 | 609 ± 12 | 614 ± 13
Leukocytes (10^3^/µL)
Day 3 | 9.96 ± 0.33 | 10.09 ± 0.38 | 9.22 ± 0.25 | 9.90 ± 0.38 | 10.69 ± 0.22 | 9.78 ± 0.26
Day 21 | 11.22 ± 0.36 | 10.24 ± 0.30 | 10.81 ± 0.51 | 10.77 ± 0.44 | 12.23 ± 0.64 | 10.89 ± 0.29
Week 14 | 10.34 ± 0.76 | 10.34 ± 0.79 | 10.38 ± 0.66 | 10.37 ± 0.67 | 10.74 ± 0.40 | 9.79 ± 0.42
Segmented neutrophils (10^3^/µL)
Day 3 | 1.05 ± 0.06 | 1.04 ± 0.05 | 0.94 ± 0.03 | 1.00 ± 0.04 | 1.06 ± 0.04 | 1.01 ± 0.03
Day 21 | 1.02 ± 0.05 | 1.02 ± 0.06 | 1.10 ± 0.03 | 0.99 ± 0.03 | 1.14 ± 0.06 | 1.00 ± 0.04
Week 14 | 1.31 ± 0.08 | 1.41 ± 0.09 | 1.71 ± 0.12* | 1.35 ± 0.05 | 1.48 ± 0.09 | 1.55 ± 0.08
Lymphocytes (10^3/^µL)
Day 3 | 8.21 ± 0.28 | 8.27 ± 0.30 | 7.55 ± 0.21 | 8.11 ± 0.32 | 8.88 ± 0.21 | 8.09 ± 0.24
Day 21 | 9.34 ± 0.29 | 8.31 ± 0.21 | 8.82 ± 0.43 | 8.86 ± 0.39 | 10.23 ± 0.57 | 9.06 ± 0.22
Week 14 | 7.85 ± 0.61 | 7.79 ± 0.60 | 7.51 ± 0.46 | 7.96 ± 0.59 | 8.02 ± 0.34 | 7.13 ± 0.39
Monocytes (10^3^/µL)
Day 3 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.01
Day 21 | 0.15 ± 0.01 | 0.16 ± 0.02 | 0.19 ± 0.01 | 0.16 ± 0.01 | 0.14 ± 0.01 | 0.13 ± 0.01
Week 14 | 0.13 ± 0.01 | 0.14 ± 0.02 | 0.14 ± 0.02 | 0.13 ± 0.01 | 0.14 ± 0.01 | 0.12 ± 0.01
Basophils (10^3^/µL)
Day 3 | 0.056 ± 0.006 | 0.071 ± 0.012 | 0.076 ± 0.013 | 0.073 ± 0.008 | 0.070 ± 0.008 | 0.055 ± 0.007
Day 21 | 0.056 ± 0.004 | 0.057 ± 0.009 | 0.055 ± 0.004 | 0.056 ± 0.006 | 0.063 ± 0.007 | 0.060 ± 0.004
Week 14 | 0.097 ± 0.012 | 0.083 ± 0.016 | 0.082 ± 0.009 | 0.083 ± 0.014 | 0.099 ± 0.014 | 0.087 ± 0.013
Eosinophils (10^3^/µL)
Day 3 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.01
Day 21 | 0.04 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.04 ± 0.00 | 0.03 ± 0.00
Week 14 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01
Large unstained cells (10^3^/µL)
Day 3 | 0.460 ± 0.022 | 0.516 ± 0.059 | 0.460 ± 0.045 | 0.521 ± 0.045 | 0.481 ± 0.030 | 0.432 ± 0.037
Day 21 | 0.618 ± 0.057 | 0.662 ± 0.089 | 0.622 ± 0.058 | 0.661 ± 0.046 | 0.616 ± 0.044 | 0.602 ± 0.027
Week 14 | 0.874 ± 0.133 | 0.842 ± 0.124 | 0.847 ± 0.084 | 0.769 ± 0.070 | 0.909 ± 0.070 | 0.823 ± 0.063
Clinical Chemistry
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 21 | 9 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 12.2 ± 0.4 | 12.4 ± 0.3 | 12.8 ± 0.3 | 11.8 ± 0.5 | 12.2 ± 0.5 | 13.5 ± 0.5
Day 21 | 17.1 ± 1.2 | 13.6 ± 0.5 | 13.2 ± 0.4* | 14.4 ± 0.3 | 18.7 ± 1.6 | 15.9 ± 0.8
Week 14 | 14.0 ± 0.6 | 14.0 ± 0.7 | 13.8 ± 0.4 | 13.6 ± 0.5 | 13.7 ± 0.4 | 13.6 ± 0.4
Creatinine (mg/dL)
Day 3 | 0.52 ± 0.01 | 0.53 ± 0.02 | 0.50 ± 0.00 | 0.50 ± 0.00 | 0.49 ± 0.01 | 0.51 ± 0.01
Day 21 | 0.56 ± 0.02 | 0.58 ± 0.01 | 0.59 ± 0.01 | 0.58 ± 0.01 | 0.60 ± 0.01 | 0.57 ± 0.02
Week 14 | 0.73 ± 0.03 | 0.72 ± 0.01 | 0.70 ± 0.02 | 0.69 ± 0.03 | 0.68 ± 0.02 | 0.69 ± 0.02
Total protein (g/dL)
Day 3 | 5.9 ± 0.1 | 5.8 ± 0.1 | 5.7 ± 0.1 | 5.8 ± 0.1 | 5.9 ± 0.0 | 5.8 ± 0.1
Day 21 | 6.7 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.1 | 6.8 ± 0.1 | 6.7 ± 0.1 | 6.5 ± 0.1
Week 14 | 6.9 ± 0.1 | 6.8 ± 0.1 | 6.8 ± 0.1 | 6.7 ± 0.1 | 6.7 ± 0.1 | 6.7 ± 0.1
Albumin (g/dL)
Day 3 | 4.0 ± 0.0 | 4.0 ± 0.0 | 3.9 ± 0.0 | 3.9 ± 0.1 | 4.0 ± 0.0 | 4.0 ± 0.0
Day 21 | 4.3 ± 0.0 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.3 ± 0.0 | 4.4 ± 0.1 | 4.3 ± 0.0
Week 14 | 4.3 ± 0.0 | 4.4 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0
Alanine aminotransferase (IU/L)
Day 3 | 61 ± 2 | 65 ± 3 | 60 ± 2 | 62 ± 2 | 63 ± 2 | 66 ± 1
Day 21 | 43 ± 6 | 43 ± 5 | 47 ± 3 | 45 ± 4 | 52 ± 5 | 51 ± 2
Week 14 | 78 ± 4^b^ | 70 ± 3 | 62 ± 3** | 62 ± 3** | 65 ± 4** | 60 ± 3**
Alkaline phosphatase (IU/L)
Day 3 | 728 ± 21 | 687 ± 14 | 679 ± 11 | 692 ± 16 | 668 ± 27 | 698 ± 23
Day 21 | 417 ± 22 | 446 ± 7 | 437 ± 11 | 432 ± 8 | 378 ± 23 | 440 ± 15
Week 14 | 187 ± 6^b^ | 199 ± 7 | 183 ± 6 | 187 ± 6 | 182 ± 7 | 189 ± 5
Creatine kinase (IU/L)
Day 3 | 437 ± 43 | 401 ± 35 | 435 ± 37 | 413 ± 36 | 432 ± 36 | 469 ± 51
Day 21 | 398 ± 33 | 362 ± 28 | 400 ± 69 | 317 ± 18 | 365 ± 34 | 334 ± 29
Week 14 | 291 ± 64^b^ | 367 ± 74 | 626 ± 213 | 288 ± 36 | 258 ± 38 | 562 ± 203
Sorbitol dehydrogenase (IU/L)
Day 3 | 20 ± 1 | 20 ± 1 | 19 ± 1 | 18 ± 1 | 20 ± 1 | 18 ± 1
Day 21 | 32 ± 1 | 31 ± 1 | 32 ± 2 | 31 ± 1 | 29 ± 1 | 28 ± 1*
Week 14 | 37 ± 3c | 31 ± 1 | 32 ± 2^b^ | 32 ± 3 | 30 ± 2 | 27 ± 2**
Bile acids (µmol/L)
Day 3 | 23.3 ± 2.3 | 21.7 ± 1.4 | 22.0 ± 1.3 | 23.9 ± 1.8 | 23.1 ± 1.4 | 27.3 ± 1.6
Day 21 | 31.6 ± 3.2 | 34.3 ± 3.2 | 28.7 ± 4.0 | 31.8 ± 4.2 | 28.7 ± 3.5 | 34.9 ± 2.7
Week 14 | 25.6 ± 5.6^b^ | 24.6 ± 2.4 | 25.6 ± 4.0 | 24.6 ± 2.8 | 18.8 ± 2.5 | 19.7 ± 2.5
Female
Hematology
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 21 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 9 | 9 | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
Day 3 | 44.6 ± 0.5 | 45.5 ± 0.5 | 46.5 ± 0.7 | 45.5 ± 0.8 | 46.0 ± 0.5 | 49.2 ± 1.5*
Day 21 | 48.1 ± 0.4 | 49.0 ± 0.6 | 48.6 ± 0.4 | 49.4 ± 0.5 | 48.0 ± 0.3 | 47.8 ± 0.4
Week 14 | 45.0 ± 0.6 | 45.3 ± 0.5 | 46.0 ± 0.3 | 45.9 ± 0.4 | 45.1 ± 0.3 | 45.0 ± 0.5
Hematocrit (spun) (%)
Day 3 | 44.0 ± 0.6 | 44.8 ± 0.6 | 45.6 ± 0.6 | 44.3 ± 0.8 | 45.1 ± 0.3 | 47.7 ± 1.3
Day 21 | 47.2 ± 0.5 | 48.5 ± 0.7 | 48.0 ± 0.5 | 48.6 ± 0.5 | 47.5 ± 0.3 | 47.5 ± 0.5
Week 14 | 43.8 ± 0.6 | 44.6 ± 0.6 | 45.6 ± 0.3 | 45.1 ± 0.3 | 43.9 ± 0.4 | 44.3 ± 0.4
Hemoglobin (g/dL)
Day 3 | 14.6 ± 0.1 | 15.0 ± 0.1 | 15.3 ± 0.2 | 15.0 ± 0.3 | 15.2 ± 0.1* | 16.2 ± 0.4**
Day 21 | 15.8 ± 0.1 | 16.4 ± 0.2 | 16.1 ± 0.1 | 16.4 ± 0.2 | 15.9 ± 0.1 | 16.0 ± 0.2
Week 14 | 14.8 ± 0.2 | 14.7 ± 0.1 | 15.0 ± 0.1 | 15.0 ± 0.1 | 14.8 ± 0.1 | 14.7 ± 0.1
Erythrocytes (10^6^/µL)
Day 3 | 7.48 ± 0.07 | 7.59 ± 0.06 | 7.78 ± 0.10 | 7.64 ± 0.14 | 7.71 ± 0.08 | 8.22 ± 0.22**
Day 21 | 8.18 ± 0.07 | 8.40 ± 0.13 | 8.31 ± 0.09 | 8.44 ± 0.11 | 8.22 ± 0.05 | 8.17 ± 0.07
Week 14 | 8.42 ± 0.11 | 8.41 ± 0.11 | 8.54 ± 0.07 | 8.55 ± 0.07 | 8.41 ± 0.05 | 8.40 ± 0.08
Reticulocytes (10^5^/µL)
Day 3 | 5.5 ± 0.2 | 5.0 ± 0.2 | 5.5 ± 0.2 | 5.0 ± 0.1 | 4.9 ± 0.2 | 5.5 ± 0.2
Day 21 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.6 ± 0.1 | 2.9 ± 0.1**
Week 14 | 2.3 ± 0.0 | 2.1 ± 0.1 | 2.4 ± 0.1 | 2.2 ± 0.1 | 2.2 ± 0.1 | 2.4 ± 0.1
Nucleated erythrocytes/100 leukocytes
Day 3 | 0.5 ± 0.2 | 0.7 ± 0.3 | 0.1 ± 0.1 | 0.2 ± 0.1 | 0.3 ± 0.2 | 0.0 ± 0.0
Day 21 | 0.3 ± 0.2 | 0.1 ± 0.1 | 0.1 ± 0.1 | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.1 ± 0.1
Week 14 | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.1 ± 0.1 | 0.3 ± 0.2 | 0.0 ± 0.0 | 0.0 ± 0.0
Mean cell volume (fL)
Day 3 | 59.6 ± 0.4 | 59.9 ± 0.3 | 59.7 ± 0.3 | 59.6 ± 0.3 | 59.6 ± 0.3 | 59.9 ± 0.3
Day 21 | 58.8 ± 0.3 | 58.4 ± 0.5 | 58.5 ± 0.3 | 58.6 ± 0.3 | 58.5 ± 0.2 | 58.5 ± 0.3
Week 14 | 53.5 ± 0.1 | 53.8 ± 0.2 | 53.9 ± 0.2 | 53.7 ± 0.2 | 53.7 ± 0.1 | 53.6 ± 0.1
Mean cell hemoglobin (pg)
Day 3 | 19.6 ± 0.1 | 19.8 ± 0.1 | 19.7 ± 0.1 | 19.6 ± 0.1 | 19.7 ± 0.1 | 19.6 ± 0.1
Day 21 | 19.4 ± 0.1 | 19.5 ± 0.1 | 19.4 ± 0.1 | 19.5 ± 0.2 | 19.3 ± 0.1 | 19.5 ± 0.1
Week 14 | 17.6 ± 0.1 | 17.5 ± 0.1 | 17.6 ± 0.1 | 17.5 ± 0.1 | 17.6 ± 0.1 | 17.4 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 32.9 ± 0.2 | 33.0 ± 0.2 | 32.9 ± 0.2 | 32.9 ± 0.1 | 33.0 ± 0.1 | 32.8 ± 0.2
Day 21 | 32.9 ± 0.1 | 33.4 ± 0.2 | 33.1 ± 0.1 | 33.2 ± 0.2 | 33.0 ± 0.1 | 33.4 ± 0.2
Week 14 | 32.8 ± 0.3 | 32.5 ± 0.2 | 32.5 ± 0.3 | 32.6 ± 0.2 | 32.9 ± 0.3 | 32.6 ± 0.2
Platelets (10^3^/µL)
Day 3 | 846 ± 20 | 868 ± 17 | 857 ± 12 | 892 ± 20 | 897 ± 23 | 867 ± 25
Day 21 | 710 ± 12 | 727 ± 21 | 727 ± 19 | 736 ± 22 | 777 ± 7** | 763 ± 23*
Week 14 | 551 ± 23 | 589 ± 9 | 582 ± 24 | 637 ± 16** | 659 ± 15** | 680 ± 14**
Leukocytes (10^3^/µL)
Day 3 | 10.15 ± 0.49 | 9.97 ± 0.37 | 10.72 ± 0.36 | 10.85 ± 0.37 | 10.40 ± 0.53 | 11.33 ± 0.48
Day 21 | 11.11 ± 0.37 | 10.29 ± 0.42 | 10.71 ± 0.40 | 10.22 ± 0.39 | 9.81 ± 0.23 | 10.44 ± 0.46
Week 14 | 7.35 ± 0.45 | 8.91 ± 0.46 | 8.29 ± 0.80 | 9.34 ± 0.79 | 9.21 ± 0.61 | 9.25 ± 0.68
Segmented neutrophils (10^3^/µL)
Day 3 | 1.12 ± 0.06 | 0.86 ± 0.05* | 0.92 ± 0.04 | 0.96 ± 0.05 | 0.89 ± 0.05* | 0.91 ± 0.05*
Day 21 | 1.04 ± 0.07 | 0.89 ± 0.05 | 0.94 ± 0.05 | 0.94 ± 0.09 | 0.84 ± 0.04 | 0.99 ± 0.06
Week 14 | 1.04 ± 0.08 | 1.59 ± 0.10** | 1.38 ± 0.14 | 1.38 ± 0.09 | 1.29 ± 0.12 | 1.62 ± 0.17*
Lymphocytes (10^3^/µL)
Day 3 | 8.32 ± 0.41 | 8.41 ± 0.31 | 9.02 ± 0.32 | 9.14 ± 0.37 | 8.81 ± 0.48 | 9.61 ± 0.40
Day 21 | 9.32 ± 0.3 | 8.73 ± 0.38 | 8.90 ± 0.36 | 8.46 ± 0.30 | 8.25 ± 0.23 | 8.79 ± 0.41
Week 14 | 5.46 ± 0.34 | 6.08 ± 0.34 | 5.89 ± 0.61 | 6.88 ± 0.62 | 6.82 ± 0.38 | 6.55 ± 0.44
Monocytes (10^3^/µL)
Day 3 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.02 | 0.20 ± 0.02
Day 21 | 0.16 ± 0.02 | 0.14 ± 0.02 | 0.19 ± 0.04 | 0.15 ± 0.01 | 0.13 ± 0.01 | 0.12 ± 0.01
Week 14 | 0.11 ± 0.02 | 0.18 ± 0.02 | 0.14 ± 0.02 | 0.12 ± 0.01 | 0.13 ± 0.02 | 0.14 ± 0.02
Basophils (10^3^/µL)
Day 3 | 0.065 ± 0.010 | 0.059 ± 0.007 | 0.070 ± 0.008 | 0.072 ± 0.006 | 0.061 ± 0.008 | 0.075 ± 0.007
Day 21 | 0.053 ± 0.004 | 0.044 ± 0.004 | 0.054 ± 0.004 | 0.055 ± 0.007 | 0.044 ± 0.003 | 0.047 ± 0.003
Week 14 | 0.054 ± 0.009 | 0.080 ± 0.011 | 0.063 ± 0.013 | 0.079 ± 0.011 | 0.076 ± 0.017 | 0.077 ± 0.016
Eosinophils (10^3^/µL)
Day 3 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.05 ± 0.00 | 0.05 ± 0.01 | 0.05 ± 0.00
Day 21 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.05 ± 0.00
Week 14 | 0.05 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01
Large unstained cells (10^3^/µL)
Day 3 | 0.437 ± 0.037 | 0.441 ± 0.035 | 0.494 ± 0.048 | 0.470 ± 0.032 | 0.426 ± 0.028 | 0.479 ± 0.039
Day 21 | 0.500 ± 0.040 | 0.438 ± 0.036 | 0.587 ± 0.054 | 0.569 ± 0.041 | 0.503 ± 0.031 | 0.445 ± 0.024
Week 14 | 0.629 ± 0.056 | 0.912 ± 0.087 | 0.747 ± 0.095 | 0.815 ± 0.109 | 0.830 ± 0.122 | 0.806 ± 0.113
Clinical Chemistry
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 21 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 9 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 11.0 ± 0.3 | 12.5 ± 0.5* | 12.3 ± 0.5* | 12.6 ± 0.4* | 12.8 ± 0.5** | 13.2 ± 0.5**
Day 21 | 14.6 ± 0.3 | 14.6 ± 0.3 | 15.2 ± 0.3 | 16.0 ± 0.4* | 15.8 ± 0.3* | 17.5 ± 0.6**
Week 14 | 12.6 ± 0.5 | 13.4 ± 0.8 | 13.6 ± 0.6 | 11.9 ± 0.5 | 12.9 ± 0.5 | 14.4 ± 0.5
Creatinine (mg/dL)
Day 3 | 0.45 ± 0.02 | 0.48 ± 0.01 | 0.50 ± 0.02 | 0.46 ± 0.02 | 0.47 ± 0.02 | 0.48 ± 0.01
Day 21 | 0.51 ± 0.01 | 0.50 ± 0.02 | 0.51 ± 0.01 | 0.49 ± 0.02 | 0.49 ± 0.01 | 0.49 ± 0.01
Week 14 | 0.63 ± 0.03 | 0.60 ± 0.03 | 0.60 ± 0.02 | 0.60 ± 0.01 | 0.60 ± 0.01 | 0.61 ± 0.01
Total protein (g/dL)
Day 3 | 6.1 ± 0.1 | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.1 ± 0.1 | 6.1 ± 0.1 | 6.3 ± 0.2
Day 21 | 6.3 ± 0.1 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.7 ± 0.2 | 6.4 ± 0.1 | 6.5 ± 0.1
Week 14 | 7.3 ± 0.2 | 7.0 ± 0.1 | 7.0 ± 0.1 | 7.0 ± 0.1 | 6.8 ± 0.1** | 6.6 ± 0.1**
Albumin (g/dL)
Day 3 | 4.1 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.3 ± 0.1
Day 21 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.4 ± 0.0 | 4.5 ± 0.1 | 4.4 ± 0.0 | 4.3 ± 0.0
Week 14 | 5.0 ± 0.1 | 4.7 ± 0.1* | 4.7 ± 0.1* | 4.7 ± 0.1* | 4.6 ± 0.1** | 4.5 ± 0.1**
Alanine aminotransferase (IU/L)
Day 3 | 53 ± 2 | 55 ± 1 | 56 ± 2 | 53 ± 2 | 53 ± 2 | 49 ± 2
Day 21 | 41 ± 4 | 38 ± 3^b^ | 38 ± 4 | 33 ± 4^b^ | 40 ± 4 | 37 ± 5^c^
Week 14 | 57 ± 4 | 77 ± 9 | 61 ± 5 | 45 ± 1* | 48 ± 4* | 47 ± 4*
Alkaline phosphatase (IU/L)
Day 3 | 517 ± 13 | 503 ± 11 | 513 ± 13 | 495 ± 11 | 490 ± 10 | 478 ± 7**
Day 21 | 328 ± 9 | 336 ± 13 | 335 ± 12 | 305 ± 9 | 300 ± 7 | 282 ± 12**
Week 14 | 143 ± 7 | 149 ± 8 | 147 ± 6 | 127 ± 5 | 130 ± 7 | 121 ± 9
Creatine kinase (IU/L)
Day 3 | 270 ± 11 | 228 ± 18 | 232 ± 13 | 228 ± 10 | 235 ± 21 | 276 ± 19
Day 21 | 262 ± 25 | 304 ± 34 | 326 ± 28 | 318 ± 28 | 342 ± 59 | 317 ± 33
Week 14 | 414 ± 88 | 322 ± 58 | 459 ± 90 | 285 ± 33 | 352 ± 95 | 272 ± 57
Sorbitol dehydrogenase (IU/L)
Day 3 | 18 ± 1 | 19 ± 0 | 18 ± 0 | 18 ± 0 | 18 ± 1 | 19 ± 1
Day 21 | 32 ± 2 | 32 ± 2 | 32 ± 3 | 33 ± 3 | 32 ± 2 | 35 ± 3
Week 14 | 23 ± 1 | 28 ± 3 | 24 ± 2 | 19 ± 1 | 20 ± 2 | 19 ± 1
Bile acids (µmol/L)
Day 3 | 13.9 ± 0.8 | 12.4 ± 0.7 | 15.3 ± 1.2 | 13.7 ± 1.0 | 14.0 ± 1.3 | 15.1 ± 1.2
Day 21 | 25.0 ± 1.6 | 29.3 ± 3.9 | 55.8 ± 25.7 | 32.7 ± 7.6^b^ | 24.7 ± 2.6 | 103.6 ± 50.8
Week 14 | 25.5 ± 3.4 | 32.8 ± 5.1 | 22.8 ± 2.2 | 23.7 ± 1.4 | 30.3 ± 3.2 | 25.9 ± 2.8

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

Table F-2 Hematology Data for Mice in the Three-month Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematocrit (auto) (%) | 49.5 ± 0.5 | 50.2 ± 0.6 | 49.3 ± 0.4 | 50.3 ± 0.4 | 48.8 ± 0.6 | 49.8 ± 0.7
Hematocrit (spun) (%) | 50.2 ± 0.6 | 50.8 ± 0.6 | 49.9 ± 0.4 | 50.6 ± 0.6 | 49.4 ± 0.5 | 50.3 ± 0.7
Hemoglobin (g/dL) | 16.6 ± 0.2 | 17.2 ± 0.3 | 16.6 ± 0.1 | 17.0 ± 0.2 | 16.5 ± 0.2 | 16.8 ± 0.2
Erythrocytes (10^6^/µL) | 11.10 ± 0.09 | 11.31 ± 0.14 | 11.08 ± 0.11 | 11.24 ± 0.08 | 10.79 ± 0.10 | 11.00 ± 0.14
Reticulocytes (10^5^/µL) | 4.0 ± 0.1 | 4.1 ± 0.1 | 3.9 ± 0.1 | 4.5 ± 0.6 | 4.1 ± 0.1 | 4.3 ± 0.1
Nucleated erythrocytes/100 leukocytes | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.1 ± 0.1
Mean cell volume (fL) | 44.6 ± 0.1 | 44.4 ± 0.2 | 44.5 ± 0.2 | 44.8 ± 0.2 | 45.2 ± 0.2 | 45.2 ± 0.2
Mean cell hemoglobin (pg) | 15.0 ± 0.1 | 15.2 ± 0.1 | 15.0 ± 0.1 | 15.1 ± 0.1 | 15.3 ± 0.1** | 15.3 ± 0.1**
Mean cell hemoglobin concentration (g/dL) | 33.5 ± 0.2 | 34.3 ± 0.2* | 33.7 ± 0.2 | 33.7 ± 0.2 | 33.9 ± 0.1 | 33.8 ± 0.1
Platelets (10^3^/µL) | 827 ± 32 | 812 ± 39 | 816 ± 34 | 789 ± 49 | 886 ± 40 | 799 ± 26
Leukocytes (10^3^/µL) | 6.15 ± 0.39 | 5.37 ± 0.31 | 5.87 ± 0.32 | 6.72 ± 0.22 | 6.03 ± 0.41 | 5.63 ± 0.33
Segmented neutrophils (10^3^/µL) | 0.66 ± 0.06 | 0.62 ± 0.06 | 0.61 ± 0.06 | 0.71 ± 0.05 | 0.57 ± 0.04 | 0.58 ± 0.05
Lymphocytes (10^3^/µL) | 5.12 ± 0.31 | 4.42 ± 0.25 | 4.92 ± 0.25 | 5.60 ± 0.18 | 5.09 ± 0.37 | 4.68 ± 0.27
Monocytes (10^3^/µL) | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.06 ± 0.01
Basophils (10^3^/µL) | 0.030 ± 0.006 | 0.023 ± 0.005 | 0.028 ± 0.006 | 0.029 ± 0.007 | 0.022 ± 0.003 | 0.026 ± 0.005
Eosinophils (10^3^/µL) | 0.12 ± 0.01 | 0.10 ± 0.02 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.13 ± 0.02
Large unstained cells (10^3^/µL) | 0.138 ± 0.016 | 0.118 ± 0.014 | 0.133 ± 0.007 | 0.177 ± 0.015 | 0.150 ± 0.011 | 0.154 ± 0.014
Female
Hematocrit (auto) (%) | 46.2 ± 1.4 | 45.8 ± 0.9 | 48.5 ± 0.6 | 47.0 ± 0.5 | 46.8 ± 0.4 | 46.9 ± 0.3
Hematocrit (spun) (%) | 46.9 ± 1.5 | 46.5 ± 0.9 | 48.7 ± 0.7 | 47.6 ± 0.5 | 47.1 ± 0.5 | 47.2 ± 0.3
Hemoglobin (g/dL) | 15.0 ± 0.5 | 14.7 ± 0.3 | 15.5 ± 0.2 | 15.2 ± 0.1 | 15.2 ± 0.1 | 15.2 ± 0.1
Erythrocytes (10^6^/µL) | 10.02 ± 0.29 | 9.88 ± 0.20 | 10.52 ± 0.09 | 10.18 ± 0.09 | 10.14 ± 0.08 | 10.05 ± 0.08
Reticulocytes (10^5^/µL) | 4.0 ± 0.2 | 4.1 ± 0.1 | 4.4 ± 0.2 | 4.0 ± 0.3 | 3.7 ± 0.2 | 4.2 ± 0.1
Nucleated erythrocytes/100 leukocytes | 0.1 ± 0.1 | 0.1 ± 0.1 | 0.1 ± 0.1 | 0.2 ± 0.1 | 0.0 ± 0.0 | 0.1 ± 0.1
Mean cell volume (fL) | 46.1 ± 0.2 | 46.3 ± 0.2 | 46.0 ± 0.2 | 46.2 ± 0.2 | 46.2 ± 0.2 | 46.7 ± 0.2
Mean cell hemoglobin (pg) | 15.0 ± 0.1 | 14.9 ± 0.0 | 14.8 ± 0.1 | 14.9 ± 0.1 | 15.0 ± 0.1 | 15.1 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.5 ± 0.2 | 32.1 ± 0.2 | 32.0 ± 0.3 | 32.3 ± 0.2 | 32.4 ± 0.3 | 32.3 ± 0.2
Platelets (10^3^/µL) | 776 ± 55 | 854 ± 43 | 957 ± 35* | 927 ± 45 | 840 ± 39 | 912 ± 48
Leukocytes (10^3^/µL) | 5.19 ± 0.55 | 5.40 ± 0.28 | 4.93 ± 0.26 | 4.72 ± 0.33 | 5.46 ± 0.37 | 5.24 ± 0.28
Segmented neutrophils (10^3^/µL) | 0.79 ± 0.19 | 0.65 ± 0.10 | 0.56 ± 0.06 | 0.57 ± 0.06 | 0.59 ± 0.05 | 0.63 ± 0.07
Lymphocytes (10^3^/µL) | 4.03 ± 0.39 | 4.36 ± 0.21 | 4.06 ± 0.20 | 3.80 ± 0.25 | 4.51 ± 0.32 | 4.26 ± 0.22
Monocytes (10^3^/µL) | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.00**
Basophils (10^3^/µL) | 0.020 ± 0.005 | 0.023 ± 0.004 | 0.018 ± 0.005 | 0.037 ± 0.013 | 0.025 ± 0.007 | 0.021 ± 0.003
Eosinophils (10^3^/µL) | 0.08 ± 0.02 | 0.12 ± 0.01 | 0.07 ± 0.02 | 0.08 ± 0.01 | 0.11 ± 0.01 | 0.10 ± 0.01
Large unstained cells (10^3^/µL) | 0.173 ± 0.016 | 0.162 ± 0.008 | 0.147 ± 0.020 | 0.179 ± 0.018 | 0.159 ± 0.014 | 0.182 ± 0.011

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.