# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Bromodichloroacetic acid was tested in two independent bacterial gene mutation assays. In the first assay, testing procedures followed protocols reported by Zeiger et al..^139^ A commercially obtained sample of bromodichloroacetic acid was sent to the laboratory under code. It was incubated with the Salmonella typhimurium tester strains TA97, TA98, TA100, and TA1535 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following 2 days incubation at 37°C.

In the second bacterial mutagenicity test, a sample of the same lot of bromodichloroacetic acid that was used in the 2-year bioassay was sent to the testing laboratory for assessment of mutagenicity in S. typhimurium strains TA97, TA98, and TA100 and in Escherichia coli strain WP2 uvrA/pKM101. Incubation in either buffer or S9 mix (from induced Sprague Dawley rat liver) and plating on minimal glucose agar plates was carried out as described above. Histidine-independent (for the S. typhimurium strains) or tryptophan-independent (for the E. coli strain) mutant colonies arising on these plates were counted following 2 days incubation at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and at least five doses of bromodichloroacetic acid; the highest concentration tested was 10,000 µg/plate.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al..^140^ At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of nine or 10 animals per exposure group. In addition, the percentage of polychromatic erythrocytes (PCEs) in a population of 1,000 erythrocytes was determined for each exposure group as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the 3-month studies were accepted without repeat tests, because additional test data could not be obtained. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.4 Results

Bromodichloroacetic acid was tested in two independent bacterial gene mutation assays. The first assay used a sample of the compound that had not been analytically characterized by the NTP; the second assay was conducted on the NTP-procured bioassay sample of bromodichloroacetic acid that had been extensively characterized. In the first assay, bromodichloroacetic acid (concentration range of 100 to 10,000 µg/plate) was judged to be weakly positive based on a pattern of responses seen in S. typhimurium strain TA97 in the presence of various concentrations of induced rat or hamster S9 metabolic activation mix; an equivocal response was obtained in TA97 in the absence of S9, and no mutagenic activity was seen in S. typhimurium strains TA98, TA100, or TA1535 (Table E-1).

In the second assay, conducted with the same lot of bromodichloroacetic acid that was used in the 2-year bioassays, positive responses were seen in S. typhimurium strains TA97, TA98, and TA100 and the E. coli strain WP2 uvrA/pkM101 over a concentration range of 500 to 6,000 µg/plate in the absence of S9 (Table E-2). With S9, equivocal responses were seen with the three S. typhimurium strains, and a positive response was observed in the E. coli strain. Thus, these two different samples of bromodichloroacetic acid gave different results in bacterial gene mutation assays, but the clearest indication of mutagenic activity was seen in the second assay conducted with the bioassay lot of bromodichloroacetic acid.

In vivo, no significant increases in the frequencies of micronucleated NCEs were observed in blood samples from male or female B6C3F1/N mice administered bromodichloroacetic acid (concentration range of 62.5 to 1,000 mg/L) in drinking water for 3 months (Table E-3). Small increases were seen in the percentage of reticulocytes (PCEs) among total red blood cells in the highest exposure concentration groups of male and female mice, but these were not significant.

Table E-1 Mutagenicity of Bromodichloroacetic Acid in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | Without S9
TA100 | 0 | 121 ± 1 | 109 ± 6.0 | 152 ± 6
| 100 | 101 ± 4 | 101 ± 2.0 | 155 ± 4
| 333 | 118 ± 10 | 110 ± 3.0 | 159 ± 25
| 1,000 | 117 ± 14 | 113 ± 6.0 | 142 ± 7
| 3,333 | 124 ± 7 | 131 ± 5.0 | 155 ± 15
| 10,000 | 149 ± 7^b^ | 64 ± 9.0^b^ | 88 ± 12^b^
Trial summary | | Negative | Negative | Negative
Positive control^c^ | | 769 ± 14 | 1,116 ± 41.0 | 885 ± 41
Strain | Dose (μg/plate) | With 10% Hamster S9 | With 5% Hamster S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 30% Hamster S9
TA100 | 0 | 153 ± 9 | 105 ± 5 | 100 ± 3 | 122 ± 4 | 120 ± 9
| 100 | 162 ± 9 | | | 131 ± 7 | 108 ± 3
| 333 | 146 ± 7 | 108 ± 3 | 106 ± 6 | 130 ± 1 | 102 ± 7
| 666 | | 102 ± 7 | 111 ± 2
| 1,000 | 178 ± 3 | 103 ± 6 | 104 ± 0 | 129 ± 7 | 117 ± 8
| 1,666 | | 102 ± 3 | 99 ± 3
| 3,333 | 192 ± 10 | 120 ± 5 | 112 ± 6 | 177 ± 4^d^ | 142 ± 4^d^
| 6,666 | | 130 ± 2 | 125 ± 3
| 10,000 | 107 ± 10^b^ | | | 157 ± 26^d^ | 104 ± 4^d^
Trial summary | | Equivocal | Negative | Equivocal | Equivocal | Negative
Positive control | | 857 ± 20 | 756 ± 14 | 721 ± 9 | 791 ± 2 | 868 ± 62
Strain | Dose (μg/plate) | With 10% Rat S9 | With 5% Rat S9 | With 10% Rat S9 | With 30% Rat S9 | With 30% Rat S9
TA100 | 0 | 153 ± 7 | 107 ± 7 | 109 ± 3 | 118 ± 9 | 120 ± 3
| 100 | 164 ± 3 | | | 110 ± 2 | 111 ± 8
| 333 | 159 ± 13 | 108 ± 6 | 112 ± 3 | 112 ± 10 | 119 ± 17
| 666 | | 98 ± 4 | 110 ± 4
| 1,000 | 172 ± 12 | 106 ± 4 | 94 ± 4 | 113 ± 6 | 154 ± 4
| 1,666 | | 108 ± 1 | 100 ± 5
| 3,333 | 187 ± 7 | 118 ± 2 | 117 ± 5 | 177 ± 8^d^ | 141 ± 13^d^
| 6,666 | | 134 ± 3 | 128 ± 5
| 10,000 | 80 ± 16^b^ | | | 140 ± 69^b,d^ | 98 ± 9^d^
Trial summary | | Negative | Equivocal | Negative | Equivocal | Negative
Positive control | | 706 ± 31 | 703 ± 17 | 655 ± 25 | 436 ± 32 | 611 ± 128
Strain | Dose (μg/plate) | Without S9 | Without S9 | Without S9
TA97 | 0 | 134 ± 5 | 185 ± 11 | 125 ± 8
| 33 | | | 123 ± 23
| 100 | 136 ± 11 | 202 ± 6
| 333 | 133 ± 4 | 213 ± 4
| 666 | | | 120 ± 5
| 1,000 | 146 ± 5 | 211 ± 6 | 155 ± 9
| 1,666 | | | 132 ± 7
| 3,333 | 149 ± 2 | 238 ± 3 | 149 ± 5
| 6,666 | | | 208 ± 10
| 10,000 | 88 ± 8^b^ | 90 ± 38^b^
Trial summary | | Negative | Equivocal | Equivocal
Positive control | | 584 ± 37 | 682 ± 37 | 648 ± 14
Strain | Dose (μg/plate) | With 10% Hamster S9 | With 10% Hamster S9 | With 5% Hamster S9 | With 30% Hamster S9
TA97 | 0 | 180 ± 1 | 132 ± 4 | 139 ± 13 | 171 ± 2
| 33 | | 134 ± 5
| 100 | 185 ± 8 | | | 177 ± 9
| 333 | 203 ± 7 | | 142 ± 2 | 166 ± 6
| 666 | | 142 ± 10 | 138 ± 10
| 1,000 | 216 ± 14 | 152 ± 10 | 151 ± 12 | 173 ± 12
| 1,666 | | 150 ± 4 | 167 ± 3
| 3,333 | 235 ± 11 | 161 ± 7 | 180 ± 4 | 173 ± 3^d^
| 6,666 | | 203 ± 14 | 216 ± 8
| 10,000 | 162 ± 61^b^ | | | 152 ± 8^d^
Trial summary | | Weakly positive | Equivocal | Weakly positive | Negative
Positive control | | 785 ± 66 | 746 ± 25 | 820 ± 17 | 837 ± 16
Strain | Dose (μg/plate) | With 10% Rat S9 | With 10% Rat S9 | With 30% Rat S9 | With 5% Rat S9
TA97 | 0 | 178 ± 6 | 156 ± 7 | 192 ± 8 | 140 ± 5
| 33 | | 167 ± 8 | | 141 ± 5
| 100 | 181 ± 6 | | 198 ± 7
| 333 | 192 ± 14 | | 203 ± 8
| 666 | | 153 ± 11 | | 157 ± 6
| 1,000 | 218 ± 1 | 153 ± 9 | 208 ± 16 | 149 ± 4
| 1,666 | | 173 ± 7 | | 152 ± 4
| 3,333 | 247 ± 19 | 188 ± 8 | 183 ± 8^d^ | 173 ± 5
| 6,666 | | 236 ± 9 | | 228 ± 16
| 10,000 | 162 ± 15^b^ | | 177 ± 6^d^
Trial summary | | Weakly positive | Equivocal | Negative | Weakly positive
Positive control | | 681 ± 25 | 652 ± 16 | 782 ± 30 | 694 ± 6
Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9 | With 30% Rat S9
TA98 | 0 | 16 ± 1 | 21 ± 2 | 29 ± 2 | 27 ± 4 | 30 ± 0 | 20 ± 2
| 100 | 13 ± 2 | 25 ± 3 | 28 ± 4 | 31 ± 2 | 22 ± 4 | 22 ± 1
| 333 | 20 ± 1 | 27 ± 2 | 27 ± 4 | 26 ± 2 | 27 ± 3 | 20 ± 1
| 1,000 | 17 ± 2 | 20 ± 1 | 28 ± 2 | 42 ± 3 | 32 ± 3 | 30 ± 5
| 3,333 | 30 ± 4 | 32 ± 5 | 39 ± 6 | 41 ± 3^d^ | 37 ± 1 | 34 ± 5^d^
| 10,000 | 12 ± 2^b^ | 8 ± 2^b^ | 29 ± 9^b^ | 32 ± 2^d^ | 16 ± 3^b^ | 16 ± 4^d^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 338 ± 11 | 321 ± 36 | 875 ± 30 | 372 ± 51 | 702 ± 17 | 360 ± 31
TA1535 | 0 | 9 ± 2 | 7 ± 0 | 9 ± 3 | 9 ± 0 | 12 ± 2 | 10 ± 1
| 100 | 9 ± 2 | 10 ± 3 | 6 ± 1 | 10 ± 1 | 10 ± 1 | 9 ± 1
| 333 | 8 ± 2 | 7 ± 0 | 6 ± 1 | 8 ± 1 | 10 ± 2 | 7 ± 0
| 1,000 | 9 ± 2 | 6 ± 1 | 10 ± 2 | 8 ± 0 | 9 ± 2 | 10 ± 1
| 3,333 | 10 ± 2 | 5 ± 1 | 8 ± 2 | 10 ± 1^d^ | 9 ± 1 | 8 ± 1^d^
| 10,000 | Toxic | 2 ± 0^b^ | 7 ± 0^b^ | 9 ± 2^d^ | 4 ± 1^b^ | 9 ± 0^d^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 810 ± 40 | 846 ± 36 | 129 ± 1 | 202 ± 8 | 107 ± 5 | 172 ± 24

^a^ Study was performed at SRI International. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^139^ 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^d^ Precipitate on plate.

Table E-2 Mutagenicity of Bromodichloroacetic Acid in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100 | 0 | 89 ± 6 | 103 ± 6 | 110 ± 6 | 114 ± 4
| 500 | 112 ± 1 | 127 ± 6 | 113 ± 3 | 121 ± 1
| 1,000 | 170 ± 9 | 151 ± 16 | 127 ± 1 | 134 ± 10
| 1,500 | 281 ± 13 | 307 ± 17 | 126 ± 14 | 138 ± 7^b^
| 3,000 | 500 ± 12 | 986 ± 21 | 129 ± 2 | 126 ± 14
| 4,500 | 664 ± 30 | 1,216 ± 35 | 138 ± 6 | 140 ± 8
| 6,000 | 623 ± 38 | 1,203 ± 22 | 156 ± 9 | 166 ± 6
Trial summary | | Positive | Positive | Equivocal | Equivocal
Positive control^c^ | | 591 ± 24 | 763 ± 23 | 634 ± 25 | 856 ± 26^b^
TA97 | 0 | 111 ± 11 | 120 ± 8 | 151 ± 4 | 172 ± 8
| 500 | 147 ± 5 | 119 ± 7 | 181 ± 3 | 173 ± 0
| 1,000 | 139 ± 10 | 121 ± 6 | 164 ± 5 | 174 ± 7
| 1,500 | 169 ± 1 | 149 ± 16 | 166 ± 4 | 184 ± 2
| 3,000 | 312 ± 17 | 229 ± 7 | 168 ± 14 | 169 ± 14
| 4,500 | 452 ± 24 | 354 ± 32 | 232 ± 15 | 214 ± 10
| 6,000 | 528 ± 10 | 354 ± 14 | 217 ± 12 | 232 ± 1
Trial summary | | Positive | Positive | Equivocal | Equivocal
Positive control | | 1,539 ± 44 | 2,400 ± 70 | 2,744 ± 138 | 1,854 ± 82
TA98 | 0 | 24 ± 1 | 29 ± 3 | 27 ± 1 | 35 ± 8
| 500 | 32 ± 3 | 37 ± 5 | 28 ± 2 | 38 ± 3
| 1,000 | 19 ± 2 | 33 ± 1 | 39 ± 5 | 44 ± 1
| 1,500 | 30 ± 4 | 42 ± 8 | 28 ± 3 | 47 ± 7
| 3,000 | 47 ± 7 | 64 ± 5 | 28 ± 2 | 51 ± 5
| 4,500 | 59 ± 2 | 106 ± 12 | 41 ± 7 | 62 ± 4
| 6,000 | 73 ± 5 | 149 ± 3 | 41 ± 3 | 65 ± 5
Trial summary | | Positive | Positive | Equivocal | Equivocal
Positive control | | 622 ± 69 | 740 ± 11 | 1,476 ± 25 | 2,066 ± 28
Escherichia coli WP2 uvrA/pKM101
| 0 | 159 ± 3 | 168 ± 23 | 166 ± 9 | 157 ± 16
| 500 | 182 ± 7 | 213 ± 7 | 209 ± 5 | 226 ± 5
| 1,000 | 203 ± 17 | 199 ± 28 | 236 ± 14 | 195 ± 33
| 1,500 | 225 ± 19 | 239 ± 4 | 246 ± 6 | 274 ± 12
| 3,000 | 274 ± 6 | 319 ± 12 | 273 ± 6 | 335 ± 6
| 4,500 | 373 ± 16 | 454 ± 22 | 315 ± 7 | 381 ± 9
| 6,000 | 586 ± 12 | 619 ± 22 | 380 ± 16 | 356 ± 46
Trial summary | | Positive | Positive | Positive | Positive
Positive control | | 1,803 ± 88 | 1,924 ± 29 | 1,259 ± 12 | 1,657 ± 20

^a^ Study was performed at ILS, Inc., using lot NJ 87-90/9/2005 and a modification of the protocol presented by Zeiger et al..^139^ Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ Contamination.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 9-aminoacridine (TA97), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Administration of Bromodichloroacetic Acid in Drinking Water for Three Months^a^

| Exposure Concentration (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Water^d^ | 0 | 10 | 3.50 ± 0.56 | | 3.91 ± 0.25
Bromodichloroacetic acid | 62.5 | 9 | 3.11 ± 0.45 | 0.6792 | 4.71 ± 0.23
| 125 | 10 | 3.40 ± 0.69 | 0.5480 | 4.18 ± 0.26
| 250 | 10 | 3.30 ± 0.37 | 0.5960 | 3.88 ± 0.18
| 500 | 10 | 4.20 ± 0.49 | 0.2121 | 4.57 ± 0.24
| 1,000 | 10 | 4.40 ± 0.52 | 0.1552 | 4.64 ± 0.21
| | | P = 0.045^e^
Female
Water | 0 | 10 | 4.20 ± 0.51 | | 4.52 ± 0.35
Bromodichloroacetic acid | 62.5 | 10 | 2.40 ± 0.27 | 0.9868 | 4.98 ± 0.28
| 125 | 10 | 2.40 ± 0.45 | 0.9868 | 4.80 ± 0.30
| 250 | 10 | 2.50 ± 0.40 | 0.9813 | 4.52 ± 0.37
| 500 | 10 | 3.20 ± 0.39 | 0.8779 | 4.59 ± 0.33
| 1,000 | 10 | 3.60 ± 0.43 | 0.7520 | 5.70 ± 0.37
| | | P = 0.215

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^140^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; exposed group values are significant at p ≤ 0.005.

^d^ Control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at p ≤ 0.025.