# Appendix D Summary of Lesions in Female Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Disposition Summary
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^b^ | 8 | 8 | 8 | 8
Fourteen-month interim evaluation^b^ | 8 | 8 | 8 | 8
Early deaths
Moribund | 9 | 9 | 8 | 11
Natural deaths | 11 | 8 | 13 | 12
Survivors
Died last week of study | – | – | – | 1
Terminal kill | 30 | 33 | 29 | 26
Animals examined microscopically | 66 | 66 | 66 | 66
Alimentary System
Esophagus | (50) | (50) | (47) | (48)
Sarcoma | – | – | – | 1 (2%)
Gallbladder | (47) | (48) | (50) | (44)
Leiomyosarcoma, metastatic, mesentery | – | 1 (2%) | – | –
Intestine large, cecum | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | 1 (2%) | –
Intestine large, colon | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Intestine large, rectum | (49) | (50) | (50) | (50)
Intestine small, duodenum | (49) | (50) | (50) | (49)
Adenoma | – | – | 1 (2%) | –
Leiomyosarcoma | – | 1 (2%) | – | –
Intestine small, ileum | (50) | (50) | (50) | (49)
Carcinoma | – | 1 (2%) | – | –
Leiomyosarcoma, metastatic, urinary bladder | – | – | 1 (2%) | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Leiomyosarcoma | – | 1 (2%) | – | –
Liver | (49) | (50) | (49) | (50)
Hemangiosarcoma | 2 (4%) | 4 (8%) | 4 (8%) | 8 (16%)
Hemangiosarcoma, metastatic, skin | – | – | 1 (2%) | –
Hemangiosarcoma, metastatic, spleen | – | 1 (2%) | – | –
Hepatoblastoma | – | 1 (2%) | 3 (6%) | 4 (8%)
Hepatoblastoma, multiple | – | – | 1 (2%) | 2 (4%)
Hepatocellular adenoma | 8 (16%) | 4 (8%) | 5 (10%) | 7 (14%)
Hepatocellular adenoma, multiple | 25 (51%) | 38 (76%) | 37 (76%) | 37 (74%)
Hepatocellular carcinoma | 9 (18%) | 12 (24%) | 16 (33%) | 13 (26%)
Hepatocellular carcinoma, multiple | – | 5 (10%) | 6 (12%) | 13 (26%)
Hepatocholangiocarcinoma | – | – | – | 1 (2%)
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Mesentery | (10) | (13) | (13) | (10)
Fibrosarcoma, metastatic, skin | – | – | 1 (8%) | –
Fibrous histiocytoma | – | 1 (8%) | 1 (8%) | –
Hemangiosarcoma | 1 (10%) | – | – | –
Leiomyosarcoma | – | 1 (8%) | – | –
Leiomyosarcoma, metastatic, urinary bladder | – | – | 1 (8%) | –
Oral mucosa | (2) | (2) | (0) | (0)
Pancreas | (49) | (50) | (50) | (48)
Cystadenoma | – | 1 (2%) | – | –
Leiomyosarcoma | – | 1 (2%) | – | –
Salivary glands | (48) | (49) | (44) | (45)
Stomach, forestomach | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Squamous cell papilloma | 1 (2%) | – | – | 2 (4%)
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (0) | (0) | (0) | (1)
Squamous cell carcinoma | – | – | – | 1 (100%)
Tooth | (0) | (2) | (0) | (1)
Cardiovascular System
Blood vessel | (50) | (50) | (48) | (49)
Heart | (50) | (50) | (48) | (48)
Endocrine System
Adrenal cortex | (49) | (50) | (47) | (49)
Leiomyosarcoma | – | 1 (2%) | – | –
Subcapsular, adenoma | – | 1 (2%) | – | –
Adrenal medulla | (50) | (50) | (48) | (49)
Leiomyosarcoma | – | 1 (2%) | – | –
Pheochromocytoma benign | – | – | 1 (2%) | –
Islets, pancreatic | (49) | (50) | (50) | (48)
Parathyroid gland | (45) | (46) | (41) | (38)
Pituitary gland | (49) | (49) | (46) | (48)
Pars distalis, adenoma | 2 (4%) | 1 (2%) | 3 (7%) | –
Thyroid gland | (49) | (50) | (46) | (45)
C-cell, carcinoma | – | – | – | 1 (2%)
Follicular cell, adenoma | – | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (47) | (50) | (50) | (48)
Carcinoma | – | – | – | 1 (2%)
Ovary | (50) | (50) | (50) | (50)
Cystadenoma | 1 (2%) | 3 (6%) | 2 (4%) | 2 (4%)
Granulosa cell tumor benign | – | – | 1 (2%) | –
Granulosa cell tumor malignant | – | – | – | 1 (2%)
Hemangiosarcoma | – | 1 (2%) | 2 (4%) | –
Uterus | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | 2 (4%) | –
Polyp stromal | 4 (8%) | 3 (6%) | 1 (2%) | 1 (2%)
Sarcoma stromal | – | – | 1 (2%) | –
Vagina | (0) | (0) | (0) | (1)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | 1 (2%) | –
Hemangiosarcoma, metastatic, liver | 1 (2%) | – | – | –
Lymph node | (2) | (3) | (3) | (5)
Axillary, schwannoma malignant, metastatic, skin | – | – | – | 1 (20%)
Lumbar, plasma cell tumor malignant | – | – | 1 (33%) | –
Lumbar, schwannoma malignant, metastatic, skin | – | – | – | 1 (20%)
Renal, plasma cell tumor malignant | – | – | 1 (33%) | –
Lymph node, mandibular | (48) | (49) | (44) | (45)
Plasma cell tumor malignant | – | – | 1 (2%) | –
Lymph node, mesenteric | (48) | (50) | (47) | (47)
Plasma cell tumor malignant | – | – | 1 (2%) | –
Spleen | (49) | (50) | (50) | (48)
Hemangiosarcoma | – | 2 (4%) | 1 (2%) | –
Hemangiosarcoma, metastatic, skin | – | – | 1 (2%) | –
Plasma cell tumor malignant | – | – | 1 (2%) | –
Thymus | (50) | (50) | (46) | (46)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Plasma cell tumor malignant | – | – | 1 (2%) | –
Schwannoma malignant, metastatic, skin | 1 (2%) | – | – | –
Thymoma malignant | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (49) | (50)
Carcinoma | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Basal cell carcinoma | – | – | – | 1 (2%)
Fibrosarcoma | – | – | 1 (2%) | –
Fibrous histiocytoma | 3 (6%) | 1 (2%) | 2 (4%) | 4 (8%)
Hemangioma | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | 1 (2%) | 1 (2%) | –
Osteosarcoma | – | 1 (2%) | – | –
Sarcoma | 1 (2%) | – | 1 (2%) | –
Schwannoma malignant | 3 (6%) | – | 1 (2%) | 5 (10%)
Squamous cell carcinoma | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Osteoma | 1 (2%) | – | – | 1 (2%)
Osteosarcoma | – | 1 (2%) | – | –
Skeletal muscle | (1) | (2) | (2) | (1)
Fibrosarcoma, metastatic, skin | – | – | 1 (50%) | –
Fibrous histiocytoma, metastatic, mesentery | – | 1 (50%) | – | –
Hemangiosarcoma | 1 (100%) | – | – | –
Leiomyosarcoma | – | 1 (50%) | – | –
Sarcoma | – | – | 1 (50%) | –
Nervous System
Brain | (49) | (50) | (47) | (49)
Respiratory System
Lung | (50) | (50) | (48) | (48)
Alveolar/bronchiolar adenoma | 3 (6%) | 2 (4%) | 1 (2%) | 2 (4%)
Alveolar/bronchiolar carcinoma | 2 (4%) | 2 (4%) | 1 (2%) | 5 (10%)
Alveolar/bronchiolar carcinoma, multiple | – | 1 (2%) | – | –
Fibrous histiocytoma, metastatic, skin | – | – | – | 1 (2%)
Hemangiosarcoma, metastatic, liver | 1 (2%) | – | – | –
Hepatoblastoma, metastatic, liver | – | – | 2 (4%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | 6 (12%) | 4 (8%) | 7 (15%)
Schwannoma malignant, metastatic, skin | 1 (2%) | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (46) | (46)
Special Senses System
Eye | (48) | (50) | (46) | (46)
Harderian gland | (48) | (50) | (46) | (46)
Adenoma | 5 (10%) | 4 (8%) | 6 (13%) | 5 (11%)
Carcinoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Urinary System
Kidney | (50) | (50) | (50) | (49)
Urinary bladder | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skin | 1 (2%) | – | – | –
Leiomyosarcoma | – | – | 1 (2%) | –
Systemic Lesions
Multiple organs^c^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 2 (4%) | 3 (6%) | 1 (2%) | 3 (6%)
Lymphoma malignant | 6 (12%) | 3 (6%) | 6 (12%) | 10 (20%)
Neoplasm Summary
Total animals with primary neoplasms^d^ | 45 | 47 | 46 | 49
Total primary neoplasms | 83 | 106 | 120 | 136
Total animals with benign neoplasms | 36 | 43 | 43 | 44
Total benign neoplasms | 50 | 58 | 58 | 58
Total animals with malignant neoplasms | 31 | 33 | 38 | 45
Total malignant neoplasms | 33 | 48 | 62 | 78
Total animals with metastatic neoplasms | 4 | 10 | 10 | 8
Total metastatic neoplasms | 7 | 10 | 14 | 11
Total animals with malignant neoplasms of uncertain primary site | – | – | 1 | –

^a^ Number of core study animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Pathology data for interim evaluation animals are not presented in this table.

^c^ Number of animals with any tissue examined microscopically.

^d^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Harderian Gland: Adenoma
Overall rate^a^ | 5/50 (10%) | 4/50 (8%) | 6/50 (12%) | 5/50 (10%)
Adjusted rate^b^ | 11.5% | 9.1% | 13.5% | 11.7%
Terminal rate^c^ | 3/30 (10%) | 3/33 (9%) | 3/29 (10%) | 4/27 (15%)
First incidence (days) | 540 | 509 | 575 | 614
Poly-3 test^d^ | P = 0.484 | P = 0.494N | P = 0.513 | P = 0.619
Harderian Gland: Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 7/50 (14%) | 6/50 (12%)
Adjusted rate | 11.5% | 9.1% | 15.8% | 14.0%
Terminal rate | 3/30 (10%) | 3/33 (9%) | 4/29 (14%) | 4/27 (15%)
First incidence (days) | 540 | 509 | 575 | 614
Poly-3 test | P = 0.336 | P = 0.494N | P = 0.392 | P = 0.488
Liver: Hemangiosarcoma
Overall rate | 2/49 (4%) | 4/50 (8%) | 4/49 (8%) | 8/50 (16%)
Adjusted rate | 4.7% | 9.2% | 9.2% | 18.6%
Terminal rate | 1/30 (3%) | 3/33 (9%) | 3/29 (10%) | 5/27 (19%)
First incidence (days) | 596 | 659 | 575 | 660
Poly-3 test | P = 0.026 | P = 0.347 | P = 0.346 | P = 0.045
Liver: Hepatocellular Adenoma
Overall rate | 33/49 (67%) | 42/50 (84%) | 42/49 (86%) | 44/50 (88%)
Adjusted rate | 75.3% | 90.7% | 92.5% | 93.0%
Terminal rate | 26/30 (87%) | 32/33 (97%) | 28/29 (97%) | 27/27 (100%)
First incidence (days) | 540 | 386 | 597 | 503
Poly-3 test | P = 0.009 | P = 0.030 | P = 0.015 | P = 0.010
Liver: Hepatocellular Carcinoma
Overall rate | 9/49 (18%) | 17/50 (34%) | 22/49 (45%) | 26/50 (52%)
Adjusted rate | 21.1% | 37.9% | 49.8% | 59.1%
Terminal rate | 5/30 (17%) | 13/33 (39%) | 15/29 (52%) | 20/27 (74%)
First incidence (days) | 604 | 509 | 603 | 607
Poly-3 test | P < 0.001 | P = 0.065 | P = 0.004 | P < 0.001
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 36/49 (73%) | 44/50 (88%) | 43/49 (88%) | 46/50 (92%)
Adjusted rate | 81.1% | 93.7% | 94.7% | 95.5%
Terminal rate | 26/30 (87%) | 33/33 (100%) | 29/29 (100%) | 27/27 (100%)
First incidence (days) | 540 | 386 | 597 | 503
Poly-3 test | P = 0.013 | P = 0.043 | P = 0.030 | P = 0.017
Liver: Hepatoblastoma
Overall rate | 0/49 (0%) | 1/50 (2%) | 4/49 (8%) | 6/50 (12%)
Adjusted rate | 0.0% | 2.3% | 9.3% | 13.9%
Terminal rate | 0/30 (0%) | 0/33 (0%) | 3/29 (10%) | 3/27 (11%)
First incidence (days) | –^e^ | 688 | 716 | 636
Poly-3 test | P = 0.003 | P = 0.506 | P = 0.062 | P = 0.016
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 9/49 (18%) | 18/50 (36%) | 24/49 (49%) | 28/50 (56%)
Adjusted rate | 21.1% | 40.0% | 54.4% | 63.0%
Terminal rate | 5/30 (17%) | 13/33 (39%) | 17/29 (59%) | 20/27 (74%)
First incidence (days) | 604 | 509 | 603 | 607
Poly-3 test | P < 0.001 | P = 0.043 | P < 0.001 | P < 0.001
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 36/49 (73%) | 44/50 (88%) | 43/49 (88%) | 46/50 (92%)
Adjusted rate | 81.1% | 93.7% | 94.7% | 95.5%
Terminal rate | 26/30 (87%) | 33/33 (100%) | 29/29 (100%) | 27/27 (100%)
First incidence (days) | 540 | 386 | 597 | 503
Poly-3 test | P = 0.013 | P = 0.043 | P = 0.030 | P = 0.017
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 1/48 (2%) | 2/48 (4%)
Adjusted rate | 7.1% | 4.6% | 2.4% | 4.8%
Terminal rate | 3/30 (10%) | 2/33 (6%) | 0/29 (0%) | 1/27 (4%)
First incidence (days) | 729 (T) | 729 (T) | 687 | 614
Poly-3 test | P = 0.418N | P = 0.491N | P = 0.306N | P = 0.509N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 1/48 (2%) | 5/48 (10%)
Adjusted rate | 4.7% | 6.8% | 2.4% | 12.0%
Terminal rate | 1/30 (3%) | 0/33 (0%) | 0/29 (0%) | 4/27 (15%)
First incidence (days) | 584 | 549 | 698 | 503
Poly-3 test | P = 0.146 | P = 0.514 | P = 0.506N | P = 0.205
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 2/48 (4%) | 7/48 (15%)
Adjusted rate | 11.7% | 11.3% | 4.7% | 16.6%
Terminal rate | 4/30 (13%) | 2/33 (6%) | 0/29 (0%) | 5/27 (19%)
First incidence (days) | 584 | 549 | 687 | 503
Poly-3 test | P = 0.305 | P = 0.611N | P = 0.220N | P = 0.367
Ovary: Cystadenoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 2/50 (4%) | 2/50 (4%)
Adjusted rate | 2.4% | 6.9% | 4.6% | 4.7%
Terminal rate | 0/30 (0%) | 3/33 (9%) | 1/29 (3%) | 1/27 (4%)
First incidence (days) | 694 | 729 (T) | 721 | 710
Poly-3 test | P = 0.498 | P = 0.311 | P = 0.508 | P = 0.499
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 2/49 (4%) | 1/49 (2%) | 3/46 (7%) | 0/48 (0%)
Adjusted rate | 4.8% | 2.3% | 7.5% | 0.0%
Terminal rate | 2/30 (7%) | 1/33 (3%) | 3/29 (10%) | 0/27 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | –
Poly-3 test | P = 0.251N | P = 0.488N | P = 0.483 | P = 0.239N
Skin: Fibrous Histiocytoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 7.0% | 2.3% | 4.6% | 9.4%
Terminal rate | 0/30 (0%) | 0/33 (0%) | 0/29 (0%) | 1/27 (4%)
First incidence (days) | 604 | 666 | 666 | 662
Poly-3 test | P = 0.287 | P = 0.303N | P = 0.492N | P = 0.495
Skin: Fibrous Histiocytoma, Fibrosarcoma, or Sarcoma
Overall rate | 4/50 (8%) | 1/50 (2%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 9.2% | 2.3% | 9.0% | 9.4%
Terminal rate | 0/30 (0%) | 0/33 (0%) | 0/29 (0%) | 1/27 (4%)
First incidence (days) | 576 | 666 | 597 | 662
Poly-3 test | P = 0.394 | P = 0.180N | P = 0.633N | P = 0.632
Skin: Malignant Schwannoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 1/50 (2%) | 5/50 (10%)
Adjusted rate | 7.1% | 0.0% | 2.3% | 11.4%
Terminal rate | 1/30 (3%) | 0/33 (0%) | 0/29 (0%) | 1/27 (4%)
First incidence (days) | 701 | – | 669 | 534
Poly-3 test | P = 0.113 | P = 0.115N | P = 0.295N | P = 0.372
Uterus: Stromal Polyp
Overall rate | 4/50 (8%) | 3/50 (6%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 9.4% | 6.9% | 2.3% | 2.3%
Terminal rate | 2/30 (7%) | 3/33 (9%) | 1/29 (3%) | 0/27 (0%)
First incidence (days) | 712 | 729 (T) | 729 (T) | 614
Poly-3 test | P = 0.091N | P = 0.490N | P = 0.171N | P = 0.176N
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 4/50 (8%) | 3/50 (6%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 9.4% | 6.9% | 4.6% | 2.3%
Terminal rate | 2/30 (7%) | 3/33 (9%) | 2/29 (7%) | 0/27 (0%)
First incidence (days) | 712 | 729 (T) | 729 (T) | 614
Poly-3 test | P = 0.113N | P = 0.490N | P = 0.326N | P = 0.176N
All Organs: Hemangiosarcoma
Overall rate | 6/50 (12%) | 8/50 (16%) | 12/50 (24%) | 9/50 (18%)
Adjusted rate | 13.8% | 18.4% | 26.9% | 20.9%
Terminal rate | 3/30 (10%) | 6/33 (18%) | 7/29 (24%) | 6/27 (22%)
First incidence (days) | 596 | 659 | 575 | 660
Poly-3 test | P = 0.219 | P = 0.386 | P = 0.101 | P = 0.275
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 6/50 (12%) | 8/50 (16%) | 12/50 (24%) | 10/50 (20%)
Adjusted rate | 13.8% | 18.4% | 26.9% | 23.3%
Terminal rate | 3/30 (10%) | 6/33 (18%) | 7/29 (24%) | 7/27 (26%)
First incidence (days) | 596 | 659 | 575 | 660
Poly-3 test | P = 0.146 | P = 0.386 | P = 0.101 | P = 0.193
All Organs: Histiocytic Sarcoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 4.7% | 6.9% | 2.3% | 7.0%
Terminal rate | 1/30 (3%) | 1/33 (3%) | 0/29 (0%) | 0/27 (0%)
First incidence (days) | 549 | 666 | 682 | 636
Poly-3 test | P = 0.476 | P = 0.508 | P = 0.494N | P = 0.500
All Organs: Malignant Lymphoma
Overall rate | 6/50 (12%) | 3/50 (6%) | 6/50 (12%) | 10/50 (20%)
Adjusted rate | 13.8% | 6.9% | 13.8% | 22.6%
Terminal rate | 4/30 (13%) | 3/33 (9%) | 3/29 (10%) | 5/27 (19%)
First incidence (days) | 544 | 729 (T) | 701 | 265
Poly-3 test | P = 0.071 | P = 0.244N | P = 0.619N | P = 0.213
All Organs: Benign Neoplasms
Overall rate | 36/50 (72%) | 43/50 (86%) | 43/50 (86%) | 44/50 (88%)
Adjusted rate | 81.4% | 91.5% | 92.5% | 93.0%
Terminal rate | 27/30 (90%) | 32/33 (97%) | 28/29 (97%) | 27/27 (100%)
First incidence (days) | 540 | 386 | 575 | 503
Poly-3 test | P = 0.058 | P = 0.101 | P = 0.074 | P = 0.057
All Organs: Malignant Neoplasms
Overall rate | 31/50 (62%) | 33/50 (66%) | 38/50 (76%) | 45/50 (90%)
Adjusted rate | 64.9% | 70.6% | 81.2% | 92.9%
Terminal rate | 14/30 (47%) | 22/33 (67%) | 21/29 (72%) | 25/27 (93%)
First incidence (days) | 544 | 509 | 575 | 265
Poly-3 test | P < 0.001 | P = 0.353 | P = 0.056 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 45/50 (90%) | 47/50 (94%) | 46/50 (92%) | 49/50 (98%)
Adjusted rate | 93.1% | 97.9% | 98.3% | 99.1%
Terminal rate | 27/30 (90%) | 33/33 (100%) | 29/29 (100%) | 27/27 (100%)
First incidence (days) | 540 | 386 | 575 | 265

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the control incidence is the pvalue associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table D-3 Historical Incidence of Liver Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatoblastoma
Historical Incidence: Drinking Water Studies
β-Picoline (November 2004) | 38/49 | 11/49 | 1/49
Bromodichloroacetic acid (September 2006) | 33/49 | 9/49 | 0/49
Total (%) | 71/98 (72.5%) | 20/98 (20.4%) | 10/98 (10.0%)
Mean ± standard deviation | 72.5% ± 7.2% | 20.4% ± 2.9% | 10.0% ± 2.8%
Range | 67%–78% | 18%–22% | 8%–12%
Overall Historical Incidence: All Routes
Total (%) | 378/948 (39.9%) | 152/948 (16.0%) | 40/948 (4.2%)
Mean ± standard deviation | 39.9% ± 18.7% | 16.0% ± 10.6% | 4.2% ± 3.5%
Range | 14%–78% | 4%–46% | 0%–12%

^a^ Data as of June 2013.

Table D-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Disposition Summary
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^b^ | 8 | 8 | 8 | 8
Fourteen-month interim evaluation^b^ | 8 | 8 | 8 | 8
Early deaths
Moribund | 9 | 9 | 8 | 11
Natural deaths | 11 | 8 | 13 | 12
Survivors
Died last week of study | – | – | – | 1
Terminal kill | 30 | 33 | 29 | 26
Animals examined microscopically | 66 | 66 | 66 | 66
Alimentary System
Esophagus | (50) | (50) | (47) | (48)
Gallbladder | (47) | (48) | (50) | (44)
Intestine large, cecum | (50) | (50) | (50) | (50)
Diverticulum | – | 1 (2%) | – | –
Epithelium, hyperplasia | – | 1 (2%) | – | –
Lymphoid tissue, hyperplasia | – | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Serosa, inflammation | – | – | 1 (2%) | –
Intestine large, rectum | (49) | (50) | (50) | (50)
Serosa, inflammation | – | – | 1 (2%) | –
Intestine small, duodenum | (49) | (50) | (50) | (49)
Intestine small, ileum | (50) | (50) | (50) | (49)
Inflammation | 1 (2%) | 1 (2%) | 1 (2%) | –
Intestine small, jejunum | (50) | (50) | (50) | (50)
Inflammation | – | – | – | 1 (2%)
Epithelium, hyperplasia | – | 1 (2%) | – | –
Peyer’s patch, hyperplasia, lymphoid | – | – | – | 1 (2%)
Peyer’s patch, mineralization | – | 1 (2%) | – | –
Liver | (49) | (50) | (49) | (50)
Angiectasis | – | 1 (2%) | 6 (12%) | 3 (6%)
Basophilic focus | 3 (6%) | 1 (2%) | 1 (2%) | 3 (6%)
Clear cell focus | 5 (10%) | 5 (10%) | 8 (16%) | 5 (10%)
Eosinophilic focus | 22 (45%) | 33 (66%) | 38 (78%) | 40 (80%)
Fatty change | 4 (8%) | 2 (4%) | 2 (4%) | 1 (2%)
Fatty change, focal | – | – | – | 2 (4%)
Focus of cellular alteration, atypical | – | 2 (4%) | 6 (12%) | 16 (32%)
Hematopoietic cell proliferation | 1 (2%) | 2 (4%) | 2 (4%) | –
Hemorrhage | 1 (2%) | – | – | –
Infarct | – | 1 (2%) | – | –
Inflammation | 27 (55%) | 18 (36%) | 9 (18%) | 15 (30%)
Mineralization | – | 1 (2%) | 1 (2%) | –
Mixed cell focus | 4 (8%) | 10 (20%) | 4 (8%) | 4 (8%)
Pigmentation | – | – | – | 1 (2%)
Tension lipidosis | 4 (8%) | 1 (2%) | 3 (6%) | –
Thrombosis | – | – | 1 (2%) | 1 (2%)
Bile duct, cyst | 1 (2%) | – | – | –
Bile duct, hyperplasia | 2 (4%) | 4 (8%) | 3 (6%) | 3 (6%)
Centrilobular, fatty change | – | 2 (4%) | – | –
Hepatocyte, hypertrophy | – | 1 (2%) | – | –
Hepatocyte, necrosis | 2 (4%) | 4 (8%) | 2 (4%) | 6 (12%)
Oval cell, hyperplasia | – | – | 1 (2%) | 1 (2%)
Portal, fibrosis | – | – | 1 (2%) | –
Mesentery | (10) | (13) | (13) | (10)
Inflammation | 1 (10%) | – | – | –
Necrosis | 7 (70%) | 11 (85%) | 11 (85%) | 9 (90%)
Oral mucosa | (2) | (2) | (0) | (0)
Gingival, hyperplasia | 1 (50%) | – | – | –
Pharyngeal, hyperplasia | – | 2 (100%) | – | –
Pharyngeal, inflammation | 1 (50%) | – | – | –
Pancreas | (49) | (50) | (50) | (48)
Inflammation | – | 1 (2%) | – | –
Mineralization, focal | – | 1 (2%) | – | –
Acinus, atrophy | – | 3 (6%) | 1 (2%) | –
Acinus, hyperplasia | – | – | 1 (2%) | –
Duct, cyst | – | – | – | 1 (2%)
Salivary glands | (48) | (49) | (44) | (45)
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | 1 (2%)
Ulcer | 1 (2%) | – | – | 1 (2%)
Epithelium, hyperplasia | – | – | – | 2 (4%)
Stomach, glandular | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | –
Mineralization | 1 (2%) | 3 (6%) | – | –
Epithelium, hyperplasia | – | – | – | 2 (4%)
Glands, ectasia | 2 (4%) | – | – | 2 (4%)
Tongue | (0) | (0) | (0) | (1)
Tooth | (0) | (2) | (0) | (1)
Malformation | – | – | – | 1 (100%)
Pulp, inflammation | – | 2 (100%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (48) | (49)
Heart | (50) | (50) | (48) | (48)
Cardiomyopathy | 38 (76%) | 34 (68%) | 33 (69%) | 35 (73%)
Atrium, thrombosis | – | – | – | 1 (2%)
Endocardium, inflammation | 1 (2%) | – | – | 1 (2%)
Myocardium, inflammation | 1 (2%) | – | – | –
Myocardium, mineralization | 1 (2%) | – | – | –
Valve, thrombosis | – | – | – | 1 (2%)
Ventricle, thrombosis | 1 (2%) | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (49) | (50) | (47) | (49)
Degeneration, cystic | – | 2 (4%) | – | –
Degeneration, fatty | – | – | 1 (2%) | –
Hematopoietic cell proliferation | – | 3 (6%) | 1 (2%) | 1 (2%)
Hyperplasia | 7 (14%) | 12 (24%) | 5 (11%) | 1 (2%)
Hypertrophy | 5 (10%) | 10 (20%) | 3 (6%) | 5 (10%)
Infiltration cellular, mononuclear cell | 1 (2%) | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Vacuolization cytoplasmic | – | 2 (4%) | – | –
Adrenal medulla | (50) | (50) | (48) | (49)
Amyloid deposition | – | 1 (2%) | – | –
Hyperplasia | 2 (4%) | 1 (2%) | – | –
Infiltration cellular, mononuclear cell | – | – | 1 (2%) | –
Islets, pancreatic | (49) | (50) | (50) | (48)
Parathyroid gland | (45) | (46) | (41) | (38)
Cyst | 2 (4%) | – | – | 1 (3%)
Pituitary gland | (49) | (49) | (46) | (48)
Angiectasis | 3 (6%) | – | – | –
Cyst | 2 (4%) | 1 (2%) | – | 2 (4%)
Mineralization | 1 (2%) | – | – | –
Pars distalis, hyperplasia | 14 (29%) | 12 (24%) | 8 (17%) | 11 (23%)
Thyroid gland | (49) | (50) | (46) | (45)
Infiltration cellular, mononuclear cell | 1 (2%) | – | 1 (2%) | –
Inflammation | – | 2 (4%) | – | 1 (2%)
C-cell, hyperplasia | – | 2 (4%) | – | 1 (2%)
Follicle, cyst | 1 (2%) | 6 (12%) | 4 (9%) | 3 (7%)
Follicular cell, hyperplasia | – | – | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (47) | (50) | (50) | (48)
Ovary | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Atrophy | – | – | – | 2 (4%)
Cyst | 4 (8%) | 3 (6%) | 5 (10%) | 4 (8%)
Infiltration cellular, mononuclear cell | 1 (2%) | – | – | 1 (2%)
Mineralization | – | – | 1 (2%) | 1 (2%)
Pigmentation, hemosiderin | – | – | 1 (2%) | –
Periovarian tissue, inflammation | – | – | 1 (2%) | –
Uterus | (50) | (50) | (50) | (50)
Angiectasis | 2 (4%) | – | – | –
Infiltration cellular, mononuclear cell | – | – | – | 1 (2%)
Inflammation | 4 (8%) | 2 (4%) | – | 2 (4%)
Mineralization | – | 1 (2%) | – | –
Thrombosis | – | – | 1 (2%) | –
Endometrium, hyperplasia, cystic | 44 (88%) | 45 (90%) | 37 (74%) | 38 (76%)
Endometrium, hyperplasia, reticulum cell | 1 (2%) | – | – | –
Vagina | (0) | (0) | (0) | (1)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)
Hyperplasia | 1 (2%) | – | – | –
Necrosis | – | – | 1 (2%) | –
Lymph node | (2) | (3) | (3) | (5)
Inguinal, hyperplasia | – | – | – | 1 (20%)
Lumbar, hyperplasia, plasma cell | – | 1 (33%) | 1 (33%) | –
Mediastinal, hyperplasia, plasma cell | – | 1 (33%) | – | –
Mediastinal, inflammation | – | – | – | 1 (20%)
Renal, degeneration, cystic | – | 1 (33%) | – | –
Lymph node, mandibular | (48) | (49) | (44) | (45)
Hematopoietic cell proliferation | – | 1 (2%) | – | –
Hyperplasia, lymphoid | 1 (2%) | 2 (4%) | – | –
Inflammation | 1 (2%) | – | – | –
Lymph node, mesenteric | (48) | (50) | (47) | (47)
Degeneration, cystic | – | 1 (2%) | – | –
Hematopoietic cell proliferation | – | 2 (4%) | – | –
Hyperplasia, lymphoid | 1 (2%) | 2 (4%) | 1 (2%) | –
Hyperplasia, plasma cell | – | 3 (6%) | – | –
Inflammation | – | 2 (4%) | 1 (2%) | –
Spleen | (49) | (50) | (50) | (48)
Accessory spleen | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 5 (10%) | 4 (8%) | 2 (4%) | 4 (8%)
Hyperplasia, lymphoid | 16 (33%) | 16 (32%) | 11 (22%) | 10 (21%)
Infarct | 1 (2%) | – | – | –
Necrosis | – | – | – | 1 (2%)
Pigmentation, hemosiderin | 2 (4%) | 4 (8%) | – | –
Thymus | (50) | (50) | (46) | (46)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (50) | (50) | (49) | (50)
Hyperplasia | – | – | 1 (2%) | –
Inflammation | – | – | – | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Inflammation, granulomatous | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | – | – | – | 3 (6%)
Osteopetrosis | – | – | – | 1 (2%)
Maxilla, osteomalacia | 1 (2%) | – | – | –
Vertebra, fibrosis | – | – | 1 (2%) | –
Skeletal muscle | (1) | (2) | (2) | (1)
Nervous System
Brain | (49) | (50) | (47) | (49)
Cyst epithelial inclusion | – | – | 1 (2%) | –
Arteriole, meninges, inflammation | – | – | – | 1 (2%)
Respiratory System
Lung | (50) | (50) | (48) | (48)
Inflammation | 4 (8%) | 5 (10%) | 2 (4%) | 3 (6%)
Thrombosis | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Alveolus, infiltration cellular, histiocyte | 3 (6%) | 2 (4%) | – | 3 (6%)
Perivascular, infiltration cellular, mononuclear cell | – | 4 (8%) | 1 (2%) | 2 (4%)
Nose | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | 1 (2%) | 2 (4%) | – | 1 (2%)
Inflammation | 3 (6%) | 4 (8%) | 7 (14%) | 4 (8%)
Glands, dilatation | 1 (2%) | – | – | –
Glands, hyperplasia | – | – | 1 (2%) | 1 (2%)
Goblet cell, hypertrophy | – | 2 (4%) | – | 1 (2%)
Respiratory epithelium, hyperplasia | 1 (2%) | – | – | 1 (2%)
Trachea | (50) | (50) | (46) | (46)
Inflammation | – | – | – | 1 (2%)
Special Senses System
Eye | (48) | (50) | (46) | (46)
Cataract | 2 (4%) | 1 (2%) | – | –
Cornea, hyperplasia, squamous | – | 1 (2%) | – | –
Cornea, inflammation | 1 (2%) | 3 (6%) | 1 (2%) | –
Retina, dysplasia | 1 (2%) | 1 (2%) | – | –
Retrobulbar, inflammation | – | – | – | 1 (2%)
Harderian gland | (48) | (50) | (46) | (46)
Inflammation | – | – | – | 1 (2%)
Epithelium, hyperplasia | 2 (4%) | 3 (6%) | 1 (2%) | 2 (4%)
Urinary System
Kidney | (50) | (50) | (50) | (49)
Hydronephrosis | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Infarct | 4 (8%) | 2 (4%) | 5 (10%) | 7 (14%)
Infiltration cellular, mononuclear cell | 2 (4%) | – | 2 (4%) | 1 (2%)
Inflammation | 3 (6%) | 4 (8%) | 1 (2%) | 1 (2%)
Metaplasia, osseous | 1 (2%) | 3 (6%) | – | 1 (2%)
Mineralization | – | 2 (4%) | 1 (2%) | –
Nephropathy | 40 (80%) | 38 (76%) | 31 (62%) | 30 (61%)
Glomerulus, amyloid deposition | – | 1 (2%) | 1 (2%) | –
Papilla, necrosis | – | 1 (2%) | – | –
Renal tubule, cyst | 1 (2%) | 1 (2%) | – | –
Renal tubule, hyperplasia | – | 1 (2%) | – | –
Renal tubule, necrosis | 1 (2%) | – | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Infiltration cellular, mononuclear cell | 1 (2%) | – | – | –
Inflammation | – | 2 (4%) | 1 (2%) | –
Transitional epithelium, hyperplasia | – | – | – | 1 (2%)

^a^ Number of core study animals examined microscopically at the site and the number of animals with lesion.

^b^ Pathology data for interim evaluation animals are not presented in this table.