# Appendix C Summary of Lesions in Male Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Disposition Summary
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^b^ | 8 | 8 | 8 | 8
Fourteen-month interim evaluation^b^ | 8 | 8 | 8 | 7
Early deaths
Moribund | 15 | 14 | 27 | 27
Natural deaths | 10 | 15 | 10 | 14
Survivors
Terminal kill | 25 | 21 | 12 | 10
Missing | – | – | 1 | –
Animals examined microscopically | 66 | 66 | 65 | 66
Alimentary System
Esophagus | (50) | (50) | (49) | (51)
Gallbladder | (48) | (49) | (48) | (47)
Intestine large, cecum | (50) | (50) | (49) | (51)
Carcinoma | 1 (2%) | – | – | –
Intestine large, colon | (50) | (50) | (49) | (51)
Intestine large, rectum | (50) | (50) | (49) | (51)
Serosa, hemangiosarcoma, metastatic, liver | – | 1 (2%) | – | –
Intestine small, duodenum | (50) | (50) | (49) | (51)
Adenoma | 1 (2%) | – | 1 (2%) | –
Carcinoma | 1 (2%) | 1 (2%) | – | –
Intestine small, ileum | (50) | (50) | (49) | (51)
Intestine small, jejunum | (50) | (50) | (49) | (51)
Carcinoma | 1 (2%) | 3 (6%) | – | 2 (4%)
Liver | (50) | (50) | (49) | (51)
Cholangiocarcinoma | – | – | – | 1 (2%)
Hemangioma | – | – | 1 (2%) | –
Hemangiosarcoma | 1 (2%) | 4 (8%) | 2 (4%) | 4 (8%)
Hemangiosarcoma, metastatic, spleen | 1 (2%) | – | 1 (2%) | –
Hepatoblastoma | 3 (6%) | 18 (36%) | 28 (57%) | 22 (43%)
Hepatoblastoma, multiple | 1 (2%) | 6 (12%) | 12 (24%) | 12 (24%)
Hepatocellular adenoma | 11 (22%) | 12 (24%) | 15 (31%) | 17 (33%)
Hepatocellular adenoma, multiple | 28 (56%) | 29 (58%) | 27 (55%) | 23 (45%)
Hepatocellular carcinoma | 8 (16%) | 10 (20%) | 17 (35%) | 22 (43%)
Hepatocellular carcinoma, multiple | 4 (8%) | 12 (24%) | 10 (20%) | 17 (33%)
Hepatocholangiocarcinoma | – | – | 2 (4%) | 2 (4%)
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Mesentery | (7) | (1) | (3) | (6)
Carcinoma, metastatic, uncertain primary site | – | – | – | 1 (17%)
Fibrous histiocytoma | – | – | – | 1 (17%)
Hepatoblastoma, metastatic, liver | – | – | 1 (33%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (33%) | –
Lipoma | 1 (14%) | – | – | –
Pancreas | (50) | (50) | (49) | (51)
Sarcoma | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (49) | (51)
Stomach, forestomach | (50) | (50) | (49) | (51)
Squamous cell papilloma | – | 1 (2%) | – | 1 (2%)
Stomach, glandular | (50) | (50) | (49) | (51)
Tooth | (35) | (22) | (13) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (49) | (51)
Heart | (50) | (50) | (49) | (51)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 2 (4%) | –
Schwannoma malignant | – | 1 (2%) | – | –
Pericardium, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (50)
Subcapsular, adenoma | 2 (4%) | – | 1 (2%) | –
Adrenal medulla | (50) | (50) | (49) | (50)
Islets, pancreatic | (50) | (50) | (49) | (51)
Parathyroid gland | (44) | (45) | (44) | (44)
Pituitary gland | (50) | (49) | (49) | (51)
Thyroid gland | (50) | (50) | (49) | (51)
Follicular cell, adenoma | 1 (2%) | – | 1 (2%) | –
General Body System
Peritoneum | (0) | (0) | (0) | (1)
Genital System
Epididymis | (50) | (50) | (49) | (51)
Fibrous histiocytoma, metastatic, mesentery | – | – | – | 1 (2%)
Penis | (0) | (1) | (0) | (0)
Preputial gland | (50) | (50) | (49) | (51)
Prostate | (50) | (50) | (49) | (51)
Seminal vesicle | (50) | (50) | (49) | (51)
Fibrous histiocytoma, metastatic, mesentery | – | – | – | 1 (2%)
Testes | (50) | (50) | (49) | (51)
Interstitial cell, adenoma | 1 (2%) | – | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (49) | (51)
Hemangiosarcoma | – | – | – | 1 (2%)
Hemangiosarcoma, metastatic, liver | – | 1 (2%) | – | –
Hemangiosarcoma, metastatic, spleen | 1 (2%) | – | 2 (4%) | –
Lymph node | (0) | (1) | (2) | (5)
Mediastinal, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (50%) | –
Pancreatic, carcinoma, metastatic, uncertain primary site | – | – | – | 1 (20%)
Pancreatic, hepatoblastoma, metastatic, liver | – | – | – | 1 (20%)
Pancreatic, hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (20%)
Lymph node, mandibular | (50) | (50) | (49) | (51)
Lymph node, mesenteric | (50) | (48) | (48) | (48)
Carcinoma, metastatic, uncertain primary site | – | – | – | 1 (2%)
Hepatoblastoma, metastatic, liver | – | 1 (2%) | – | –
Spleen | (50) | (50) | (49) | (50)
Hemangiosarcoma | 2 (4%) | – | 2 (4%) | –
Thymus | (45) | (45) | (45) | (44)
Fibrous histiocytoma, metastatic, mesentery | – | – | – | 1 (2%)
Osteosarcoma, metastatic, bone | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Thymoma benign | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (5) | (3) | (4) | (7)
Skin | (50) | (50) | (49) | (51)
Fibrous histiocytoma | 1 (2%) | 1 (2%) | – | 1 (2%)
Fibrous histiocytoma, metastatic, mesentery | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | 1 (2%) | – | –
Hemangiosarcoma, metastatic, spleen | 1 (2%) | – | – | –
Lipoma | 1 (2%) | – | – | –
Squamous cell papilloma | – | 1 (2%) | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (49) | (51)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Osteoma | – | – | 1 (2%) | –
Osteosarcoma | – | 1 (2%) | – | –
Skeletal muscle | (0) | (2) | (2) | (2)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (50%) | –
Carcinoma, metastatic, uncertain primary site | – | – | – | 1 (50%)
Hepatoblastoma | – | – | – | 1 (50%)
Hepatoblastoma, metastatic, liver | – | 1 (50%) | – | 1 (50%)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (50%) | –
Osteosarcoma, metastatic, bone | – | 1 (50%) | – | –
Nervous System
Brain | (50) | (50) | (49) | (51)
Meningioma malignant | 1 (2%) | – | – | –
Peripheral nerve | (2) | (1) | (0) | (0)
Spinal cord | (2) | (1) | (0) | (0)
Respiratory System
Lung | (50) | (50) | (49) | (51)
Alveolar/bronchiolar adenoma | 11 (22%) | 14 (28%) | 8 (16%) | 2 (4%)
Alveolar/bronchiolar adenoma, multiple | 2 (4%) | – | 1 (2%) | –
Alveolar/bronchiolar carcinoma | 7 (14%) | 10 (20%) | 4 (8%) | 2 (4%)
Alveolar/bronchiolar carcinoma, multiple | – | 1 (2%) | 1 (2%) | –
Hepatoblastoma, metastatic, liver | – | 3 (6%) | 12 (24%) | 5 (10%)
Hepatocellular carcinoma, metastatic, liver | 8 (16%) | 11 (22%) | 5 (10%) | 15 (29%)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Osteosarcoma, metastatic, bone | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, heart | – | 1 (2%) | – | –
Nose | (50) | (50) | (49) | (51)
Glands, olfactory epithelium, adenoma | – | 1 (2%) | – | –
Trachea | (50) | (50) | (49) | (51)
Special Senses System
Eye | (50) | (50) | (49) | (51)
Iris, melanoma malignant | 1 (2%) | – | – | –
Harderian gland | (50) | (50) | (49) | (51)
Adenoma | 6 (12%) | 11 (22%) | 14 (29%) | 19 (37%)
Carcinoma | – | – | – | 3 (6%)
Urinary System
Kidney | (50) | (50) | (49) | (51)
Adenoma | 2 (4%) | 2 (4%) | – | 2 (4%)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Carcinoma, metastatic, uncertain primary site | – | – | – | 1 (2%)
Ureter | (1) | (0) | (0) | (0)
Urethra | (1) | (0) | (0) | (0)
Hemangiosarcoma | 1 (100%) | – | – | –
Urinary bladder | (50) | (50) | (49) | (51)
Systemic Lesions
Multiple organs^c^ | (50) | (50) | (49) | (51)
Histiocytic sarcoma | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Leukemia lymphocytic | – | – | 1 (2%) | –
Lymphoma malignant | – | – | 1 (2%) | 1 (2%)
Mesothelioma malignant | 1 (2%) | – | – | 3 (6%)
Neoplasm Summary
Total animals with primary neoplasms^d^ | 48 | 50 | 49 | 51
Total primary neoplasms | 103 | 142 | 152 | 161
Total animals with benign neoplasms | 43 | 44 | 46 | 44
Total benign neoplasms | 67 | 72 | 70 | 65
Total animals with malignant neoplasms | 30 | 42 | 49 | 47
Total malignant neoplasms | 36 | 70 | 82 | 96
Total animals with metastatic neoplasms | 10 | 17 | 20 | 21
Total metastatic neoplasms | 12 | 25 | 30 | 38
Total animals with malignant neoplasms of uncertain primary site | 1 | – | – | 1

^a^ Number of core study animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Pathology data for interim evaluation animals are not presented in this table.

^c^ Number of animals with any tissue examined microscopically.

^d^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Harderian Gland: Adenoma
Overall rate^a^ | 6/50 (12%) | 11/50 (22%) | 14/49 (29%) | 19/51 (37%)
Adjusted rate^b^ | 14.7% | 26.1% | 38.0% | 48.8%
Terminal rate^c^ | 2/25 (8%) | 4/21 (19%) | 5/12 (42%) | 3/10 (30%)
First incidence (days) | 548 | 533 | 491 | 458
Poly-3 test^d^ | P < 0.001 | P = 0.155 | P = 0.015 | P < 0.001
Harderian Gland: Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/49 (0%) | 3/51 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 9.3%
Terminal rate | 0/25 (0%) | 0/21 (0%) | 0/12 (0%) | 2/10 (20%)
First incidence (days) | –^e^ | – | – | 624
Poly-3 test | P = 0.008 | –^f^ | – | P = 0.087
Harderian Gland: Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 11/50 (22%) | 14/49 (29%) | 20/51 (39%)
Adjusted rate | 14.7% | 26.1% | 38.0% | 51.4%
Terminal rate | 2/25 (8%) | 4/21 (19%) | 5/12 (42%) | 4/10 (40%)
First incidence (days) | 548 | 533 | 491 | 458
Poly-3 test | P < 0.001 | P = 0.155 | P = 0.015 | P < 0.001
Small Intestine (Jejunum): Carcinoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/49 (0%) | 2/51 (4%)
Adjusted rate | 2.5% | 7.3% | 0.0% | 6.2%
Terminal rate | 0/25 (0%) | 1/21 (5%) | 0/12 (0%) | 0/10 (0%)
First incidence (days) | 548 | 581 | – | 618
Poly-3 test | P = 0.470 | P = 0.317 | P = 0.538N | P = 0.431
Small Intestine (Duodenum or Jejunum): Carcinoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 0/49 (0%) | 2/51 (4%)
Adjusted rate | 5.1% | 9.7% | 0.0% | 6.2%
Terminal rate | 0/25 (0%) | 1/21 (5%) | 0/12 (0%) | 0/10 (0%)
First incidence (days) | 548 | 581 | – | 618
Poly-3 test | P = 0.484N | P = 0.355 | P = 0.283N | P = 0.619
Small Intestine (Duodenum or Jejunum): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 1/49 (2%) | 2/51 (4%)
Adjusted rate | 7.6% | 9.7% | 3.1% | 6.2%
Terminal rate | 1/25 (4%) | 1/21 (5%) | 1/12 (8%) | 0/10 (0%)
First incidence (days) | 548 | 581 | 730 (T) | 618
Poly-3 test | P = 0.382N | P = 0.522 | P = 0.378N | P = 0.592N
Liver: Hemangiosarcoma
Overall rate | 1/50 (2%) | 4/50 (8%) | 2/49 (4%) | 4/51 (8%)
Adjusted rate | 2.6% | 9.7% | 6.1% | 12.3%
Terminal rate | 1/25 (4%) | 1/21 (5%) | 1/12 (8%) | 1/10 (10%)
First incidence (days) | 730 (T) | 609 | 603 | 600
Poly-3 test | P = 0.139 | P = 0.196 | P = 0.443 | P = 0.128
Liver: Hepatocellular Adenoma
Overall rate | 39/50 (78%) | 41/50 (82%) | 42/49 (86%) | 40/51 (78%)
Adjusted rate | 87.2% | 89.8% | 90.9% | 91.3%
Terminal rate | 25/25 (100%) | 20/21 (95%) | 10/12 (83%) | 10/10 (100%)
First incidence (days) | 449 | 434 | 477 | 322
Poly-3 test | P = 0.288 | P = 0.471 | P = 0.388 | P = 0.355
Liver: Hepatocellular Carcinoma
Overall rate | 12/50 (24%) | 22/50 (44%) | 27/49 (55%) | 39/51 (76%)
Adjusted rate | 29.3% | 49.5% | 66.1% | 87.1%
Terminal rate | 7/25 (28%) | 8/21 (38%) | 7/12 (58%) | 8/10 (80%)
First incidence (days) | 548 | 511 | 480 | 260
Poly-3 test | P < 0.001 | P = 0.041 | P < 0.001 | P < 0.001
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 42/50 (84%) | 47/50 (94%) | 46/49 (94%) | 48/51 (94%)
Adjusted rate | 91.2% | 97.7% | 96.5% | 98.1%
Terminal rate | 25/25 (100%) | 21/21 (100%) | 11/12 (92%) | 10/10 (100%)
First incidence (days) | 449 | 434 | 477 | 260
Poly-3 test | P = 0.071 | P = 0.109 | P = 0.211 | P = 0.081
Liver: Hepatoblastoma
Overall rate | 4/50 (8%) | 24/50 (48%) | 40/49 (82%) | 34/51 (67%)
Adjusted rate | 10.1% | 53.6% | 87.1% | 77.5%
Terminal rate | 1/25 (4%) | 8/21 (38%) | 9/12 (75%) | 5/10 (50%)
First incidence (days) | 590 | 433 | 477 | 360
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 15/50 (30%) | 34/50 (68%) | 48/49 (98%) | 45/51 (88%)
Adjusted rate | 36.1% | 71.9% | 98.0% | 95.5%
Terminal rate | 8/25 (32%) | 11/21 (52%) | 11/12 (92%) | 9/10 (90%)
First incidence (days) | 548 | 433 | 477 | 260
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 42/50 (84%) | 50/50 (100%) | 48/49 (98%) | 49/51 (96%)
Adjusted rate | 91.2% | 100.0% | 98.0% | 99.1%
Terminal rate | 25/25 (100%) | 21/21 (100%) | 11/12 (92%) | 10/10 (100%)
First incidence (days) | 449 | 433 | 477 | 260
Poly-3 test | P = 0.036 | P = 0.015 | P = 0.110 | P = 0.034
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 13/50 (26%) | 14/50 (28%) | 9/49 (18%) | 2/51 (4%)
Adjusted rate | 31.5% | 32.7% | 24.9% | 6.1%
Terminal rate | 7/25 (28%) | 6/21 (29%) | 1/12 (8%) | 0/10 (0%)
First incidence (days) | 578 | 434 | 498 | 458
Poly-3 test | P = 0.005N | P = 0.547 | P = 0.344N | P = 0.006N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 7/50 (14%) | 11/50 (22%) | 5/49 (10%) | 2/51 (4%)
Adjusted rate | 17.9% | 26.6% | 14.6% | 6.2%
Terminal rate | 5/25 (20%) | 6/21 (29%) | 2/12 (17%) | 1/10 (10%)
First incidence (days) | 688 | 511 | 480 | 625
Poly-3 test | P = 0.058N | P = 0.253 | P = 0.474N | P = 0.130N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 19/50 (38%) | 25/50 (50%) | 13/49 (27%) | 4/51 (8%)
Adjusted rate | 45.8% | 56.5% | 34.3% | 12.0%
Terminal rate | 11/25 (44%) | 12/21 (57%) | 2/12 (17%) | 1/10 (10%)
First incidence (days) | 578 | 434 | 480 | 458
Poly-3 test | P < 0.001N | P = 0.212 | P = 0.199N | P < 0.001N
All Organs: Hemangiosarcoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 4/49 (8%) | 5/51 (10%)
Adjusted rate | 12.6% | 12.1% | 11.7% | 15.3%
Terminal rate | 2/25 (8%) | 1/21 (5%) | 1/12 (8%) | 2/10 (20%)
First incidence (days) | 626 | 609 | 499 | 600
Poly-3 test | P = 0.428 | P = 0.604N | P = 0.591N | P = 0.504
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 5/49 (10%) | 5/51 (10%)
Adjusted rate | 12.6% | 12.1% | 14.6% | 15.3%
Terminal rate | 2/25 (8%) | 1/21 (5%) | 2/12 (17%) | 2/10 (20%)
First incidence (days) | 626 | 609 | 499 | 600
Poly-3 test | P = 0.398 | P = 0.604N | P = 0.538 | P = 0.504
All Organs: Malignant Mesothelioma
Overall rate | 1/50 (2%) | 0/50 (0%) | 0/49 (0%) | 3/51 (6%)
Adjusted rate | 2.6% | 0.0% | 0.0% | 9.1%
Terminal rate | 1/25 (4%) | 0/21 (0%) | 0/12 (0%) | 0/10 (0%)
First incidence (days) | 730 (T) | – | – | 521
Poly-3 test | P = 0.071 | P = 0.494N | P = 0.535N | P = 0.249
All Organs: Benign Neoplasms
Overall rate | 43/50 (86%) | 44/50 (88%) | 46/49 (94%) | 44/51 (86%)
Adjusted rate | 92.8% | 93.8% | 96.0% | 94.3%
Terminal rate | 25/25 (100%) | 20/21 (95%) | 11/12 (92%) | 10/10 (100%)
First incidence (days) | 449 | 434 | 477 | 322
Poly-3 test | P = 0.435 | P = 0.612 | P = 0.398 | P = 0.570
All Organs: Malignant Neoplasms
Overall rate | 30/50 (60%) | 42/50 (84%) | 49/49 (100%) | 47/51 (92%)
Adjusted rate | 66.7% | 85.6% | 100.0% | 98.2%
Terminal rate | 14/25 (56%) | 15/21 (71%) | 12/12 (100%) | 10/10 (100%)
First incidence (days) | 449 | 433 | 477 | 260
Poly-3 test | P < 0.001 | P = 0.021 | P < 0.001 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 48/50 (96%) | 50/50 (100%) | 49/49 (100%) | 51/51 (100%)
Adjusted rate | 98.3% | 100.0% | 100.0% | 100.0%
Terminal rate | 25/25 (100%) | 21/21 (100%) | 12/12 (100%) | 10/10 (100%)
First incidence (days) | 449 | 433 | 477 | 260
Poly-3 test | P = 0.307 | P = 0.604 | P = 0.609 | P = 0.599

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table C-3 Historical Incidence of Liver Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Carcinoma | Hepatoblastoma
Historical Incidence: Drinking Water Studies
β-Picoline (November 2004) | 26/50 | 6/50
Bromodichloroacetic acid (September 2006) | 12/50 | 4/50
Total (%) | 38/100 (38.0%) | 10/100 (10.0%)
Mean ± standard deviation | 38.0% ± 19.8% | 10.0% ± 2.8%
Range | 24%–52% | 8%–12%
Overall Historical Incidence: All Routes
Total (%) | 348/949 (36.7%) | 40/949 (4.2%)
Mean ± standard deviation | 36.7% ± 11.4% | 4.2% ± 3.5%
Range | 22%–56% | 0%–12%

^a^ Data as of June 2013.

Table C-4 Historical Incidence of Harderian Gland Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma or Carcinoma
Historical Incidence: Drinking Water Studies
β-Picoline (November 2004) | 7/50
Bromodichloroacetic acid (September 2006) | 6/50
Total (%) | 13/100 (13.0%)
Mean ± standard deviation | 13.0% ± 1.4%
Range | 12%–14%
Overall Historical Incidence: All Routes
Total (%) | 153/950 (16.1%)
Mean ± standard deviation | 16.1% ± 4.9%
Range | 6%–24%

^a^ Data as of June 2013.

Table C-5 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Disposition Summary
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^b^ | 8 | 8 | 8 | 8
Fourteen-month interim evaluation^b^ | 8 | 8 | 8 | 7
Early deaths
Moribund | 15 | 14 | 27 | 27
Natural deaths | 10 | 15 | 10 | 14
Survivors
Terminal kill | 25 | 21 | 12 | 10
Missing | – | – | 1 | –
Animals examined microscopically | 66 | 66 | 65 | 66
Alimentary System
Esophagus | (50) | (50) | (49) | (51)
Gallbladder | (48) | (49) | (48) | (47)
Intestine large, cecum | (50) | (50) | (49) | (51)
Lymphoid tissue, hyperplasia | – | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (49) | (51)
Epithelium, hyperplasia | – | 1 (2%) | – | –
Intestine large, rectum | (50) | (50) | (49) | (51)
Intestine small, duodenum | (50) | (50) | (49) | (51)
Intestine small, ileum | (50) | (50) | (49) | (51)
Inflammation | 3 (6%) | 1 (2%) | – | –
Epithelium, hyperplasia | 2 (4%) | – | – | –
Muscularis, hyperplasia | 1 (2%) | – | – | –
Intestine small, jejunum | (50) | (50) | (49) | (51)
Inflammation | 1 (2%) | – | – | 2 (4%)
Peyer’s patch, hyperplasia, lymphoid | – | 2 (4%) | – | 1 (2%)
Liver | (50) | (50) | (49) | (51)
Amyloid deposition | – | – | 1 (2%) | –
Angiectasis | 1 (2%) | – | 1 (2%) | 1 (2%)
Basophilic focus | 1 (2%) | 2 (4%) | 6 (12%) | 3 (6%)
Clear cell focus | 18 (36%) | 14 (28%) | 4 (8%) | 14 (27%)
Congestion | – | – | – | 1 (2%)
Eosinophilic focus | 30 (60%) | 33 (66%) | 30 (61%) | 16 (31%)
Fatty change | 11 (22%) | 1 (2%) | – | 4 (8%)
Fatty change, focal | – | 1 (2%) | – | –
Focus of cellular alteration, atypical | – | 19 (38%) | 42 (86%) | 43 (84%)
Hematopoietic cell proliferation | 1 (2%) | – | 1 (2%) | –
Infarct | – | 1 (2%) | 1 (2%) | 1 (2%)
Infiltration cellular, mixed cell | – | – | – | 1 (2%)
Inflammation | 7 (14%) | 6 (12%) | 3 (6%) | 4 (8%)
Mineralization | – | – | 1 (2%) | –
Mixed cell focus | 13 (26%) | 6 (12%) | 4 (8%) | 5 (10%)
Tension lipidosis | 3 (6%) | 1 (2%) | – | –
Bile duct, cyst | – | 1 (2%) | – | 1 (2%)
Capsule, fibrosis | – | – | – | 1 (2%)
Centrilobular, fatty change | – | – | 1 (2%) | 1 (2%)
Hepatocyte, necrosis | 5 (10%) | 9 (18%) | 10 (20%) | 8 (16%)
Oval cell, hyperplasia | 1 (2%) | – | 3 (6%) | –
Mesentery | (7) | (1) | (3) | (6)
Inflammation | – | – | – | 1 (17%)
Necrosis | 5 (71%) | 1 (100%) | 1 (33%) | 2 (33%)
Pancreas | (50) | (50) | (49) | (51)
Amyloid deposition | 1 (2%) | – | – | –
Fibrosis | – | – | – | 1 (2%)
Acinus, atrophy | 2 (4%) | – | – | –
Acinus, hyperplasia | – | 1 (2%) | 1 (2%) | –
Duct, cyst | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (49) | (51)
Hyperplasia | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (49) | (51)
Inflammation | 1 (2%) | 1 (2%) | – | 1 (2%)
Ulcer | 3 (6%) | 1 (2%) | 1 (2%) | 2 (4%)
Epithelium, hyperplasia | 2 (4%) | – | 1 (2%) | 1 (2%)
Stomach, glandular | (50) | (50) | (49) | (51)
Amyloid deposition | – | – | 3 (6%) | 1 (2%)
Erosion | – | – | – | 1 (2%)
Inflammation | 1 (2%) | – | – | –
Mineralization | 1 (2%) | – | – | –
Ulcer | – | – | 2 (4%) | –
Epithelium, hyperplasia | 2 (4%) | – | – | –
Glands, ectasia | – | 1 (2%) | – | 1 (2%)
Tooth | (35) | (22) | (13) | (0)
Dysplasia | 1 (3%) | – | – | –
Malformation | 34 (97%) | 20 (91%) | 13 (100%) | –
Peridontal tissue, fibrosis | – | 2 (9%) | – | –
Peridontal tissue, inflammation | – | 1 (5%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (49) | (51)
Aorta, inflammation | – | – | – | 1 (2%)
Aorta, mineralization | – | – | 1 (2%) | 1 (2%)
Heart | (50) | (50) | (49) | (51)
Cardiomyopathy | 31 (62%) | 41 (82%) | 30 (61%) | 33 (65%)
Arteriole, hyperplasia | 1 (2%) | – | – | –
Arteriole, inflammation | 1 (2%) | 1 (2%) | – | –
Artery, inflammation | – | – | – | 1 (2%)
Artery, mineralization | – | – | 1 (2%) | –
Atrium, thrombosis | 2 (4%) | – | 1 (2%) | –
Endocardium, inflammation | – | – | – | 1 (2%)
Epicardium, fibrosis | 1 (2%) | – | – | –
Myocardium, mineralization | 1 (2%) | – | 1 (2%) | 2 (4%)
Valve, inflammation | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (50)
Angiectasis | – | 1 (2%) | – | 1 (2%)
Hyperplasia | – | 2 (4%) | – | 1 (2%)
Hypertrophy | 14 (28%) | 21 (42%) | 9 (18%) | 9 (18%)
Necrosis | – | – | – | 1 (2%)
Subcapsular, hyperplasia | – | – | 1 (2%) | –
Adrenal medulla | (50) | (50) | (49) | (50)
Angiectasis | 1 (2%) | – | – | –
Hyperplasia | – | 1 (2%) | 1 (2%) | 1 (2%)
Mineralization | – | – | – | 1 (2%)
Necrosis | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (49) | (51)
Parathyroid gland | (44) | (45) | (44) | (44)
Pituitary gland | (50) | (49) | (49) | (51)
Cyst | – | 5 (10%) | – | 2 (4%)
Pars distalis, hyperplasia | 1 (2%) | 2 (4%) | 4 (8%) | –
Thyroid gland | (50) | (50) | (49) | (51)
Cyst | – | 1 (2%) | – | –
C-cell, hyperplasia | – | 1 (2%) | – | –
Follicle, cyst | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%)
Follicular cell, hyperplasia | – | – | 1 (2%) | –
General Body System
Peritoneum | (0) | (0) | (0) | (1)
Genital System
Epididymis | (50) | (50) | (49) | (51)
Atrophy | – | 7 (14%) | 10 (20%) | 17 (33%)
Granuloma sperm | – | – | – | 1 (2%)
Hypospermia | – | 1 (2%) | – | 17 (33%)
Inflammation | 2 (4%) | 1 (2%) | 1 (2%) | –
Epithelium, degeneration | 1 (2%) | 1 (2%) | 10 (20%) | 6 (12%)
Mesothelium, hyperplasia | – | – | 1 (2%) | 1 (2%)
Penis | (0) | (1) | (0) | (0)
Hyperplasia, squamous | – | 1 (100%) | – | –
Preputial gland | (50) | (50) | (49) | (51)
Atrophy | – | 1 (2%) | – | –
Inflammation | 7 (14%) | 4 (8%) | 3 (6%) | 8 (16%)
Duct, ectasia | 6 (12%) | 6 (12%) | 5 (10%) | 10 (20%)
Prostate | (50) | (50) | (49) | (51)
Atrophy | – | – | – | 1 (2%)
Inflammation | 3 (6%) | 3 (6%) | 1 (2%) | 2 (4%)
Arteriole, inflammation | – | – | – | 1 (2%)
Seminal vesicle | (50) | (50) | (49) | (51)
Atrophy | – | 1 (2%) | – | 1 (2%)
Dilatation | 1 (2%) | 1 (2%) | 1 (2%) | –
Inflammation | 2 (4%) | 2 (4%) | 3 (6%) | 1 (2%)
Testes | (50) | (50) | (49) | (51)
Atrophy | 4 (8%) | 6 (12%) | 13 (27%) | 23 (45%)
Fibrosis | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (49) | (51)
Angiectasis | – | – | – | 2 (4%)
Hyperplasia | – | 2 (4%) | – | –
Necrosis | – | 1 (2%) | – | –
Lymph node | (0) | (1) | (2) | (5)
Axillary, hyperplasia, plasma cell | – | – | – | 1 (20%)
Lumbar, hyperplasia, lymphoid | – | 1 (100%) | – | –
Lumbar, hyperplasia, plasma cell | – | 1 (100%) | – | 1 (20%)
Lumbar, inflammation, suppurative | – | – | – | 1 (20%)
Renal, hyperplasia, plasma cell | – | – | – | 1 (20%)
Lymph node, mandibular | (50) | (50) | (49) | (51)
Degeneration, cystic | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Hyperplasia, plasma cell | 3 (6%) | 1 (2%) | – | 1 (2%)
Lymph node, mesenteric | (50) | (48) | (48) | (48)
Hematopoietic cell proliferation | – | 1 (2%) | – | –
Hemorrhage | – | – | – | 2 (4%)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Hyperplasia, plasma cell | 2 (4%) | 4 (8%) | – | 1 (2%)
Necrosis, lymphoid | – | – | – | 1 (2%)
Spleen | (50) | (50) | (49) | (50)
Atrophy | – | – | 3 (6%) | 1 (2%)
Hematopoietic cell proliferation | 1 (2%) | 3 (6%) | 5 (10%) | 4 (8%)
Hyperplasia, lymphoid | 4 (8%) | 7 (14%) | 5 (10%) | 5 (10%)
Infarct | – | – | 1 (2%) | –
Thymus | (45) | (45) | (45) | (44)
Atrophy | – | 1 (2%) | – | –
Mineralization | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (5) | (3) | (4) | (7)
Skin | (50) | (50) | (49) | (51)
Inflammation, suppurative | – | – | 1 (2%) | –
Ulcer | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Dermis, fibrosis | – | 1 (2%) | – | –
Epidermis, hyperplasia | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (49) | (51)
Cranium, periosteum, fibrosis | – | – | – | 1 (2%)
Femur, osteopetrosis | – | 1 (2%) | – | –
Skeletal muscle | (0) | (2) | (2) | (2)
Nervous System
Brain | (50) | (50) | (49) | (51)
Cerebrum, demyelination | – | – | 1 (2%) | –
Peripheral nerve | (2) | (1) | (0) | (0)
Degeneration | 1 (50%) | 1 (100%) | – | –
Spinal cord | (2) | (1) | (0) | (0)
Demyelination | – | 1 (100%) | – | –
Respiratory System
Lung | (50) | (50) | (49) | (51)
Inflammation | 1 (2%) | – | 3 (6%) | 4 (8%)
Thrombosis | 1 (2%) | 2 (4%) | – | 2 (4%)
Alveolar epithelium, hyperplasia | 2 (4%) | 2 (4%) | 4 (8%) | 4 (8%)
Alveolus, infiltration cellular, histiocyte | – | 1 (2%) | 4 (8%) | 1 (2%)
Capillary, thrombosis | – | – | – | 1 (2%)
Perivascular, infiltration cellular, mononuclear cell | 1 (2%) | – | – | –
Vein, mineralization | – | – | 1 (2%) | –
Nose | (50) | (50) | (49) | (51)
Inflammation | 5 (10%) | 9 (18%) | 7 (14%) | 9 (18%)
Glands, dilatation | – | – | 1 (2%) | –
Glands, fibrosis | – | – | 1 (2%) | –
Glands, hyperplasia | – | 3 (6%) | 2 (4%) | –
Respiratory epithelium, hyperplasia | – | 1 (2%) | – | –
Respiratory epithelium, metaplasia | – | 1 (2%) | – | –
Turbinate, fibrosis, focal | – | – | – | 1 (2%)
Trachea | (50) | (50) | (49) | (51)
Inflammation | – | – | – | 1 (2%)
Peritracheal tissue, cyst | 1 (2%) | – | – | –
Special Senses System
Eye | (50) | (50) | (49) | (51)
Cataract | 1 (2%) | – | 1 (2%) | 1 (2%)
Phthisis bulbi | – | – | – | 2 (4%)
Synechia | 1 (2%) | – | – | 1 (2%)
Cornea, inflammation | – | 2 (4%) | 2 (4%) | 1 (2%)
Optic nerve, degeneration | 1 (2%) | 1 (2%) | – | –
Retina, dysplasia | 1 (2%) | 1 (2%) | 1 (2%) | –
Harderian gland | (50) | (50) | (49) | (51)
Inflammation | – | – | – | 1 (2%)
Epithelium, hyperplasia | 1 (2%) | 1 (2%) | 3 (6%) | 4 (8%)
Urinary System
Kidney | (50) | (50) | (49) | (51)
Atrophy, diffuse | – | – | – | 1 (2%)
Casts protein | – | – | – | 1 (2%)
Hydronephrosis | 2 (4%) | – | 1 (2%) | 1 (2%)
Infarct | 3 (6%) | 3 (6%) | – | 5 (10%)
Infiltration cellular, mononuclear cell | – | 1 (2%) | – | 2 (4%)
Inflammation | 3 (6%) | 4 (8%) | 2 (4%) | 3 (6%)
Metaplasia, osseous | – | 3 (6%) | – | –
Mineralization | 2 (4%) | 1 (2%) | 1 (2%) | –
Nephropathy | 49 (98%) | 47 (94%) | 45 (92%) | 42 (82%)
Papilla, necrosis | 1 (2%) | – | 1 (2%) | –
Renal tubule, cyst | 4 (8%) | 3 (6%) | 1 (2%) | –
Renal tubule, hyperplasia | – | 2 (4%) | – | –
Ureter | (1) | (0) | (0) | (0)
Urethra | (1) | (0) | (0) | (0)
Urinary bladder | (50) | (50) | (49) | (51)
Infiltration cellular, mononuclear cell | – | – | – | 1 (2%)
Inflammation | 2 (4%) | – | – | 1 (2%)
Metaplasia, squamous | 1 (2%) | – | – | –
Transitional epithelium, hyperplasia | – | – | – | 1 (2%)

^a^ Number of core study animals examined microscopically at the site and the number of animals with lesion.

^b^ Pathology data for interim evaluation animals are not presented in this table.