# Appendix B Summary of Lesions in Female F344/NTac Rats in the Two-year Drinking Water Study of Bromodicholoroacetic Acid

Table B-1 Summary of the Incidence of Neoplasms in Female F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Disposition Summary
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^b^ | 8 | 8 | 8 | 8
Thirteen-month interim evaluation^b^ | 8 | 8 | 8 | 8
Early deaths
Moribund | 10 | 22 | 42 | 44
Natural deaths | 6 | 2 | 1 | 4
Survivors
Terminal kill | 34 | 26 | 7 | 2
Animals examined microscopically | 66 | 66 | 66 | 66
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 2 (4%)
Intestine large, rectum | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | 1 (2%) | –
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Sarcoma | – | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50)
Hemangioma | 1 (2%) | – | – | –
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatocellular adenoma | – | – | 2 (4%) | 1 (2%)
Mesentery | (3) | (4) | (3) | (2)
Oral mucosa | (0) | (0) | (0) | (1)
Pharyngeal, squamous cell papilloma | – | – | – | 1 (100%)
Pancreas | (50) | (50) | (50) | (50)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (50) | (50) | (50) | (50)
Squamous cell carcinoma | – | – | 1 (2%) | –
Squamous cell papilloma | – | 2 (4%) | – | 1 (2%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Schwannoma malignant | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Pheochromocytoma benign, multiple | – | – | – | 1 (2%)
Pheochromocytoma malignant | 1 (2%) | 1 (2%) | | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Carcinoma | – | 1 (2%) | – | –
Parathyroid gland | (47) | (46) | (49) | (49)
Pituitary gland | (50) | (50) | (49) | (50)
Pars distalis, adenoma | 23 (46%) | 20 (40%) | 11 (22%) | 11 (22%)
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, adenoma | 11 (22%) | 10 (20%) | 6 (12%) | 7 (14%)
C-cell, carcinoma | – | – | 1 (2%)
Follicular cell, adenoma | – | – | 1 (2%) | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (49) | (49) | (48)
Adenoma | 7 (14%) | 11 (22%) | 8 (16%) | 7 (15%)
Carcinoma | 1 (2%) | – | – | –
Bilateral, adenoma | 1 (2%) | – | – | –
Ovary | (50) | (50) | (50) | (50)
Granulosa cell tumor malignant | – | – | 1 (2%) | –
Hemangiosarcoma | – | – | 1 (2%) | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | – | 1 (2%)
Uterus | (50) | (50) | (50) | (50)
Deciduoma NOS | 1 (2%) | – | – | –
Fibrous histiocytoma | 1 (2%) | – | – | –
Leiomyosarcoma | 1 (2%) | – | – | –
Polyp stromal | 3 (6%) | 6 (12%) | 8 (16%) | 5 (10%)
Polyp stromal, multiple | 1 (2%) | – | – | –
Sarcoma stromal | 1 (2%) | – | – | 1 (2%)
Cervix, granular cell tumor NOS | – | – | 1 (2%) | –
Cervix, hemangiosarcoma | – | – | 1 (2%) | –
Endometrium, adenoma | – | 1 (2%) | – | –
Endometrium, carcinoma | – | – | – | 1 (2%)
Vagina | (1) | (0) | (0) | (0)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (4) | (4) | (2) | (2)
Lymph node, mandibular | (50) | (50) | (50) | (50)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Thymus | (48) | (49) | (47) | (48)
Thymoma malignant | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Carcinoma | – | 1 (2%) | 3 (6%) | 8 (16%)
Fibroadenoma | 22 (44%) | 13 (26%) | 10 (20%) | 12 (24%)
Fibroadenoma, multiple | 6 (12%) | 34 (68%) | 37 (74%) | 27 (54%)
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | – | – | – | 1 (2%)
Subcutaneous tissue, fibroma | 2 (4%) | – | 3 (6%) | 2 (4%)
Subcutaneous tissue, lipoma | 2 (4%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (0) | (1) | (0) | (0)
Rhabdomyosarcoma | – | 1 (100%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma | 1 (2%) | – | 2 (4%) | –
Oligodendroglioma NOS | – | – | 1 (2%) | 1 (2%)
Spinal cord | (0) | (0) | (1) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | 1 (2%) | – | –
Carcinoma, metastatic, mammary gland | – | – | 1 (2%) | –
Pheochromocytoma malignant, metastatic, adrenal medulla | 1 (2%) | 1 (2%) | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Lacrimal gland | (0) | (2) | (0) | (0)
Zymbal’s gland | (0) | (0) | (0) | (2)
Carcinoma | – | – | – | 2 (100%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^c^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | 1 (2%) | – | –
Leukemia mononuclear | 19 (38%) | 17 (34%) | 8 (16%) | 10 (20%)
Neoplasm Summary
Total animals with primary neoplasms^d^ | 47 | 50 | 49 | 48
Total primary neoplasms | 110 | 125 | 113 | 107
Total animals with benign neoplasms | 41 | 48 | 48 | 46
Total benign neoplasms | 83 | 101 | 93 | 81
Total animals with malignant neoplasms | 23 | 21 | 13 | 22
Total malignant neoplasms | 25 | 24 | 16 | 25
Total animals with metastatic neoplasms | 1 | 2 | 1 | 1
Total metastatic neoplasms | 1 | 2 | 1 | 2
Total animals with uncertain neoplasms— benign or malignant | 2 | – | 4 | 1
Total uncertain neoplasms | 2 | – | 4 | 1

^a^ Number of core study animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Pathology data for interim evaluation animals are not presented in this table.

^c^ Number of animals with any tissue examined microscopically.

^d^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Brain: Glioma or Oligodendroglioma
Overall rate^a^ | 1/50 (2%) | 0/50 (0%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate^b^ | 2.2% | 0.0% | 9.0% | 3.5%
Terminal rate^c^ | 0/34 (0%) | 0/26 (0%) | 1/7 (14%) | 0/2 (0%)
First incidence (days) | 645 | – | 561 | 631
Poly-3 test^d^ | P = 0.266 | P = 0.512N | P = 0.207 | P = 0.647
Clitoral Gland: Adenoma
Overall rate | 8/50 (16%)^e^ | 11/49 (22%) | 8/49 (16%) | 7/48 (15%)
Adjusted rate | 17.8% | 25.7% | 23.9% | 23.2%
Terminal rate | 7/34 (21%) | 7/25 (28%) | 2/6 (33%) | 0/2 (0%)
First incidence (days) | 690 | 558 | 564 | 509
Poly-3 test | P = 0.348 | P = 0.262 | P = 0.354 | P = 0.392
Mammary Gland: Fibroadenoma
Overall rate | 28/50 (56%) | 47/50 (94%) | 47/50 (94%) | 39/50 (78%)
Adjusted rate | 60.1% | 96.6% | 99.1% | 89.6%
Terminal rate | 21/34 (62%) | 26/26 (100%) | 7/7 (100%) | 2/2 (100%)
First incidence (days) | 551 | 558 | 449 | 414
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Mammary Gland: Adenoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 2.2% | 4.7% | 8.9% | 3.5%g
Terminal rate | 0/34 (0%) | 2/26 (8%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | 635 | 727 (T) | 386 | 488
Poly-3 test | P = 0.365 | P = 0.479 | P = 0.213 | P = 0.650
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 28/50 (56%) | 47/50 (94%) | 48/50 (96%) | 40/50 (80%)
Adjusted rate | 60.1% | 96.6% | 99.4% | 90.5%
Terminal rate | 21/34 (62%) | 26/26 (100%) | 7/7 (100%) | 2/2 (100%)
First incidence (days) | 551 | 558 | 386 | 414
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Mammary Gland: Carcinoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 8/50 (16%)
Adjusted rate | 0.0% | 2.3% | 9.1% | 25.8%
Terminal rate | 0/34 (0%) | 0/26 (0%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | –^f^ | 558 | 533 | 509
Poly-3 test | P < 0.001 | P = 0.492 | P = 0.074 | P < 0.001
Mammary Gland: Adenoma or Carcinoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 6/50 (12%) | 9/50 (18%)
Adjusted rate | 2.2% | 7.0% | 17.2% | 28.4%
Terminal rate | 0/34 (0%) | 2/26 (8%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | 635 | 558 | 386 | 488
Poly-3 test | P < 0.001 | P = 0.288 | P = 0.024 | P < 0.001
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 28/50 (56%) | 47/50 (94%) | 48/50 (96%) | 42/50 (84%)
Adjusted rate | 60.1% | 96.6% | 99.4% | 92.5%
Terminal rate | 21/34 (62%) | 26/26 (100%) | 7/7 (100%) | 2/2 (100%)
First incidence (days) | 551 | 558 | 386 | 414
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 23/50 (46%) | 20/50 (40%) | 11/49 (22%) | 11/50 (22%)
Adjusted rate | 48.7% | 45.2% | 31.3% | 34.5%
Terminal rate | 13/34 (38%) | 12/26 (46%) | 1/7 (14%) | 0/2 (0%)
First incidence (days) | 551 | 551 | 449 | 551
Poly-3 test | P = 0.070N | P = 0.449N | P = 0.084N | P = 0.153N
Skin: Fibroma
Overall rate | 2/50 (4%) | 0/50 (0%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 4.4% | 0.0% | 8.9% | 6.9%
Terminal rate | 1/34 (3%) | 0/26 (0%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | 608 | – | 574 | 585
Poly-3 test | P = 0.249 | P = 0.251N | P = 0.369 | P = 0.524
Thyroid Gland (C-Cell): Adenoma
Overall rate | 11/50 (22%) | 10/50 (20%) | 6/50 (12%) | 7/50 (14%)
Adjusted rate | 24.2% | 22.3% | 18.1% | 23.1%
Terminal rate | 9/34 (27%) | 4/26 (15%) | 2/7 (29%) | 1/2 (50%)
First incidence (days) | 635 | 558 | 601 | 586
Poly-3 test | P = 0.446N | P = 0.514N | P = 0.354N | P = 0.562N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 11/50 (22%) | 10/50 (20%) | 7/50 (14%) | 7/50 (14%)
Adjusted rate | 24.2% | 22.3% | 21.1% | 23.1%
Terminal rate | 9/34 (27%) | 4/26 (15%) | 3/7 (43%) | 1/2 (50%)
First incidence (days) | 635 | 558 | 601 | 586
Poly-3 test | P = 0.482N | P = 0.514N | P = 0.477N | P = 0.562N
Uterus: Stromal Polyp
Overall rate | 4/50 (8%) | 6/50 (12%) | 8/50 (16%) | 5/50 (10%)
Adjusted rate | 8.9% | 13.6% | 22.4% | 16.7%
Terminal rate | 4/34 (12%) | 2/26 (8%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | 727 (T) | 551 | 498 | 544
Poly-3 test | P = 0.138 | P = 0.359 | P = 0.085 | P = 0.265
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 5/50 (10%) | 6/50 (12%) | 8/50 (16%) | 6/50 (12%)
Adjusted rate | 11.1% | 13.6% | 22.4% | 19.6%
Terminal rate | 4/34 (12%) | 2/26 (8%) | 0/7 (0%) | 0/2 (0%)
First incidence (days) | 641 | 551 | 498 | 519
Poly-3 test | P = 0.133 | P = 0.484 | P = 0.143 | P = 0.247
All Organs: Mononuclear Cell Leukemia
Overall rate | 19/50 (38%) | 17/50 (34%) | 8/50 (16%) | 10/50 (20%)
Adjusted rate | 41.4% | 39.1% | 23.6% | 31.6%
Terminal rate | 14/34 (41%) | 11/26 (42%) | 1/7 (14%) | 1/2 (50%)
First incidence (days) | 551 | 594 | 609 | 554
Poly-3 test | P = 0.126N | P = 0.497N | P = 0.076N | P = 0.261N
All Organs: Benign Neoplasms
Overall rate | 41/50 (82%) | 48/50 (96%) | 48/50 (96%) | 46/50 (92%)
Adjusted rate | 85.4% | 97.5% | 99.4% | 97.3%
Terminal rate | 29/34 (85%) | 26/26 (100%) | 7/7 (100%) | 2/2 (100%)
First incidence (days) | 551 | 551 | 386 | 414
Poly-3 test | P = 0.011 | P = 0.028 | P = 0.009 | P = 0.034
All Organs: Malignant Neoplasms
Overall rate | 23/50 (46%) | 21/50 (42%) | 14/50 (28%) | 22/50 (44%)
Adjusted rate | 48.5% | 46.8% | 39.1% | 60.5%
Terminal rate | 14/34 (41%) | 11/26 (42%) | 2/7 (29%) | 1/2 (50%)
First incidence (days) | 432 | 558 | 429 | 509
Poly-3 test | P = 0.189 | P = 0.518N | P = 0.261N | P = 0.183
All Organs: Benign or Malignant Neoplasms
Overall rate | 47/50 (94%) | 50/50 (100%) | 49/50 (98%) | 48/50 (96%)
Adjusted rate | 95.7% | 100.0% | 99.8% | 99.5%
Terminal rate | 32/34 (94%) | 26/26 (100%) | 7/7 (100%) | 2/2 (100%)
First incidence (days) | 432 | 551 | 386 | 414
Poly-3 test | P = 0.155 | P = 0.214 | P = 0.239 | P = 0.274

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for brain, clitoral gland, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ A single incidence of carcinoma occurred in an animal that also had an adenoma.

^f^ Not applicable; no neoplasms in animal group.

Table B-3 Summary of the Incidence of Nonneoplastic Lesions in Female F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Disposition Summary
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^b^ | 8 | 8 | 8 | 8
Thirteen-month interim evaluation^b^ | 8 | 8 | 8 | 8
Early deaths
Moribund | 10 | 22 | 42 | 44
Natural deaths | 6 | 2 | 1 | 4
Survivors
Terminal kill | 34 | 26 | 7 | 2
Animals examined microscopically | 66 | 66 | 66 | 66
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Parasite metazoan | 6 (12%) | 9 (18%) | 5 (10%) | 4 (8%)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 3 (6%) | – | 1 (2%) | 2 (4%)
Basophilic focus | 42 (84%) | 46 (92%) | 46 (92%) | 46 (92%)
Clear cell focus | 14 (28%) | 10 (20%) | 5 (10%) | 8 (16%)
Degeneration, cystic | 1 (2%) | 1 (2%) | – | –
Eosinophilic focus | 6 (12%) | 13 (26%) | 21 (42%) | 22 (44%)
Fatty change | 10 (20%) | 7 (14%) | 5 (10%) | 5 (10%)
Fatty change, focal | 1 (2%) | 2 (4%) | – | –
Hematopoietic cell proliferation | 3 (6%) | 7 (14%) | 14 (28%) | 9 (18%)
Hepatodiaphragmatic nodule | 5 (10%) | 9 (18%) | 12 (24%) | 15 (30%)
Inflammation, chronic active | 36 (72%) | 33 (66%) | 40 (80%) | 35 (70%)
Mixed cell focus | 2 (4%) | 3 (6%) | 2 (4%) | 3 (6%)
Necrosis | 2 (4%) | 1 (2%) | 1 (2%) | 2 (4%)
Necrosis, multifocal | 1 (2%) | – | – | –
Tension lipidosis | 1 (2%) | – | – | –
Bile duct, hyperplasia | 28 (56%) | 27 (54%) | 28 (56%) | 22 (44%)
Oval cell, hyperplasia | 2 (4%) | – | – | –
Serosa, fibrosis | – | – | – | 1 (2%)
Mesentery | (3) | (4) | (3) | (2)
Fat, necrosis | 3 (100%) | 4 (100%) | 3 (100%) | 2 (100%)
Oral mucosa | (0) | (0) | (0) | (1)
Pancreas | (50) | (50) | (50) | (50)
Atrophy | 9 (18%) | 13 (26%) | 11 (22%) | 14 (28%)
Acinus, hyperplasia | 6 (12%) | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Degeneration | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation | 2 (4%) | 1 (2%) | 1 (2%) | –
Ulcer | 1 (2%) | 1 (2%) | 1 (2%) | –
Epithelium, dysplasia | – | – | – | 1 (2%)
Epithelium, hyperplasia | 2 (4%) | 1 (2%) | 4 (8%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Erosion | – | – | – | 1 (2%)
Mineralization | 1 (2%) | – | – | –
Tongue | (50) | (50) | (50) | (50)
Foreign body | 1 (2%) | – | – | –
Inflammation | 1 (2%) | – | – | –
Ulcer | 1 (2%) | – | – | –
Epithelium, hyperplasia | 1 (2%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 45 (90%) | 42 (84%) | 39 (78%) | 35 (70%)
Atrium, thrombosis | – | 1 (2%) | – | –
Epicardium, inflammation | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Degeneration, cystic | 4 (8%) | 2 (4%) | 2 (4%) | 6 (12%)
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hyperplasia | – | 1 (2%) | – | –
Hypertrophy | 5 (10%) | – | 1 (2%) | 5 (10%)
Necrosis | – | – | – | 2 (4%)
Vacuolization cytoplasmic | 3 (6%) | 6 (12%) | 2 (4%) | –
Zona fasciculata, hyperplasia | – | 4 (8%) | 1 (2%) | 1 (2%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | – | 5 (10%) | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Parathyroid gland | (47) | (46) | (49) | (49)
Pituitary gland | (50) | (50) | (49) | (50)
Cyst | – | 1 (2%) | – | –
Inflammation | – | 1 (2%) | – | –
Pars distalis, angiectasis | – | – | 1 (2%) | 1 (2%)
Pars distalis, cyst | – | – | 1 (2%) | –
Pars distalis, hyperplasia | 15 (30%) | 18 (36%) | 22 (45%) | 17 (34%)
Pars distalis, vacuolization cytoplasmic | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Cyst | – | 1 (2%) | – | –
C-cell, hyperplasia | 33 (66%) | 31 (62%) | 26 (52%) | 26 (52%)
Follicular cell, hyperplasia | 1 (2%) | 2 (4%) | – | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (49) | (49) | (48)
Cyst | 1 (2%) | 1 (2%) | – | –
Hyperplasia | 1 (2%) | 5 (10%) | 3 (6%) | –
Inflammation | 2 (4%) | – | – | –
Ovary | (50) | (50) | (50) | (50)
Atrophy | 9 (18%) | 9 (18%) | 6 (12%) | 3 (6%)
Cyst | 10 (20%) | 12 (24%) | 10 (20%) | 6 (12%)
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Cervix, hypertrophy | – | 1 (2%) | 1 (2%) | –
Cervix, inflammation | 2 (4%) | 3 (6%) | – | 1 (2%)
Cervix, metaplasia, squamous | 2 (4%) | 1 (2%) | – | 1 (2%)
Cervix, epithelium, hyperplasia | 1 (2%) | – | – | –
Endometrium, hyperplasia, adenomatous | – | – | 1 (2%) | –
Endometrium, hyperplasia, cystic | 10 (20%) | 9 (18%) | 12 (24%) | 9 (18%)
Vagina | (1) | (0) | (0) | (0)
Epithelium, hyperplasia | 1 (100%) | – | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 19 (38%) | 32 (64%) | 39 (78%)
Atrophy | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | 1 (2%) | – | –
Hyperplasia | 23 (46%) | 35 (70%) | 40 (80%) | 43 (86%)
Infiltration cellular, histiocyte | – | 1 (2%) | 1 (2%) | 1 (2%)
Myelofibrosis | – | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | 1 (2%)
Lymph node | (4) | (4) | (2) | (2)
Inguinal, infiltration cellular, plasma cell | 1 (25%) | – | – | –
Lumbar, ectasia | – | 1 (25%) | – | –
Mediastinal, hyperplasia, lymphoid | – | 1 (25%) | – | –
Mediastinal, infiltration cellular, histiocyte | 1 (25%) | – | – | –
Mediastinal, infiltration cellular, plasma cell | – | – | – | 1 (50%)
Pancreatic, infiltration cellular, histiocyte | 1 (25%) | – | – | –
Lymph node, mandibular | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Infiltration cellular, plasma cell | 1 (2%) | – | 1 (2%) | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Atrophy | 4 (8%) | – | 2 (4%) | –
Ectasia | – | – | 1 (2%) | –
Infiltration cellular, histiocyte | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 6 (12%) | 13 (26%) | 29 (58%) | 31 (62%)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Pigmentation, hemosiderin | 39 (78%) | 43 (86%) | 41 (82%) | 39 (78%)
Thrombosis | – | – | – | 2 (4%)
Capsule, mineralization | 1 (2%) | – | – | –
Lymphoid follicle, atrophy | 5 (10%) | 1 (2%) | 1 (2%) | 3 (6%)
Thymus | (48) | (49) | (47) | (48)
Atrophy | 45 (94%) | 48 (98%) | 44 (94%) | 45 (94%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | – | 1 (2%) | – | –
Hyperplasia | – | 4 (8%) | 2 (4%) | 10 (20%)
Inflammation | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | 1 (2%) | – | –
Inflammation | 3 (6%) | – | – | 2 (4%)
Ulcer | 2 (4%) | – | – | –
Epidermis, hyperkeratosis | – | – | – | 1 (2%)
Epidermis, hyperplasia, squamous | 2 (4%) | – | – | 1 (2%)
Sebaceous gland, hyperplasia | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibrous osteodystrophy | 1 (2%) | 1 (2%) | – | –
Hyperplasia | – | – | 1 (2%) | –
Osteopetrosis | 2 (4%) | 2 (4%) | 8 (16%) | 5 (10%)
Tibia, fracture | – | 1 (2%) | – | –
Vertebra, fracture | – | – | – | 1 (2%)
Skeletal muscle | (0) | (1) | (0) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Hemorrhage | – | 2 (4%) | – | –
Necrosis | – | 1 (2%) | – | –
Spinal cord | (0) | (0) | (1) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Inflammation, chronic active | 20 (40%) | 26 (52%) | 26 (52%) | 28 (56%)
Alveolar epithelium, hyperplasia | 11 (22%) | 4 (8%) | 8 (16%) | 8 (16%)
Alveolar epithelium, hypertrophy | 1 (2%) | – | – | –
Alveolus, hyperplasia | – | – | 1 (2%) | –
Alveolus, infiltration cellular, histiocyte | 38 (76%) | 46 (92%) | 43 (86%) | 43 (86%)
Bronchiole, hyperplasia | – | 1 (2%) | – | 1 (2%)
Mediastinum, inflammation | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Foreign body | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%)
Inflammation | 5 (10%) | 5 (10%) | 9 (18%) | 5 (10%)
Respiratory epithelium, hyperplasia | – | – | 1 (2%) | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Fibrosis | – | – | 1 (2%) | –
Anterior chamber, inflammation | – | – | 1 (2%) | –
Ciliary body, fibrosis | 1 (2%) | – | – | –
Cornea, inflammation | – | 1 (2%) | – | 1 (2%)
Iris, inflammation | 1 (2%) | – | – | –
Lens, cataract | 5 (10%) | 1 (2%) | 6 (12%) | 3 (6%)
Posterior chamber, inflammation | 1 (2%) | – | – | –
Retina, degeneration | 6 (12%) | 2 (4%) | 5 (10%) | 3 (6%)
Retina, gliosis | 1 (2%) | 1 (2%) | 1 (2%) | –
Harderian gland | (50) | (50) | (50) | (50)
Inflammation | – | – | 1 (2%) | 1 (2%)
Lacrimal gland | (0) | (2) | (0) | (0)
Zymbal’s gland | (0) | (0) | (0) | (2)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Infarct | 1 (2%) | 1 (2%) | – | 1 (2%)
Infiltration cellular, lymphoid | – | 1 (2%) | – | –
Inflammation | 1 (2%) | – | – | –
Mineralization | 28 (56%) | 21 (42%) | 20 (40%) | 27 (54%)
Nephropathy | 43 (86%) | 40 (80%) | 44 (88%) | 46 (92%)
Cortex, cyst | 1 (2%) | – | 1 (2%) | –
Papilla, necrosis | 1 (2%) | – | – | 1 (2%)
Pelvis, calculus microscopic observation only | – | 3 (6%) | 4 (8%) | –
Pelvis, inflammation | 1 (2%) | – | 1 (2%) | –
Renal tubule, dilatation | – | – | – | 1 (2%)
Renal tubule, hyperplasia, atypical | – | 1 (2%) | 1 (2%) | –
Renal tubule, necrosis | – | – | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Transitional epithelium, hyperplasia | – | 1 (2%) | – | –

^a^ Number of core study animals examined microscopically at the site and the number of animals with lesion.

^b^ Pathology data for interim evaluation animals are not presented in this table.