# Appendix A Summary of Lesions in Male F344/NTac Rats in the Two-year Drinking Water Study of Bromodicholoroacetic Acid

Table A-1 Summary of the Incidence of Neoplasms in Male F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Disposition Summary
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^b^ | 8 | 8 | 8 | 8
Thirteen-month interim evaluation^b^ | 8 | 8 | 8 | 8
Early deaths
Moribund | 26 | 23 | 20 | 27
Natural deaths | 5 | 6 | 5 | 4
Survivors
Terminal kill | 19 | 21 | 25 | 19
Animals examined microscopically | 66 | 66 | 66 | 66
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (49) | (50)
Adenoma | – | – | 1 (2%) | –
Intestine large, colon | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | 1 (2%)
Intestine large, rectum | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Intestine small, duodenum | (50) | (50) | (49) | (50)
Intestine small, ileum | (50) | (50) | (49) | (50)
Intestine small, jejunum | (50) | (50) | (49) | (50)
Liver | (50) | (50) | (50) | (50)
Cholangiocarcinoma | – | – | 1 (2%) | –
Fibrous histiocytoma | 1 (2%) | – | – | –
Hemangioma | – | – | – | 1 (2%)
Hepatocellular adenoma | – | 1 (2%) | 2 (4%) | –
Osteosarcoma, metastatic, bone | – | – | – | 1 (2%)
Mesentery | (7) | (4) | (9) | (10)
Oral mucosa | (50) | (50) | (50) | (50)
Squamous cell carcinoma | 1 (2%) | – | – | –
Squamous cell papilloma | – | – | 2 (4%) | 1 (2%)
Pancreas | (50) | (50) | (49) | (50)
Adenoma, mixed cell | – | – | – | 1 (2%)
Acinus, adenoma | 1 (2%) | – | 2 (4%) | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | 1 (2%) | – | 1 (2%) | –
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (50) | (50) | (50) | (50)
Squamous cell carcinoma | – | – | 1 (2%) | 1 (2%)
Squamous cell papilloma | – | – | – | 1 (2%)
Tooth | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Atrium, endocardium, schwannoma malignant | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | – | 4 (8%) | –
Carcinoma | – | 1 (2%) | – | –
Osteosarcoma, metastatic, bone | – | – | – | 1 (2%)
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 8 (16%) | 7 (14%) | 8 (16%) | 11 (22%)
Pheochromocytoma malignant | – | 1 (2%) | 2 (4%) | 1 (2%)
Bilateral, carcinoma, metastatic, thyroid gland | – | 1 (2%) | – | –
Bilateral, pheochromocytoma benign | 2 (4%) | 1 (2%) | 1 (2%) | –
Islets, pancreatic | (50) | (50) | (49) | (50)
Adenoma | – | 3 (6%) | 2 (4%) | –
Parathyroid gland | (49) | (48) | (46) | (44)
Pituitary gland | (50) | (49) | (49) | (48)
Pars distalis, adenoma | 26 (52%) | 29 (59%) | 26 (53%) | 20 (42%)
Pars distalis, carcinoma | – | 1 (2%) | – | –
Thyroid gland | (50) | (50) | (50) | (50)
Bilateral, C-cell, adenoma | 2 (4%) | – | 1 (2%) | –
C-cell, adenoma | 5 (10%) | 9 (18%) | 8 (16%) | 8 (16%)
C-cell, carcinoma | 1 (2%) | 1 (2%) | – | –
Follicular cell, adenoma | 1 (2%) | 3 (6%) | – | 2 (4%)
Follicular cell, carcinoma | – | – | – | 2 (4%)
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (50) | (50) | (50) | (49)
Adenoma | 2 (4%) | 1 (2%) | 5 (10%) | –
Carcinoma | 2 (4%) | – | – | 1 (2%)
Bilateral, carcinoma | – | 1 (2%) | – | –
Prostate | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | 1 (2%) | – | –
Osteosarcoma | – | 1 (2%) | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50)
Bilateral, interstitial cell, adenoma | 25 (50%) | 20 (40%) | 19 (38%) | 20 (40%)
Interstitial cell, adenoma | 9 (18%) | 11 (22%) | 12 (24%) | 19 (38%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (5) | (2) | (8) | (7)
Mediastinal, fibrous histiocytoma | 1 (20%) | – | – | –
Renal, hemangiosarcoma | – | – | 1 (13%) | –
Lymph node, mandibular | (50) | (50) | (50) | (50)
Lymph node, mesenteric | (50) | (50) | (49) | (50)
Spleen | (50) | (50) | (49) | (50)
Hemangiosarcoma | – | – | 1 (2%) | 1 (2%)
Osteosarcoma, metastatic, bone | – | – | – | 1 (2%)
Thymus | (48) | (47) | (48) | (49)
Thymoma benign | – | – | – | 2 (4%)
Integumentary System
Mammary gland | (49) | (50) | (49) | (49)
Fibroadenoma | – | 2 (4%) | 3 (6%) | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | – | – | 4 (8%) | 4 (8%)
Basal cell carcinoma | – | – | – | 1 (2%)
Keratoacanthoma | 7 (14%) | 3 (6%) | 10 (20%) | 12 (24%)
Keratoacanthoma, multiple | – | – | – | 3 (6%)
Squamous cell carcinoma | – | 1 (2%) | 1 (2%) | –
Squamous cell papilloma | 2 (4%) | 1 (2%) | – | 1 (2%)
Pinna, squamous cell papilloma | 1 (2%) | – | – | –
Sebaceous gland, adenoma | – | 2 (4%) | 2 (4%) | 2 (4%)
Subcutaneous tissue, fibroma | 4 (8%) | 5 (10%) | 10 (20%) | 13 (26%)
Subcutaneous tissue, fibroma, multiple | – | 1 (2%) | – | 2 (4%)
Subcutaneous tissue, fibrosarcoma | 1 (2%) | – | 2 (4%) | 1 (2%)
Subcutaneous tissue, fibrosarcoma, multiple | – | – | – | 1 (2%)
Subcutaneous tissue, fibrous histiocytoma | 1 (2%) | – | – | –
Subcutaneous tissue, lipoma | 1 (2%) | – | 1 (2%) | –
Subcutaneous tissue, schwannoma malignant | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteoma | 1 (2%) | – | – | 1 (2%)
Osteosarcoma | – | – | – | 2 (4%)
Tendon, fibrosarcoma | – | – | – | 1 (2%)
Skeletal muscle | (4) | (0) | (2) | (0)
Fibroma | – | – | 1 (50%) | –
Fibrous histiocytoma | 1 (25%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Fibrous histiocytoma | 1 (2%) | – | – | –
Glioma | – | 1 (2%) | 2 (4%) | 2 (4%)
Oligodendroglioma NOS | – | – | 1 (2%) | 1 (2%)
Meninges, granular cell tumor benign | 2 (4%) | – | 1 (2%) | –
Peripheral nerve | (0) | (2) | (0) | (0)
Spinal cord | (0) | (2) | (0) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 3 (6%) | 2 (4%) | – | 1 (2%)
Alveolar/bronchiolar carcinoma | – | – | – | 1 (2%)
Carcinoma, metastatic, Harderian gland | 1 (2%) | – | 1 (2%) | –
Carcinoma, metastatic, thyroid gland | – | 1 (2%) | – | –
Fibrous histiocytoma | 1 (2%) | – | – | –
Osteosarcoma, metastatic, bone | – | – | – | 1 (2%)
Squamous cell carcinoma | 1 (2%) | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (1) | (0) | (0) | (0)
Neural crest tumor | 1 (100%) | – | – | –
Eye | (50) | (50) | (50) | (50)
Iris, melanoma malignant | – | – | – | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Carcinoma | 1 (2%) | – | 1 (2%) | –
Zymbal’s gland | (1) | (2) | (0) | (2)
Carcinoma | 1 (100%) | 2 (100%) | – | 2 (100%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Lipoma | 1 (2%) | – | – | –
Mesenchymal tumor malignant | – | – | 1 (2%) | –
Renal tubule, adenoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^c^ | (50) | (50) | (50) | (50)
Leukemia mononuclear | 15 (30%) | 11 (22%) | 15 (30%) | 11 (22%)
Mesothelioma malignant | 1 (2%) | 12 (24%) | 18 (36%) | 37 (74%)
Neoplasm Summary
Total animals with primary neoplasms^d^ | 49 | 48 | 48 | 50
Total primary neoplasms | 139 | 137 | 174 | 199
Total animals with benign neoplasms | 46 | 44 | 47 | 49
Total benign neoplasms | 108 | 103 | 127 | 130
Total animals with malignant neoplasms | 24 | 25 | 33 | 46
Total malignant neoplasms | 30 | 33 | 44 | 66
Total animals with metastatic neoplasms | 1 | 1 | 1 | 1
Total metastatic neoplasms | 1 | 2 | 1 | 4
Total animals with uncertain neoplasms— benign or malignant | 1 | 1 | 3 | 3
Total uncertain neoplasms | 1 | 1 | 3 | 3

^a^ Number of core study animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Pathology data for interim evaluation animals are not presented in this table.

^c^ Number of animals with any tissue examined microscopically.

^d^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Adrenal Cortex: Adenoma
Overall rate^a^ | 2/50 (4%) | 0/50 (0%) | 4/50 (8%) | 0/50 (0%)
Adjusted rate^b^ | 5.2% | 0.0% | 9.4% | 0.0%
Terminal rate^c^ | 2/19 (11%) | 0/21 (0%) | 2/25 (8%) | 0/19 (0%)
First incidence (days) | 726 (T) | –^e^ | 611 | –
Poly-3 test^d^ | P = 0.345N | P = 0.232N | P = 0.380 | P = 0.238N
Adrenal Medulla: Benign Pheochromocytoma
Overall rate | 10/50 (20%) | 8/50 (16%) | 9/50 (18%) | 11/50 (22%)
Adjusted rate | 24.9% | 20.1% | 21.2% | 27.7%
Terminal rate | 5/19 (26%) | 5/21 (24%) | 5/25 (20%) | 6/19 (32%)
First incidence (days) | 561 | 685 | 657 | 561
Poly-3 test | P = 0.377 | P = 0.403N | P = 0.444N | P = 0.489
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 10/50 (20%) | 9/50 (18%) | 11/50 (22%) | 12/50 (24%)
Adjusted rate | 24.9% | 22.6% | 25.9% | 30.2%
Terminal rate | 5/19 (26%) | 6/21 (29%) | 6/25 (24%) | 7/19 (37%)
First incidence (days) | 561 | 685 | 657 | 561
Poly-3 test | P = 0.290 | P = 0.510N | P = 0.560 | P = 0.388
Bone: Osteoma or Osteosarcoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 2.6% | 0.0% | 0.0% | 7.8%
Terminal rate | 0/19 (0%) | 0/21 (0%) | 0/25 (0%) | 2/19 (11%)
First incidence (days) | 671 | – | – | 678
Poly-3 test | P = 0.084 | P = 0.497N | P = 0.485N | P = 0.301
Brain: Glioma or Oligodendroglioma (Original Evaluation)
Overall rate | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 0.0% | 2.5% | 7.1% | 7.7%
Terminal rate | 0/19 (0%) | 1/21 (5%) | 0/25 (0%) | 0/19 (0%)
First incidence (days) | – | 726 (T) | 685 | 644
Poly-3 test | P = 0.066 | P = 0.504 | P = 0.134 | P = 0.119
Brain: Glioma or Oligodendroglioma (Original and Extended Evaluations)
Overall rate | 1/50 (0%) | 1/50 (2%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 2.6% | 2.5% | 9.5% | 7.7%
Terminal rate | 0/19 (0%) | 1/21 (5%) | 1/25 (4%) | 0/19 (0%)
First incidence (days) | 719 | 726 (T) | 685 | 644
Poly-3 test | P = 0.162 | P = 0.504 | P = 0.071 | P = 0.119
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 7.7% | 5.1% | 0.0% | 2.6%
Terminal rate | 2/19 (11%) | 2/21 (10%) | 0/25 (0%) | 1/19 (5%)
First incidence (days) | 664 | 726 (T) | – | 726 (T)
Poly-3 test | P = 0.159N | P = 0.493N | P = 0.105N | P = 0.309N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 7.7% | 5.1% | 0.0% | 5.2%
Terminal rate | 2/19 (11%) | 2/21 (10%) | 0/25 (0%) | 2/19 (11%)
First incidence (days) | 664 | 726 (T) | – | 726 (T)
Poly-3 test | P = 0.368N | P = 0.493N | P = 0.105N | P = 0.506N
Mammary Gland: Fibroadenoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 0.0% | 5.1% | 7.2% | 2.6%
Terminal rate | 0/19 (0%) | 2/21 (10%) | 2/25 (8%) | 1/19 (5%)
First incidence (days) | – | 726 (T) | 685 | 726 (T)
Poly-3 test | P = 0.437 | P = 0.241 | P = 0.133 | P = 0.499
Oral Cavity (Oral Mucosa or Tongue): Squamous Cell Papilloma or Squamous Cell Carcinoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 2.6% | 0.0% | 7.0% | 7.7%
Terminal rate | 0/19 (0%) | 0/21 (0%) | 1/25 (4%) | 1/19 (5%)
First incidence (days) | 593 | – | 442 | 642
Poly-3 test | P = 0.105 | P = 0.498N | P = 0.338 | P = 0.302
Pancreatic Islets: Adenoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 2/49 (4%) | 0/50 (0%)
Adjusted rate | 0.0% | 7.6% | 4.9% | 0.0%
Terminal rate | 0/19 (0%) | 2/21 (10%) | 2/25 (8%) | 0/19 (0%)
First incidence (days) | – | 719 | 726 (T) | –
Poly-3 test | P = 0.409N | P = 0.121 | P = 0.251 | –^f^
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 26/50 (52%) | 29/49 (59%) | 26/49 (53%) | 20/48 (42%)
Adjusted rate | 59.5% | 66.8% | 58.1% | 49.3%
Terminal rate | 11/19 (58%) | 13/21 (62%) | 14/24 (58%) | 8/18 (44%)
First incidence (days) | 477 | 516 | 442 | 499
Poly-3 test | P = 0.118N | P = 0.306 | P = 0.537N | P = 0.228N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 26/50 (52%) | 30/49 (61%) | 26/49 (53%) | 20/48 (42%)
Adjusted rate | 59.5% | 69.1% | 58.1% | 49.3%
Terminal rate | 11/19 (58%) | 14/21 (67%) | 14/24 (58%) | 8/18 (44%)
First incidence (days) | 477 | 516 | 442 | 499
Poly-3 test | P = 0.102N | P = 0.226 | P = 0.537N | P = 0.228N
Preputial Gland: Adenoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 5/50 (10%) | 0/49 (0%)
Adjusted rate | 5.1% | 2.5% | 11.7% | 0.0%
Terminal rate | 1/19 (5%) | 0/21 (0%) | 2/25 (8%) | 0/19 (0%)
First incidence (days) | 657 | 644 | 442 | –
Poly-3 test | P = 0.328N | P = 0.493N | P = 0.254 | P = 0.243N
Preputial Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 2/50 (4%) | 5/50 (10%) | 1/49 (2%)
Adjusted rate | 10.2% | 5.0% | 11.7% | 2.6%
Terminal rate | 1/19 (5%) | 1/21 (5%) | 2/25 (8%) | 0/19 (0%)
First incidence (days) | 657 | 644 | 442 | 610
Poly-3 test | P = 0.219N | P = 0.331N | P = 0.551 | P = 0.185N
Skin: Squamous Cell Papilloma
Overall rate | 3/50 (6%) | 1/50 (2%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 7.7% | 2.5% | 0.0% | 2.6%
Terminal rate | 2/19 (11%) | 1/21 (5%) | 0/25 (0%) | 0/19 (0%)
First incidence (days) | 680 | 726 (T) | – | 674
Poly-3 test | P = 0.196N | P = 0.298N | P = 0.105N | P = 0.306N
Skin: Keratoacanthoma
Overall rate | 7/50 (14%) | 3/50 (6%) | 10/50 (20%) | 15/50 (30%)
Adjusted rate | 17.3% | 7.6% | 23.2% | 37.1%
Terminal rate | 1/19 (5%) | 2/21 (10%) | 5/25 (20%) | 7/19 (37%)
First incidence (days) | 544 | 716 | 493 | 621
Poly-3 test | P = 0.003 | P = 0.162N | P = 0.346 | P = 0.035
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 9/50 (18%) | 4/50 (8%) | 10/50 (20%) | 16/50 (32%)
Adjusted rate | 22.2% | 10.1% | 23.2% | 39.4%
Terminal rate | 2/19 (11%) | 3/21 (14%) | 5/25 (20%) | 7/19 (37%)
First incidence (days) | 544 | 716 | 493 | 621
Poly-3 test | P = 0.010 | P = 0.120N | P = 0.559 | P = 0.069
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Squamous Cell Carcinoma
Overall rate | 9/50 (18%) | 5/50 (10%) | 11/50 (22%) | 16/50 (32%)
Adjusted rate | 22.2% | 12.7% | 25.6% | 39.4%
Terminal rate | 2/19 (11%) | 3/21 (14%) | 6/25 (24%) | 7/19 (37%)
First incidence (days) | 544 | 716 | 493 | 621
Poly-3 test | P = 0.013 | P = 0.201N | P = 0.459 | P = 0.069
Skin: Basal Cell Adenoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 0.0% | 0.0% | 9.3% | 10.4%
Terminal rate | 0/19 (0%) | 0/21 (0%) | 1/25 (4%) | 3/19 (16%)
First incidence (days) | – | – | 513 | 653
Poly-3 test | P = 0.012 | – | P = 0.074 | P = 0.059
Skin: Basal Cell Adenoma or Basal Cell Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 4/50 (8%) | 5/50 (10%)
Adjusted rate | 0.0% | 0.0% | 9.3% | 12.8%
Terminal rate | 0/19 (0%) | 0/21 (0%) | 1/25 (4%) | 3/19 (16%)
First incidence (days) | – | – | 513 | 629
Poly-3 test | P = 0.004 | – | P = 0.074 | P = 0.030
Skin: Squamous Cell Papilloma, Keratoacanthoma, Basal Cell Adenoma, Basal Cell Carcinoma, or Squamous Cell Carcinoma
Overall rate | 9/50 (18%) | 5/50 (10%) | 14/50 (28%) | 19/50 (38%)
Adjusted rate | 22.2% | 12.7% | 31.8% | 46.8%
Terminal rate | 2/19 (11%) | 3/21 (14%) | 7/25 (28%) | 10/19 (53%)
First incidence (days) | 544 | 716 | 493 | 621
Poly-3 test | P < 0.001 | P = 0.201N | P = 0.226 | P = 0.014
Skin: Squamous Cell Papilloma, Keratoacanthoma, Sebaceous Gland Adenoma, Basal Cell Adenoma, Basal Cell Carcinoma, or Squamous Cell Carcinoma
Overall rate | 9/50 (18%) | 7/50 (14%) | 15/50 (30%) | 21/50 (42%)
Adjusted rate | 22.2%. | 17.4% | 33.7% | 50.4%
Terminal rate | 2/19 (11%) | 4/21 (19%) | 7/25 (28%) | 10/19 (53%)
First incidence (days) | 544 | 509 | 493 | 436
Poly-3 test | P < 0.001 | P = 0.397N | P = 0.171 | P = 0.005
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 4/50 (8%) | 6/50 (12%) | 10/50 (20%) | 15/50 (30%)
Adjusted rate | 10.2% | 14.8% | 23.3% | 36.0%
Terminal rate | 2/19 (11%) | 2/21 (10%) | 7/25 (28%) | 7/19 (37%)
First incidence (days) | 657 | 595 | 442 | 467
Poly-3 test | P < 0.001 | P = 0.391 | P = 0.098 | P = 0.005
Skin (Subcutaneous Tissue): Fibroma, Fibrous Histiocytoma, or Fibrosarcoma
Overall rate | 6/50 (12%) | 6/50 (12%) | 12/50 (24%) | 17/50 (34%)
Adjusted rate | 15.2% | 14.8% | 27.9% | 40.4%
Terminal rate | 2/19 (11%) | 2/21 (10%) | 8/25 (32%) | 7/19 (37%)
First incidence (days) | 657 | 595 | 442 | 467
Poly-3 test | P < 0.001 | P = 0.601N | P = 0.128 | P = 0.009
Testes: Adenoma
Overall rate | 34/50 (68%) | 31/50 (62%) | 31/50 (62%) | 39/50 (78%)
Adjusted rate | 76.1% | 73.9% | 69.1% | 86.3%
Terminal rate | 15/19 (79%) | 19/21 (91%) | 19/25 (76%) | 19/19 (100%)
First incidence (days) | 537 | 526 | 513 | 467
Poly-3 test | P = 0.107 | P = 0.503N | P = 0.292N | P = 0.136
Thyroid Gland (C-Cell): Adenoma
Overall rate | 7/50 (14%) | 9/50 (18%) | 9/50 (18%) | 8/50 (16%)
Adjusted rate | 17.4% | 22.4% | 20.9% | 20.4%
Terminal rate | 3/19 (16%) | 7/21 (33%) | 5/25 (20%) | 4/19 (21%)
First incidence (days) | 544 | 533 | 585 | 642
Poly-3 test | P = 0.468 | P = 0.390 | P = 0.451 | P = 0.478
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 10/50 (20%) | 9/50 (18%) | 8/50 (16%)
Adjusted rate | 19.8% | 24.6% | 20.9% | 20.4%
Terminal rate | 3/19 (16%) | 7/21 (33%) | 5/25 (20%) | 4/19 (21%)
First incidence (days) | 544 | 533 | 585 | 642
Poly-3 test | P = 0.513N | P = 0.397 | P = 0.557 | P = 0.582
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 2.6% | 7.6% | 0.0% | 5.1%
Terminal rate | 1/19 (5%) | 1/21 (5%) | 0/25 (0%) | 0/19 (0%)
First incidence (days) | 726 (T) | 674 | – | 610
Poly-3 test | P = 0.566 | P = 0.314 | P = 0.484N | P = 0.504
Thyroid Gland (Follicular Cell): Adenoma or Carcinoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 4/50 (8%)
Adjusted rate | 2.6% | 7.6% | 0.0% | 10.2%
Terminal rate | 1/19 (5%) | 1/21 (5%) | 0/25 (0%) | 1/19 (5%)
First incidence (days) | 726 (T) | 674 | – | 610
Poly-3 test | P = 0.168 | P = 0.314 | P = 0.484N | P = 0.181
All Organs: Mononuclear Cell Leukemia
Overall rate | 15/50 (30%) | 11/50 (22%) | 15/50 (30%) | 11/50 (22%)
Adjusted rate | 36.1% | 27.1% | 34.3% | 27.0%
Terminal rate | 6/19 (32%) | 6/21 (29%) | 6/25 (24%) | 5/19 (26%)
First incidence (days) | 544 | 629 | 587 | 481
Poly-3 test | P = 0.289N | P = 0.258N | P = 0.524N | P = 0.253N
All Organs: Malignant Mesothelioma
Overall rate | 1/50 (2%) | 12/50 (24%) | 18/50 (36%) | 37/50 (74%)
Adjusted rate | 2.6% | 28.0% | 40.6% | 77.5%
Terminal rate | 0/19 (0%) | 3/21 (14%) | 10/25 (40%) | 12/19 (63%)
First incidence (days) | 683 | 309 | 442 | 389
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
All Organs: Osteoma or Osteosarcoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 2.6% | 2.5% | 0.0% | 7.8%
Terminal rate | 0/19 (0%) | 0/21 (0%) | 0/25 (0%) | 2/19 (11%)
First incidence (days) | 671 | 516 | – | 678
Poly-3 test | P = 0.158 | P = 0.754N | P = 0.485N | P = 0.301
All Organs: Benign Neoplasms
Overall rate | 46/50 (92%) | 44/50 (88%) | 47/50 (94%) | 49/50 (98%)
Adjusted rate | 96.3% | 93.7% | 96.0% | 99.7%
Terminal rate | 19/19 (100%) | 20/21 (95%) | 24/25 (96%) | 19/19 (100%)
First incidence (days) | 477 | 509 | 442 | 436
Poly-3 test | P = 0.129 | P = 0.445N | P = 0.708N | P = 0.253
All Organs: Malignant Neoplasms
Overall rate | 24/50 (48%) | 25/50 (50%) | 33/50 (66%) | 46/50 (92%)
Adjusted rate | 54.7% | 56.7% | 71.5% | 93.4%
Terminal rate | 7/19 (37%) | 11/21 (52%) | 16/25 (64%) | 17/19 (90%)
First incidence (days) | 544 | 309 | 442 | 389
Poly-3 test | P < 0.001 | P = 0.512 | P = 0.066 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 49/50 (98%) | 48/50 (96%) | 48/50 (96%) | 50/50 (100%)
Adjusted rate | 99.7% | 98.8% | 97.5% | 100.0%
Terminal rate | 19/19 (100%) | 21/21 (100%) | 24/25 (96%) | 19/19 (100%)
First incidence (days) | 477 | 309 | 442 | 389
Poly-3 test | P = 0.630 | P = 0.819N | P = 0.464N | P = 1.000

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, bone, brain, lung, pancreatic islets, pituitary gland, preputial gland, testes, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male F344/NTac Rats in the Two-year Drinking Water Study of Bromodichloroacetic Acid^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Disposition Summary
Animals initially in study | 66 | 66 | 66 | 66
Six-month interim evaluation^b^ | 8 | 8 | 8 | 8
Thirteen-month interim evaluation^b^ | 8 | 8 | 8 | 8
Early deaths
Moribund | 26 | 23 | 20 | 27
Natural deaths | 5 | 6 | 5 | 4
Survivors
Terminal kill | 19 | 21 | 25 | 19
Animals examined microscopically | 66 | 66 | 66 | 66
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (49) | (50)
Erosion | – | – | 1 (2%) | –
Inflammation | – | – | 2 (4%) | –
Intestine large, colon | (50) | (50) | (50) | (50)
Amyloid deposition | – | 1 (2%) | – | –
Inflammation | 1 (2%) | 1 (2%) | – | –
Parasite metazoan | 6 (12%) | 8 (16%) | 10 (20%) | 8 (16%)
Thrombosis | – | 1 (2%) | – | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (49) | (50)
Intestine small, ileum | (50) | (50) | (49) | (50)
Intestine small, jejunum | (50) | (50) | (49) | (50)
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | 3 (6%) | 4 (8%)
Basophilic focus | 13 (26%) | 23 (46%) | 17 (34%) | 20 (40%)
Clear cell focus | 19 (38%) | 20 (40%) | 21 (42%) | 16 (32%)
Congestion | – | – | – | 1 (2%)
Degeneration, cystic | 12 (24%) | 12 (24%) | 11 (22%) | 14 (28%)
Eosinophilic focus | 6 (12%) | 10 (20%) | 7 (14%) | 14 (28%)
Fatty change | 8 (16%) | 7 (14%) | 4 (8%) | 1 (2%)
Fatty change, focal | – | – | 1 (2%) | 4 (8%)
Fibrosis | – | – | 1 (2%) | –
Hematopoietic cell proliferation | 1 (2%) | – | – | 3 (6%)
Hemorrhage | – | 1 (2%) | 1 (2%) | –
Hepatodiaphragmatic nodule | 9 (18%) | 4 (8%) | 3 (6%) | 2 (4%)
Inflammation, chronic active | 32 (64%) | 36 (72%) | 36 (72%) | 36 (72%)
Mixed cell focus | 3 (6%) | 2 (4%) | 6 (12%) | 1 (2%)
Necrosis | 2 (4%) | 1 (2%) | 4 (8%) | 5 (10%)
Pigmentation, hemosiderin | 1 (2%) | – | 2 (4%) | 1 (2%)
Regeneration | – | – | 1 (2%) | –
Tension lipidosis | – | – | 1 (2%) | 2 (4%)
Thrombosis | – | – | – | 1 (2%)
Bile duct, cyst | 1 (2%) | – | – | 1 (2%)
Bile duct, hyperplasia | 49 (98%) | 48 (96%) | 49 (98%) | 48 (96%)
Hepatocyte, degeneration | – | – | 1 (2%) | 3 (6%)
Oval cell, hyperplasia | – | – | 1 (2%) | –
Mesentery | (7) | (4) | (9) | (10)
Fat, necrosis | 7 (100%) | 3 (75%) | 3 (33%) | 3 (30%)
Oral mucosa | (50) | (50) | (50) | (50)
Pancreas | (50) | (50) | (49) | (50)
Atrophy | 18 (36%) | 19 (38%) | 15 (31%) | 21 (42%)
Cytoplasmic alteration | 1 (2%) | – | – | –
Acinus, hyperplasia | 4 (8%) | 1 (2%) | 3 (6%) | 4 (8%)
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Metaplasia, serous | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Erosion | – | – | – | 1 (2%)
Inflammation | 13 (26%) | 8 (16%) | 4 (8%) | –
Perforation | 1 (2%) | – | – | –
Ulcer | 6 (12%) | 3 (6%) | 1 (2%) | –
Epithelium, dysplasia | 1 (2%) | – | – | –
Epithelium, hyperplasia | 12 (24%) | 8 (16%) | 4 (8%) | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Erosion | 1 (2%) | – | 1 (2%) | –
Hyperplasia, focal | 1 (2%) | – | – | –
Inflammation | 7 (14%) | 1 (2%) | 2 (4%) | –
Mineralization | 1 (2%) | – | 1 (2%) | 1 (2%)
Ulcer | 2 (4%) | – | – | –
Epithelium, hyperplasia | – | – | 1 (2%) | –
Tongue | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | –
Epithelium, hyperplasia | – | – | 1 (2%) | 2 (4%)
Tooth | (1) | (0) | (0) | (0)
Degeneration | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aneurysm | – | – | 1 (2%) | –
Inflammation | 5 (10%) | – | 3 (6%) | –
Aorta, mineralization | – | 1 (2%) | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 47 (94%) | 48 (96%) | 48 (96%) | 48 (96%)
Mineralization | – | 3 (6%) | – | –
Atrium, inflammation | – | 1 (2%) | – | –
Atrium, thrombosis | 5 (10%) | 6 (12%) | 7 (14%) | 5 (10%)
Pericardium, inflammation, chronic active | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Degeneration, cystic | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Hyperplasia | 5 (10%) | 2 (4%) | 2 (4%) | –
Hypertrophy | 1 (2%) | 3 (6%) | – | –
Mineralization | – | – | 1 (2%) | –
Vacuolization cytoplasmic | 14 (28%) | 9 (18%) | 17 (34%) | 13 (26%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 15 (30%) | 18 (36%) | 15 (30%) | 9 (18%)
Islets, pancreatic | (50) | (50) | (49) | (50)
Hyperplasia | – | 2 (4%) | – | 1 (2%)
Parathyroid gland | (49) | (48) | (46) | (44)
Hyperplasia | 6 (12%) | 1 (2%) | 1 (2%) | 1 (2%)
Pituitary gland | (50) | (49) | (49) | (48)
Atrophy | 2 (4%) | – | – | –
Pars distalis, atrophy | 1 (2%) | – | – | –
Pars distalis, hyperplasia | 12 (24%) | 14 (29%) | 18 (37%) | 21 (44%)
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, hyperplasia | 22 (44%) | 20 (40%) | 21 (42%) | 24 (48%)
Follicle, cyst | – | – | – | 2 (4%)
Follicular cell, hyperplasia | 2 (4%) | – | – | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Atrophy | 8 (16%) | 7 (14%) | 5 (10%) | 4 (8%)
Inflammation | 1 (2%) | – | – | 1 (2%)
Mesothelium, hyperplasia | – | – | 1 (2%) | –
Preputial gland | (50) | (50) | (50) | (49)
Hyperplasia | 1 (2%) | 2 (4%) | 2 (4%) | –
Inflammation | 2 (4%) | – | – | –
Duct, hyperplasia, squamous | – | – | 1 (2%) | –
Duct, inflammation | – | – | 1 (2%) | –
Prostate | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Cyst | – | – | 1 (2%) | –
Inflammation | 42 (84%) | 41 (82%) | 45 (90%) | 35 (70%)
Epithelium, hyperplasia | 11 (22%) | 17 (34%) | 12 (24%) | 14 (28%)
Seminal vesicle | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Hyperplasia | – | – | 1 (2%) | 1 (2%)
Inflammation | 3 (6%) | 3 (6%) | 2 (4%) | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Atrophy | 15 (30%) | 16 (32%) | 16 (32%) | 17 (34%)
Inflammation | 1 (2%) | – | – | –
Germinal epithelium, degeneration | 8 (16%) | 10 (20%) | 8 (16%) | 9 (18%)
Interstitial cell, hyperplasia | 23 (46%) | 26 (52%) | 24 (48%) | 19 (38%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Angiectasis | 4 (8%) | 29 (58%) | 34 (68%) | 40 (80%)
Hemorrhage | – | 5 (10%) | 1 (2%) | –
Hyperplasia | 17 (34%) | 19 (38%) | 20 (40%) | 30 (60%)
Myelofibrosis | 1 (2%) | – | – | 2 (4%)
Necrosis | – | 1 (2%) | – | –
Thrombosis | – | 4 (8%) | – | 1 (2%)
Lymph node | (5) | (2) | (8) | (7)
Iliac, ectasia | – | – | – | 1 (14%)
Iliac, hyperplasia, lymphoid | – | – | – | 1 (14%)
Iliac, necrosis, lymphoid | – | – | – | 1 (14%)
Inguinal, ectasia | – | – | – | 1 (14%)
Lumbar, ectasia | – | – | 1 (13%) | –
Lumbar, infiltration cellular, histiocyte | – | – | 1 (13%) | –
Mediastinal, hyperplasia | – | – | 1 (13%) | –
Mediastinal, hyperplasia, lymphoid | – | 1 (50%) | – | –
Mediastinal, infiltration cellular, histiocyte | – | – | – | 1 (14%)
Mediastinal, infiltration cellular, mast cell | – | 1 (50%) | – | –
Mediastinal, infiltration cellular, plasma cell | – | – | – | 1 (14%)
Pancreatic, inflammation, histiocytic | – | – | – | 1 (14%)
Renal, hyperplasia, lymphoid | – | – | 1 (13%) | –
Renal, infiltration cellular, histiocyte | – | – | – | 1 (14%)
Renal, infiltration cellular, plasma cell | 2 (40%) | – | – | –
Lymph node, mandibular | (50) | (50) | (50) | (50)
Ectasia | 4 (8%) | 1 (2%) | 2 (4%) | –
Lymph node, mesenteric | (50) | (50) | (49) | (50)
Atrophy | 2 (4%) | – | – | 4 (8%)
Ectasia | – | – | 1 (2%) | 1 (2%)
Hemorrhage | – | – | – | 2 (4%)
Necrosis | – | – | – | 1 (2%)
Spleen | (50) | (50) | (49) | (50)
Hematopoietic cell proliferation | 32 (64%) | 31 (62%) | 31 (63%) | 32 (64%)
Hemorrhage | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Infarct | 2 (4%) | 1 (2%) | – | 1 (2%)
Pigmentation, hemosiderin | 35 (70%) | 36 (72%) | 32 (65%) | 28 (56%)
Stromal hyperplasia | 1 (2%) | – | 1 (2%) | 2 (4%)
Thrombosis | – | – | – | 1 (2%)
Capsule, fibrosis | – | – | – | 1 (2%)
Lymphoid follicle, atrophy | – | – | 3 (6%) | –
Red pulp, atrophy | – | 1 (2%) | 1 (2%) | –
Thymus | (48) | (47) | (48) | (49)
Atrophy | 47 (98%) | 46 (98%) | 46 (96%) | 49 (100%)
Integumentary System
Mammary gland | (49) | (50) | (49) | (49)
Hyperplasia | 6 (12%) | 1 (2%) | 2 (4%) | 1 (2%)
Inflammation, chronic | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | – | 2 (4%) | –
Hyperplasia, squamous | – | 1 (2%) | – | –
Inflammation | 3 (6%) | 5 (10%) | 5 (10%) | 5 (10%)
Ulcer | 2 (4%) | 3 (6%) | 1 (2%) | 3 (6%)
Dermis, fibrosis | – | – | – | 1 (2%)
Epidermis, hyperkeratosis | 2 (4%) | 1 (2%) | 2 (4%) | 2 (4%)
Epidermis, hyperplasia | 3 (6%) | 5 (10%) | 5 (10%) | 2 (4%)
Epidermis, hyperplasia, basal cell | – | – | – | 1 (2%)
Epidermis, hyperplasia, squamous | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibrous osteodystrophy | 1 (2%) | – | – | –
Osteopetrosis | 3 (6%) | 1 (2%) | – | 4 (8%)
Cartilage, sternum, degeneration | – | – | – | 1 (2%)
Tibia, fracture | – | – | – | 1 (2%)
Skeletal muscle | (4) | (0) | (2) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Gliosis | – | 1 (2%) | – | –
Hemorrhage | – | 2 (4%) | – | –
Infiltration cellular, lymphocyte | – | 1 (2%) | – | –
Meninges, hyperplasia | – | – | – | 1 (2%)
Peripheral nerve | (0) | (2) | (0) | (0)
Degeneration | – | 1 (50%) | – | –
Spinal cord | (0) | (2) | (0) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Fibrosis | – | – | – | 1 (2%)
Inflammation, chronic active | 15 (30%) | 11 (22%) | 11 (22%) | 19 (38%)
Metaplasia, osseous | – | – | 1 (2%) | –
Mineralization | 1 (2%) | – | – | –
Thrombosis | 1 (2%) | – | – | –
Alveolar epithelium, hyperplasia | 5 (10%) | 7 (14%) | 12 (24%) | 10 (20%)
Alveolar epithelium, hypertrophy | – | – | – | 2 (4%)
Alveolus, infiltration cellular, histiocyte | 20 (40%) | 22 (44%) | 25 (50%) | 22 (44%)
Bronchiole, hyperplasia | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Foreign body | 12 (24%) | 16 (32%) | 10 (20%) | 17 (34%)
Inflammation | 15 (30%) | 21 (42%) | 14 (28%) | 22 (44%)
Glands, olfactory epithelium, hyperplasia | – | 1 (2%) | – | –
Glands, respiratory epithelium, hyperplasia | 1 (2%) | – | – | –
Olfactory epithelium, metaplasia | – | – | – | 1 (2%)
Respiratory epithelium, hyperplasia | 4 (8%) | – | – | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (1) | (0) | (0) | (0)
Eye | (50) | (50) | (50) | (50)
Anterior chamber, inflammation | – | – | 1 (2%) | 1 (2%)
Cornea, inflammation | – | – | – | 1 (2%)
Iris, inflammation | 1 (2%) | 1 (2%) | – | –
Lens, cataract | 2 (4%) | 5 (10%) | 1 (2%) | 6 (12%)
Retina, degeneration | 4 (8%) | 2 (4%) | 3 (6%) | 5 (10%)
Retina, dysplasia | – | – | – | 1 (2%)
Retina, gliosis | – | 2 (4%) | – | –
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia, squamous | – | – | – | 1 (2%)
Inflammation | 1 (2%) | – | 1 (2%) | –
Metaplasia, squamous | – | – | – | 1 (2%)
Zymbal’s gland | (1) | (2) | (0) | (2)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | 3 (6%) | – | 1 (2%) | –
Mineralization | 16 (32%) | 21 (42%) | 25 (50%) | 23 (46%)
Nephropathy | 48 (96%) | 49 (98%) | 49 (98%) | 49 (98%)
Cortex, cyst | 1 (2%) | 1 (2%) | – | –
Cortex, inflammation, focal | 1 (2%) | – | – | –
Pelvis, dilatation | – | 2 (4%) | – | –
Renal tubule, dilatation | – | 2 (4%) | – | –
Renal tubule, hyperplasia, atypical | – | – | – | 1 (2%)
Renal tubule, necrosis | – | – | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 2 (4%) | – | –