# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-582

Report Series: NTP Technical Report Series

Report Series Number: 582

Official citation: National Toxicology Program (NTP). 2015. NTP technical report on the toxicology and carcinogenesis studies of vinylidene chloride (CASRN 75-35-4) in F344/N rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 582.