# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Report on the Toxicology and Carcinogenesis Studies of Vinylidene Chloride (CASRN 75-35-4) in F344/N Rats and B6C3F1/N Mice (Inhalation Studies) on October 29, 2013, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, panel members had five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- John Cullen, V.M.D., Ph.D., Chairperson
  College of Veterinary Medicine
  North Carolina State University
  Raleigh, North Carolina, USA
- Norman J. Barlow, D.V.M., Ph.D., MBA, MLD
  Sanofi
  Boston, Massachussetts, USA
- Russell C. Cattley, V.M.D., Ph.D., Primary Reviewer
  College of Veterinary Medicine
  Auburn University
  Auburn, Alabama, USA
- Deborah Cory-Slechta, Ph.D.
  University of Rochester School of Medicine and Dentistry
  Rochester, New York, USA
- Terry Gordon, Ph.D., Primary Reviewer
  New York University Langone Medical Center
  New York, New York, USA
- Joel Parker, Ph.D., Primary Reviewer
  University of North Carolina at Chapel Hill
  Chapel Hill, North Carolina, USA
- Karen Regan, D.V.M.
  Regan Pathology/Toxicology Services, Inc.
  Ashland, Ohio, USA
- Timothy Zacharewski, Ph.D., Primary Reviewer
  Michigan State University
  East Lansing, Michigan, USA