# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M.E. Wyde, Ph.D., Study Scientist
  M.J. Hoenerhoff, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  S.L. Grumbein, D.V.M., Ph.D.
  S.J. Harbo, D.V.M.
  B.K. Hayden
  B.A. Renne, D.V.M.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  E.T. Adams, D.V.M., Ph.D.
  H.M. Kolenda-Roberts, D.V.M., Ph.D.
  R.A. Miller, D.V.M., Ph.D.
  A.K.R. Pandiri, Ph.D.
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups for 2-year rats (December 14, 2010) and 2-year mice (August 19, 2010)
  R.M. Kovatch, D.V.M.
- Gene Logic Laboratories, Inc., Gaithersburg, Maryland, USA
  Provided SMVCE analyses
  B.J.T. Muir, Ph.D., Principal Investigator
  B. Atkinson., M.S.
  H. Batdorf, B.S.
  Y. Wang, M.S.