# References

1 Gibbs DS Wessling RA Vinylidene chloride and poly(vinylidene chloride). Kirk-Othmer Encyclopedia of Chemical Technology. 3rd ed. New York: Wiley-Interscience; 1983. p. 764–798.
2 International Agency for Research on Cancer (IARC). IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans. Some Chemicals Used in Plastics and Elastomers. Lyon, France. 1986; 39:195-226.
3 International Agency for Research on Cancer (IARC). IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Re-evaluation of Some Organic Chemicals, Hydrazine and Hydrogen Peroxide. Lyon, France. 1999; 71:1163-1180.
4 Torkelson TR Halogenated aliphatic hydrocarbons containing chlorine, bromine, and iodine. In: Clayton GD Clayton FEeditors. Patty’s Industrial Hygiene and Toxicology. 4th ed. New York: Wiley-Interscience; 1994. p. 181–4189.
5 The Merck Index. O'Neil, MJ editor. 14th ed. Whitehouse Station, NJ: Merck and Company Inc.; 2006.
6 Cotti G Maltoni C Lefemine G Long-term carcinogenicity bioassay on vinylidene chloride administered by inhalation to Sprague-Dawley rats. New results. Ann N Y Acad Sci. 1988; 534(1):160–168. http://dx.doi.org/10.1111/j.1749-6632.1988.tb30109.x 3389653
7 Hazardous Substances Data Bank (HSDB). 1,1 Dichloroethylene. National Institute for Occupational Safety and Health; 2003.
8 International Programme on Chemical Safety (IPCS). Environmental Health Criteria 100, Vinylidene Chloride. Geneva, Switzerland: World Health Organization; 1990.
9 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for 1, 1-dichloroethene. U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 1994.
10 U.S. Environmental Protection Agency (USEPA). Toxicological Review of 1,1-Dichloroethylene (CAS No. 75-35-4) in Support of Summary Information on the Integrated Risk Information System (IRIS). Washington, DC: U.S. Environmental Protection Agency; 2002. EPA Report No. EPA/635/R02/002.
11 Maltoni CG Lefemine G Patella F Experimental research on vinylidene chloride carcino-genesis. Archives of Research on Industrial Carcino-genesis. Vol. III. Maltoni C Mehlman MAeditors. Princeton (NJ): Princeton Scientific; 1985.
12 Wallace LA Comparison of risks from outdoor and indoor exposure to toxic chemicals. Environ Health Perspect. 1991;95:7–13. http://dx.doi.org/10.1289/ehp.91957 1821381
13 American Conference of Governmental Industrial Hygienists (ACGIH). TLVs and BEIs Threshold Limit Values for Chemical Substances and Physical Agents and Biological Exposure Indices. Cincinnati, OH; 2013. p. 60.
14 McKenna MJ Zempel JA Madrid EO Gehring PJ The pharmacokinetics of [14C]vinylidene chloride in rats following inhalation exposure. Toxicol Appl Pharmacol. 1978; 45(2):599–610. http://dx.doi.org/10.1016/0041-008X(78)90121-7 705790
15 Dallas CE Weir FW Feldman S Putcha L Bruckner JV The uptake and disposition of 1,1-dichloroethylene in rats during inhalation exposure. Toxicol Appl Pharmacol. 1983; 68(1):140–151. http://dx.doi.org/10.1016/0041-008X(83)90363-0 6845373
16 Jaeger RJ Shoner LG Coffman L 1,1-Dichloroethylene hepatotoxicity: proposed mechanism of action and distribution and binding of 14C radioactivity following inhalation exposure in rats. Environ Health Perspect. 1977; 21:113–119. http://dx.doi.org/10.1289/ehp.7721113 612435
17 McKenna MJ Watanabe PG Gehring PJ Pharmacokinetics of vinylidene chloride in the rat. Environ Health Perspect. 1977; 21:99–105. http://dx.doi.org/10.1289/ehp.772199 612464
18 Bruckner JV White CA Muralidhara S Hines C Dallas CE Influence of exposure route and oral dosage regimen on 1, 1-dichloroethylene toxicokinetics and target organ toxicity. J Pharmacol Exp Ther. 2010; 333(2):519–527. http://dx.doi.org/10.1124/jpet.109.162479 20130112
19 Jones BK Hathway DE The biological fate of vinylidene chloride in rats. Chem Biol Interact. 1978; 20(1):27–41. http://dx.doi.org/10.1016/0009-2797(78)90078-9 630643
20 McKenna MJ Zempel JA Madrid EO Braun WH Gehring PJ Metabolism and pharmacokinetic profile of vinylidene chloride in rats following oral administration. Toxicol Appl Pharmacol. 1978; 45(3):821–835. http://dx.doi.org/10.1016/0041-008X(78)90173-4 725933
21 Reichert D Werner HW Metzler M Henschler D Molecular mechanism of 1,1-dichloroethylene toxicity: excreted metabolites reveal different pathways of reactive intermediates. Arch Toxicol. 1979; 42(3):159–169. http://dx.doi.org/10.1007/BF00353707 475590
22 Chieco P Moslen MT Reynolds ES Effect of administrative vehicle on oral 1,1-dichloroethylene toxicity. Toxicol Appl Pharmacol. 1981; 57(2):146–155. http://dx.doi.org/10.1016/0041-008X(81)90274-X 7222030
23 Putcha L Bruckner JV D’Souza R Desai F Feldman S Toxicokinetics and bioavailability of oral and intravenous 1,1-dichloroethylene. Fundam Appl Toxicol. 1986; 6(2):240–250. http://dx.doi.org/10.1016/0272-0590(86)90237-X 3699314
24 Jones BK Hathway DE Differences in metabolism of vinylidene chloride between mice and rats. Br J Cancer. 1978; 37(3):411–417. http://dx.doi.org/10.1038/bjc.1978.61 638019
25 Okine LK Goochee JM Gram TE Studies on the distribution and covalent binding of 1,1-dichloroethylene in the mouse. Effect of various pretreatments on covalent binding in vivo. Biochem Pharmacol. 1985; 34(22):4051–4057. http://dx.doi.org/10.1016/0006-2952(85)90386-7 4062975
26 Andersen ME French JE Gargas ML Jones RA Jenkins LJ Jr Saturable metabolism and the acute toxicity of 1,1-dichloroethylene. Toxicol Appl Pharmacol. 1979; 47(2):385–393. http://dx.doi.org/10.1016/0041-008X(79)90334-X 452030
27 D’Souza RW Andersen ME Physiologically based pharmacokinetic model for vinylidene chloride. Toxicol Appl Pharmacol. 1988; 95(2):230–240. http://dx.doi.org/10.1016/0041-008X(88)90159-7 3420614
28 Jaeger RJ Conolly RB Murphy SD Effect of 18 hr fast and glutathione depletion on 1,1-dichloroethylene-induced hepatotoxicity and lethality in rats. Exp Mol Pathol. 1974; 20(2):187–198. http://dx.doi.org/10.1016/0014-4800(74)90053-7 4824253
29 Reichert D Werner HW Henschler D Role of liver glutathione in 1,1-dichloroethylene metabolism and hepatotoxicity in intact rats and isolated perfused rat liver. Arch Toxicol. 1978; 41(3):169–178. http://dx.doi.org/10.1007/BF00354088 736789
30 Reynolds ES Moslen MT Boor PJ Jaeger RJ 1,1-Dichloroethylene hepatotoxicity. Time course of GSH changes and biochemical aberrations. Am J Pathol. 1980; 101(2):331–344. 7435541
31 Costa AK Ivanetich KM Vinylidene chloride: its metabolism by hepatic microsomal cytochrome P-450 in vitro. Biochem Pharmacol. 1982; 31(11):2083–2092. http://dx.doi.org/10.1016/0006-2952(82)90425-7 7115426
32 Liebler DC Meredith MJ Guengerich FP Formation of glutathione conjugates by reactive metabolites of vinylidene chloride in microsomes and isolated hepatocytes. Cancer Res. 1985; 45(1):186–193. 3965130
33 Liebler DC Latwesen DG Reeder TCS S-(2-chloroacetyl)glutathione, a reactive glutathione thiol ester and a putative metabolite of 1,1-dichloroethylene. Biochemistry. 1988; 27(10):3652–3657. http://dx.doi.org/10.1021/bi00410a020 3408718
34 Okine LK Gram TE In vitro studies on the metabolism and covalent binding of [14C]1,1-dichloroethylene by mouse liver, kidney and lung. Biochem Pharmacol. 1986; 35(16):2789–2795. http://dx.doi.org/10.1016/0006-2952(86)90191-7 3741469
35 Dowsley TF Forkert P-G Benesch LA Bolton JL Reaction of glutathione with the electrophilic metabolites of 1,1-dichloroethylene. Chem Biol Interact. 1995; 95(3):227–244. http://dx.doi.org/10.1016/0009-2797(94)03563-N 7728894
36 Forkert P-G In vivo formation and localization of 1,1-dichloroethylene epoxide in murine liver: identification of its glutathione conjugate 2-S-glutathionyl acetate. J Pharmacol Exp Ther. 1999; 290(3):1299–1306. 10454507
37 Forkert P-G 1,1-Dichloroethylene-induced Clara cell damage is associated with in situ formation of the reactive epoxide. Immunohistochemical detection of its glutathione conjugate. Am J Respir Cell Mol Biol. 1999; 20(6):1310–1318. http://dx.doi.org/10.1165/ajrcmb.20.6.3525 10340951
38 Jones JA Kaphalia L Treinen-Moslen M Liebler DC Proteomic characterization of metabolites, protein adducts, and biliary proteins in rats exposed to 1,1-dichloroethylene or diclofenac. Chem Res Toxicol. 2003; 16(10):1306–1317. http://dx.doi.org/10.1021/tx0340807 14565772
39 Simmonds AC Reilly CA Baldwin RM Ghanayem BI Lanza DL Yost GS Collins KS Forkert PG Bioactivation of 1,1-dichloroethylene to its epoxide by CYP2E1 and CYP2F enzymes. Drug Metab Dispos. 2004; 32(9):1032–1039. 15319346
40 Liebler DC Guengerich FP Olefin oxidation by cytochrome P-450: evidence for group migration in catalytic intermediates formed with vinylidene chloride and trans-1-phenyl-1-butene. Biochemistry. 1983; 22(24):5482–5489. http://dx.doi.org/10.1021/bi00293a005 6652073
41 Dowsley TF Ulreich JB Bolton JL Park SS Forkert P-G CYP2E1-dependent bioactivation of 1,1-dichloroethylene in murine lung: formation of reactive intermediates and glutathione conjugates. Toxicol Appl Pharmacol. 1996; 139(1):42–48. http://dx.doi.org/10.1006/taap.1996.0141 8685907
42 Forkert P-G Mechanisms of 1,1-dichloroethylene-induced cytotoxicity in lung and liver. Drug Metab Rev. 2001; 33(1):49–80. http://dx.doi.org/10.1081/DMR-100000140 11270662
43 Cossec B Cavelier L Moitessier-Bergé N Morel G de Ceaurriz J Formation of GSH-derivatives as a pathway for inactive intermediates in vinylidene chloride-treated rats. Toxicol Lett. 1996; 89(3):223–229. http://dx.doi.org/10.1016/S0378-4274(96)03819-2 9001591
44 Short RD Winston JM Minor JL Seifter J Lee C-C Effect of various treatments on toxicity of inhaled vinylidene chloride. Environ Health Perspect. 1977; 21:125–129. http://dx.doi.org/10.1289/ehp.7721125 612437
45 Kainz A Cross H Freeman S Gescher A Chipman JK Effects of 1,1-dichloroethene and of some of its metabolites on the functional viability of mouse hepatocytes. Fundam Appl Toxicol. 1993; 21(2):140–148. http://dx.doi.org/10.1006/faat.1993.1083 8405776
46 Lee RP Forkert P-G In vitro biotransformation of 1,1-dichloroethylene by hepatic cytochrome P-450 2E1 in mice. J Pharmacol Exp Ther. 1994; 270(1):371–376. 8035334
47 Dekant W Berthold K Vamvakas S Henschler D Anders MW Thioacylating intermediates as metabolites of S-(1,2-dichlorovinyl)-L-cysteine and S-(1,2,2-trichlorovinyl)-L-cysteine formed by cysteine conjugate beta-lyase. Chem Res Toxicol. 1988; 1(3):175–178. http://dx.doi.org/10.1021/tx00003a008 2979728
48 Lash LH Fisher JW Lipscomb JC Parker JC Metabolism of trichloroethylene. Environ Health Perspect. 2000; 108 Suppl 2:177–200. http://dx.doi.org/10.1289/ehp.00108s2177 10807551
49 Dowsley TF Reid K Petsikas D Ulreich JB Fisher RL Forkert P-G Cytochrome P-450-dependent bioactivation of 1,1-dichloroethylene to a reactive epoxide in human lung and liver microsomes. J Pharmacol Exp Ther. 1999; 289(2):641–648. 10215634
50 Jenkins LJ Jr Trabulus MJ Murphy SD Biochemical effects of 1,1-dichloroethylene in rats: comparison with carbon tetrachloride and 1,2-dichloroethylene. Toxicol Appl Pharmacol. 1972; 23(3):501–510. http://dx.doi.org/10.1016/0041-008X(72)90052-X 4404420
51 Ponomarkov V Tomatis L Long-term testing of vinylidene chloride and chloroprene for carcinogenicity in rats. Oncology. 1980; 37(3):136–141. http://dx.doi.org/10.1159/000225422 7360485
52 Siegel J Jones RA Coon RA Lyon JP Effects on experimental animals of acute, repeated and continuous inhalation exposures to dichloroacetylene mixtures. Toxicol Appl Pharmacol. 1971; 18(1):168–174. http://dx.doi.org/10.1016/0041-008X(71)90326-7 5542822
53 Short RD Winston JM Minor JL Hong CB Seifter J Lee CC Toxicity of vinylidene chloride in mice and rats and its alterations by various treatments. J Toxicol Environ Health. 1977; 3(5-6):913–921. http://dx.doi.org/10.1080/15287397709529625 202722
54 Jaeger R Trabulus M Murphy S The interaction of adrenalectomy, partial adrenal replacement therapy, and starvation with hepatotoxicity and lethality after 1,1-dichloroethylene intoxication. Toxicol Appl Pharmacol. 1973; 25(3):491.
55 Jaeger RJ Conolly RB Murphy SD Short-term inhalation toxicity of halogenated hydrocarbons: effects on fasting rats. Arch Environ Health. 1975; 30(1):26–31. http://dx.doi.org/10.1080/00039896.1975.10666628 1109268
56 Andersen ME Jenkins LJ Jr Oral toxicity of 1,1-dichloroethylene in the rat: effects of sex, age, and fasting. Environ Health Perspect. 1977; 21:157–163. http://dx.doi.org/10.1289/ehp.7721157 612440
57 Moslen MT Poisson LR Reynolds ES Cholestasis and increased biliary excretion of inulin in rats given 1,1-dichloroethylene. Toxicology. 1985; 34(3):201–209. http://dx.doi.org/10.1016/0300-483X(85)90171-4 3975918
58 Andersen ME Thomas OE Gargas ML Jones RA Jenkins LJ Jr The significance of multiple detoxification pathways for reactive metabolites in the toxicity of 1,1-dichloroethylene. Toxicol Appl Pharmacol. 1980; 52(3):422–432. http://dx.doi.org/10.1016/0041-008X(80)90337-3 7368215
59 Siegers CP Horn W Younes M Effect of phorone-induced glutathione depletion on the metabolism and hepatotoxicity of carbon tetrachloride and vinylidene chloride in rats. J Appl Toxicol. 1985; 5(6):352–356. http://dx.doi.org/10.1002/jat.2550050603 4078216
60 Kanz MF Whitehead RF Ferguson AE Moslen MT Potentiation of 1,1-dichloroethylene hepatotoxicity: comparative effects of hyperthyroidism and fasting. Toxicol Appl Pharmacol. 1988; 95(1):93–103. http://dx.doi.org/10.1016/S0041-008X(88)80011-5 3413796
61 Moussa M Forkert PG 1,1-Dichloroethylene-induced alterations in glutathione and covalent binding in murine lung: morphological, histochemical, and biochemical studies. J Pathol. 1992; 166(2):199–207. http://dx.doi.org/10.1002/path.1711660218 1560321
62 Andersen ME Jones RA Jenkins LJ Jr The acute toxicity of single, oral doses of 1,1-dichloroethylene in the fasted, male rat: effect of induction and inhibition of microsomal enzyme activities on mortality. Toxicol Appl Pharmacol. 1978; 46(1):227–234. http://dx.doi.org/10.1016/0041-008X(78)90153-9 725945
63 Moslen MT Whitehead RF Ferguson AE Kanz MF Protection by L-2-oxothiazolidine-4-carboxylate, a cysteine prodrug, against 1,1-dichloroethylene hepatotoxicity in rats is associated with decreases in toxin metabolism and cytochrome P-450. J Pharmacol Exp Ther. 1989; 248(1):157–163. 2913268
64 Gek Forkert P Moussa M 1,1-Dichloroethylene elicits dose-dependent alterations in covalent binding and glutathione in murine liver. Drug Metab Dispos. 1991; 19(3):580–586. 1717215
65 Forkert P-G Moussa M Temporal effects of 1,1-dichloroethylene on nonprotein sulfhydryl content in murine lung and liver. Drug Metab Dispos. 1993; 21(5):770–776. 7902234
66 Jenkins LJ Jr Andersen ME 1,1-Dichloroethylene nephrotoxicity in the rat. Toxicol Appl Pharmacol. 1978; 46(1):131–141. http://dx.doi.org/10.1016/0041-008X(78)90144-8 725939
67 Jackson NM Conolly RB Acute nephrotoxicity of 1,1-dichloroethylene in the rat after inhalation exposure. Toxicol Lett. 1985; 29(2-3):191–199. http://dx.doi.org/10.1016/0378-4274(85)90041-4 3937299
68 Ban M Hettich D Huguet N Cavelier L Nephrotoxicity mechanism of 1,1-dichloroethylene in mice. Toxicol Lett. 1995; 78(2):87–92. http://dx.doi.org/10.1016/0378-4274(94)03237-2 7618182
69 Cavelier L, Bonnet P, Morel G, de Ceaurriz J. Role of cysteine conjugation in vinylidene chloride‐induced nephrotoxicity and hepatotoxicity in fasted rats. J Appl Toxicol. 1996; 16(2):109-113. 10.1002/(SICI)1099-1263(199603)16:2<109:AID-JAT308>3.0.CO;2-9
70 Forkert P-G Reynolds ES 1,1-Dichloroethylene-induced pulmonary injury. Exp Lung Res. 1982; 3(1):57–68. http://dx.doi.org/10.3109/01902148209115816 7060543
71 National Toxicology Program (NTP). Carcinogenesis Bioassay of Vinylidene Chloride (CAS No. 75-35-4) in F344 Rats and B6C3F1 Mice (Gavage Study). Research Triangle Park, NC and Bethesda, MD: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1982. NIH Publication No. 82-1784. Technical Report Series No. 228.
72 Anderson D Hodge MC Purchase IF Dominant lethal studies with the halogenated olefins vinyl chloride and vinylidene dichloride in male CD-1 mice. Environ Health Perspect. 1977; 21:71–78. http://dx.doi.org/10.1289/ehp.772171 612461
73 Short RD Minor JL Winston JM Lee CC A dominant lethal study in male rats after repeated exposures to vinyl chloride or vinylidene chloride. J Toxicol Environ Health. 1977; 3(5-6):965–968. http://dx.doi.org/10.1080/15287397709529630 599591
74 Nitschke KD Smith FA Quast JF Norris JM Schwetz BA A three-generation rat reproductive toxicity study of vinylidene chloride in the drinking water. Fundam Appl Toxicol. 1983; 3(2):75–79. http://dx.doi.org/10.1016/S0272-0590(83)80059-1 6873531
75 Murray FJ Nitschke KD Rampy LW Schwetz BA Embryotoxicity and fetotoxicity of inhaled or ingested vinylidene chloride in rats and rabbits. Toxicol Appl Pharmacol. 1979; 49(2):189–202. http://dx.doi.org/10.1016/0041-008X(79)90241-2 494272
76 Lee CC Bhandari JC Winston JM House WB Peters PJ Dixon RL Woods JS Inhalation toxicity of vinyl chloride and vinylidene chloride. Environ Health Perspect. 1977; 21:25–32. http://dx.doi.org/10.1289/ehp.772125 565702
77 Lee CC Bhandari JC Winston JM House WB Dixon RL Woods JS Carcinogenicity of vinyl chloride and vinylidene chloride. J Toxicol Environ Health. 1978;4(1):15–30. http://dx.doi.org/10.1080/15287397809529640 633405
78 Viola PL Caputo A Carcinogenicity studies on vinylidene chloride. Environ Health Perspect. 1977; 21:45–47. http://dx.doi.org/10.1289/ehp.772145 612458
79 Hong CB Winston JM Thornburg LP Lee CC WSoods JS Follow-up study on the carcinogenicity of vinyl chloride and vinylidene chloride in rats and mice: tumor incidence and mortality subsequent to exposure. J Toxicol Environ Health. 1981; 7(6):909–924. http://dx.doi.org/10.1080/15287398109530034 7265317
80 Quast JF Humiston CG Wade CE Ballard J Beyer JE Schwetz RW Norris JM A chronic toxicity and oncogenicity study in rats and subchronic toxicity study in dogs on ingested vinylidene chloride. Fundam Appl Toxicol. 1983; 3(1):55–62. http://dx.doi.org/10.1016/S0272-0590(83)80173-0 6884624
81 Bartsch H Malaveille C Montesano R Tomatis L Tissue-mediated mutagenicity of vinylidene chloride and 2-chlorobutadiene in Salmonella typhimurium. Nature. 1975; 255(5510):641–643. http://dx.doi.org/10.1038/255641a0 1094302
82 Oesch F Protić-Sabljić M Friedberg T Klimisch H-J Glatt HR Vinylidene chloride: changes in drug-metabolizing enzymes, mutagenicity and relation to its targets for carcinogenesis. Carcinogenesis. 1983; 4(8):1031–1038. http://dx.doi.org/10.1093/carcin/4.8.1031 6347425
83 Jones BK Hathway DE Tissue-mediated mutagenicity of vinylidene chloride in Salmonella typhimurium TA1535. Cancer Lett. 1978; 5(1):1–6. http://dx.doi.org/10.1016/S0304-3835(78)80002-0 99228
84 Baden JM Kelley M Simmon VF Rice SA Mazze RI Fluroxene mutagenicity. Mutat Res. 1978; 58(2-3):183–191. http://dx.doi.org/10.1016/0165-1218(78)90008-3 34096
85 Mortelmans K Haworth S Lawlor T Speck W Tainer B Zeiger E Salmonella mutagenicity tests: II. Results from the testing of 270 chemicals. Environ Mutagen. 1986; 8 Suppl 7:1–119. https://doi.org/10.1002/em.2860080703 3516675
86 Greim H Bonse G Radwan Z Reichert D Henschler D Mutagenicity in vitro and potential carcinogenicity of chlorinated ethylenes as a function of metabolic oxiran formation. Biochem Pharmacol. 1975; 24(21):2013–2017. http://dx.doi.org/10.1016/0006-2952(75)90396-2 1108881
87 Henschler D Metabolism and mutagenicity of halogenated olefins—a comparison of structure and activity. Environ Health Perspect. 1977; 21:61–64. 348459
88 Koch R Schlegelmilch R Wolf HU Genetic effects of chlorinated ethylenes in the yeast Saccharomyces cerevisiae. Mutat Res. 1988; 206(2):209–216. http://dx.doi.org/10.1016/0165-1218(88)90162-0 3050501
89 Bronzetti G Bauer C Corsi C Leporini C Nieri R del Carratore R Genetic activity of vinylidene chloride in yeast. Mutat Res. 1981; 89(2):179–185. http://dx.doi.org/10.1016/0165-1218(81)90123-3 7027030
90 McGregor D Brown AG Cattanach P Edwards I McBride D Riach C Shepherd W Caspary WJ Van Zeeland A Responses of the L5178Y mouse lymphoma forward mutation assay: V. Gases and vapors. Environ Mol Mutagen. 1991; 17(2):122–129. http://dx.doi.org/10.1002/em.2850170209 2009867
91 Drevon C Kuroki T Mutagenicity of vinyl chloride, vinylidene chloride and chloroprene in V79 Chinese hamster cells. Mutat Res. 1979; 67(2):173–182. http://dx.doi.org/10.1016/0165-1218(79)90129-0 470972
92 Sawada M Sofuni T Ishidate M Jr Cytogenetic studies on 1,1-dichloroethylene and its two isomers in mammalian cells in vitro and in vivo. Mutat Res. 1987; 187(3):157–163. http://dx.doi.org/10.1016/0165-1218(87)90083-8 3821769
93 Reitz RH Watanabe PG McKenna MJ Quast JF Gehring PJ Effects of vinylidene chloride on DNA synthesis and DNA repair in the rat and mouse: a comparative study with dimethylnitrosamine. Toxicol Appl Pharmacol. 1980; 52(3):357–370. http://dx.doi.org/10.1016/0041-008X(80)90329-4 7368211
94 Brecher G, Schneiderman M. A time-saving device for the counting of reticulocytes. Am J Clin Pathol. 1950; 20(11_ts):2079-2084. 10.1093/ajcp/20.11_ts.1079
95 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
96 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing Park Ridge. NJ: Noyes Publications; 1985. p. 345–357.
97 McConnell EE Solleveld HA Swenberg JA Boorman GA Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
98 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
99 Cox DR Regression models and life‐tables. J Roy Stat Soc B Met. 1972; 34(2):187–220.
100 Tarone RE Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
101 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. http://dx.doi.org/10.2307/2531856 3390507
102 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. http://dx.doi.org/10.1016/0272-0590(89)90004-3 2744275
103 Piegorsch WW, Bailer AJ. Statistics for Environmental Biology and Toxicology. Section 6.3.2. London: Chapman and Hall; 1997.
104 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
105 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. http://dx.doi.org/10.2307/2532200 8241374
106 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. http://dx.doi.org/10.1080/01621459.1955.10501294
107 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
108 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
109 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
110 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
111 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. http://dx.doi.org/10.1080/00401706.1964.10490181
112 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. http://dx.doi.org/10.2307/2333011
113 Dixon WJ Massey FJ Jr Introduction to Statistical Analysis. 2nd ed. New York: McGraw Hill Book Company Inc.; 1957. p. 276–278, 412.
114 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
115 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. http://dx.doi.org/10.2307/2531963 3567307
116 Haseman JK Data analysis: statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59, discussion 81–86. http://dx.doi.org/10.1006/rtph.1995.1009 7784636
117 Haseman JK Rao GN Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. http://dx.doi.org/10.1177/019262339202000107 1411131
118 Code of Federal Regulations (CFR). 21:Part 58.
119 Schmid W The micronucleus test. Mutat Res. 1975; 31(1):9–15. http://dx.doi.org/10.1016/0165-1161(75)90058-8 48190
120 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. http://dx.doi.org/10.1016/0165-1110(83)90047-7 6888413
121 Miller JA Miller EC Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH Watson JD Winsten JAeditors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
122 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
123 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA Flamm WG Lorentzen RJeditors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co. Inc.; 1985. p. 13–59.
124 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991; 257(3):229–306. http://dx.doi.org/10.1016/0165-1110(91)90003-E 1707500
125 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. http://dx.doi.org/10.1126/science.3554512 3554512
126 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RW Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16 Suppl 18:1–14. http://dx.doi.org/10.1002/em.2850160502 2091921
127 Shelby MD Erexson GL Hook GJ Tice RR Evaluation of a three-exposure mouse bone marrow micronucleus protocol: results with 49 chemicals. Environ Mol Mutagen. 1993;21(2):160–179. http://dx.doi.org/10.1002/em.2850210210 8444144
128 Shelby MD Witt KL Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. http://dx.doi.org/10.1002/em.2850250407 7607185
129 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
130 Foureman P Mason JM Valencia R Zimmering S Chemical mutagenesis testing in Drosophila. IX. Results of 50 coded compounds tested for the National Toxicology Program. Environ Mol Mutagen. 1994; 23(1):51–63. http://dx.doi.org/10.1002/em.2850230109 8125083
131 Roberts SM Jordan KE Warren DA Britt JK James RC Evaluation of the carcinogenicity of 1,1-dichloroethylene (vinylidene chloride). Regul Toxicol Pharmacol. 2002; 35(1):44–55. http://dx.doi.org/10.1006/rtph.2001.1518 11846635
132 Kanz MF Taj Z Moslen MT 1,1-Dichloroethylene hepatotoxicity: hypothyroidism decreases metabolism and covalent binding but not injury in the rat. Toxicology. 1991; 70(2):213–229. http://dx.doi.org/10.1016/0300-483X(91)90048-6 1763416
133 Rampy LW Quast JF Humiston CG Balmer MF Schwetz BA Interim results of two-year toxicological studies in rats of vinylidene chloride incorporated in the drinking water or administered by repeated inhalation. Environ Health Perspect. 1977; 21:33–43. http://dx.doi.org/10.1289/ehp.772133 612457
134 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for 1,1-dichloroethene. U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2009.
135 Jaeger RJ Conolly RB Reynolds ES Murphy SD Biochemical toxicology of unsaturated halogenated monomers. Environ Health Perspect. 1975; 11:121–128. http://dx.doi.org/10.1289/ehp.7511121 1175549
136 Forkert P-G Forkert L Farooqui M Reynolds ES Lung injury and repair: DNA synthesis following 1,1-dichloroethylene. Toxicology. 1985; 36(2-3):199–214. http://dx.doi.org/10.1016/0300-483X(85)90054-X 4049431
137 Krantz SB Erythropoietin. Blood. 1991; 77(3):419–434. 10.1182/blood.V77.3.419.419 1991159
138 Hall RL Everds NE Principles of clinical pathology for toxicology studies. In: Hayes AWeditor. Principles and Methods of Toxicology. 5th ed. Boca Raton (FL): CRC press; 2008. p. 1317–1358.
139 Colotta F Allavena P Sica A Garlanda C Mantovani A Cancer-related inflammation, the seventh hallmark of cancer: links to genetic instability. Carcinogenesis. 2009; 30(7):1073–1081. http://dx.doi.org/10.1093/carcin/bgp127 19468060
140 Hanahan D Weinberg RA The hallmarks of cancer. Cell. 2000; 100(1):57–70. http://dx.doi.org/10.1016/S0092-8674(00)81683-9 10647931
141 Hanahan D Weinberg RA Hallmarks of cancer: the next generation. Cell. 2011; 144(5):646–674. http://dx.doi.org/10.1016/j.cell.2011.02.013 21376230
142 Hathway DE Comparative mammalian metabolism of vinyl chloride and vinylidene chloride in relation to oncogenic potential. Environ Health Perspect. 1977; 21:55–59. http://dx.doi.org/10.1289/ehp.772155 612460
143 Mutsaers SE McAnulty RJ Laurent GJ Versnel MA Whitaker D Papadimitriou JM Cytokine regulation of mesothelial cell proliferation in vitro and in vivo. Eur J Cell Biol. 1997; 72(1):24–29. 9013722
144 Maltoni C Cotti G Morisi L Chieco P Carcinogenicity bioassays of vinylidene chloride. Research plan and early results. Med Lav. 1977; 68(4):241–262. 916967
145 Quast JF McKenna MJ Rampy LW Norris JM Chronic toxicity and oncogenicity study on inhaled vinylidene chloride in rats. Fundam Appl Toxicol. 1986; 6(1):105–144. http://dx.doi.org/10.1016/0272-0590(86)90269-1 3710018
146 Lash LH Jones D Anders M Glutathione homeostasis and glutathione S-conjugate toxicity in the kidney. Reviews in Biochemical Toxicology. New York: Elsevier; 1988. p. 29–67.
147 Elfarra AA Anders MW Renal processing of glutathione conjugates. Role in nephrotoxicity. Biochem Pharmacol. 1984; 33(23):3729–3732. http://dx.doi.org/10.1016/0006-2952(84)90032-7 6508831
148 Elfarra AA Jakobson I Anders MW Mechanism of S-(1,2-dichlorovinyl)glutathione-induced nephrotoxicity. Biochem Pharmacol. 1986; 35(2):283–288. http://dx.doi.org/10.1016/0006-2952(86)90527-7 2867768
149 Eyre RJ Stevens DK Parker JC Bull RJ Renal activation of trichloroethene and S-(1,2-dichlorovinyl)-L-cysteine and cell proliferative responses in the kidneys of F344 rats and B6C3F1 mice. J Toxicol Environ Health. 1995; 46(4):465–481. http://dx.doi.org/10.1080/15287399509532049 8523472
150 Eyre RJ Stevens DK Parker JC Bull RJ Acid-labile adducts to protein can be used as indicators of the cysteine S-conjugate pathway of trichloroethene metabolism. J Toxicol Environ Health. 1995; 46(4):443–464. http://dx.doi.org/10.1080/15287399509532048 8523471
151 Caspary WJ Lee YJ Poulton S Myhr BC Mitchell AD Rudd CJ Evaluation of the L5178Y mouse lymphoma cell mutagenesis assay: quality-control guidelines and response categories. Environ Mol Mutagen. 1988; 12 Suppl 13:19–36. http://dx.doi.org/10.1002/em.2860120503 3416839
152 Mason JM Valencia R Zimmering S Chemical mutagenesis testing in Drosophila: VIII. Reexamination of equivocal results. Environ Mol Mutagen. 1992; 19(3):227–234. http://dx.doi.org/10.1002/em.2850190307 1572346
153 Margolin BH Collings BJ Mason JM Statistical analysis and sample-size determinations for mutagenicity experiments with binomial responses. Environ Mutagen. 1983; 5(5):705–716. http://dx.doi.org/10.1002/em.2860050509 6617600
154 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990; 14(3):513–522. http://dx.doi.org/10.1016/0272-0590(90)90255-I 2111256
155 Aldrich Chemical Company Inc. The Aldrich Library ^13^C and ^1^H FT-NMR Spectra. 1st ed. Pouchert C Behnke Jeditors. Milwaukee (WI); 1993. p. 142.
156 Aldrich Chemical Company Inc. In: Pouchert C, editor. The Aldrich Library of FT IR Spectra 2ed. Milwaukee, WI; 1997. p. 140D.
157 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of codeine (CAS No. 76-57-3) in F344 rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. Technical Report Series No. 455. NIH Publication No. 96-3360. https://ntp.niehs.nih.gov/results/pubs/longterm/reports/longterm/tr400499/abstracts/tr455/index.html
158 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of riddelliine (CAS No. 23246-96-0) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2003. Technical Report Series No. 508. NIH Publication No. 03-4442.
159 National Toxicology Program (NTP). Toxicology studies of cobalt metal (CAS No. 7440-48-4) in F344/N rats and B6C3F1 mice and toxicology and carcinogenesis studies of cobalt metal in F344/NTac rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2014. Technical Report Series No. 581. NIH Publication No. 98-3961.
160 Crosby LM Hyder KS DeAngelo AB Kepler TB Gaskill B Benavides GR Yoon L Morgan KT Morphologic analysis correlates with gene expression changes in cultured F344 rat mesothelial cells. Toxicol Appl Pharmacol. 2000;169(3):205–221. http://dx.doi.org/10.1006/taap.2000.9049 11133343
161 Kim Y Ton TV DeAngelo AB Morgan K Devereux TR Anna C Collins JB Paules RS Crosby LM Sills RC Major carcinogenic pathways identified by gene expression analysis of peritoneal mesotheliomas following chemical treatment in F344 rats. Toxicol Appl Pharmacol. 2006; 214(2):144–151. http://dx.doi.org/10.1016/j.taap.2005.12.009 16460773
162 Gautier L Cope L Bolstad BM Irizarry RA affy—analysis of Affymetrix GeneChip data at the probe level. Bioinformatics. 2004; 20(3):307–315. http://dx.doi.org/10.1093/bioinformatics/btg405 14960456
163 Irizarry RA Bolstad BM Collin F Cope LM Hobbs B Speed TP Summaries of Affymetrix GeneChip probe level data. Nucleic Acids Res. 2003; 31(4):e15. http://dx.doi.org/10.1093/nar/gng015 12582260
164 Guo W Sarkar SK Peddada SD Controlling false discoveries in multidimensional directional decisions, with applications to gene expression data on ordered categories. Biometrics. 2010; 66(2):485–492. http://dx.doi.org/10.1111/j.1541-0420.2009.01292.x 19645703
165 Peddada S Harris S Zajd J Harvey E ORIOGEN: order restricted inference for ordered gene expression data. Bioinformatics. 2005; 21(20):3933–3934. http://dx.doi.org/10.1093/bioinformatics/bti637 16109745
166 Garlepp MJ Leong CC Biological and immunological aspects of malignant mesothelioma. Eur Respir J. 1995;8(4):643–650. 7664867
167 Okamoto O Fujiwara S Abe M Sato Y Dermatopontin interacts with transforming growth factor beta and enhances its biological activity. Biochem J. 1999;337(Pt 3):537–541. http://dx.doi.org/10.1042/bj3370537 9895299
168 Mantovani A Molecular pathways linking inflammation and cancer. Curr Mol Med. 2010; 10(4):369–373. http://dx.doi.org/10.2174/156652410791316968 20455855
169 Mukaida N Pathophysiological roles of interleukin-8/CXCL8 in pulmonary diseases. Am J Physiol Lung Cell Mol Physiol. 2003; 284(4):L566–L577. http://dx.doi.org/10.1152/ajplung.00233.2002 12618418
170 Wang KS Frank DA Ritz J Interleukin-2 enhances the response of natural killer cells to interleukin-12 through up-regulation of the interleukin-12 receptor and STAT4. Blood. 2000; 95(10):3183–3190. 10807786
171 Blackshear PE Pandiri AR Ton TV Clayton NP Shockley KR Peddada SD Gerrish KE Sills RC Hoenerhoff MJ Spontaneous mesotheliomas in F344/N rats are characterized by dysregulation of cellular growth and immune function pathways. Toxicol Pathol. 2014; 42(5):863–876. http://dx.doi.org/10.1177/0192623313501894 23980201