# Conclusions

Under the conditions of this 2-year inhalation study, there was clear evidence of carcinogenic activity^a^ of vinylidene chloride in male F344/N rats based on increased incidences of malignant mesothelioma. Increased incidences of renal tubule carcinoma and respiratory epithelium adenoma in the nose of male rats were also considered to be related to vinylidene chloride exposure. There was some evidence of carcinogenic activity of vinylidene chloride in female F344/N rats based on increased incidences of C-cell adenoma or carcinoma in the thyroid gland and systemic mononuclear cell leukemia. Occurrences of malignant mesothelioma may have been related to vinylidene chloride exposure. There was clear evidence of carcinogenic activity of vinylidene chloride in male B6C3F1/N mice based on increased incidences of renal tubule adenoma and carcinoma. Increased incidences of hepatocholangiocarcinoma may have been related to vinylidene chloride exposure. There was clear evidence of carcinogenic activity of vinylidene chloride in female B6C3F1/N mice based on increased incidences of systemic hemangioma or hemangiosarcoma (combined). Hepatocholangiocarcinoma and hepatocellular adenoma or carcinoma (combined) in the liver of female mice were also considered to be related to vinylidene chloride exposure. Increased incidences of alveolar/bronchiolar carcinoma in the lungs and carcinoma of the small intestine may have been related to treatment.

a See Explanation of Levels of Evidence of Carcinogenic Activity. See summary of the peer review panel comments and the public discussion on this Technical Report in Appendix M.

Exposure to vinylidene chloride caused increases in the incidences of nonneoplastic lesions in the nose of rats and mice, the liver of rats, the lung of male rats, and the kidney of male mice.