# Discussion

Vinylidene chloride was nominated for study by the Agency for Toxic Substances and Disease Registry (ATSDR), based on insufficient critical information regarding its health effects as a priority hazardous substance under the Substance Specific Applied Research Program at ATSDR. The findings of previous gavage studies conducted by NTP^71^ were considered no evidence of carcinogenicity in male or female F344/N rats or B6C3F1 mice. However, because a maximum tolerated dose was not clearly demonstrated and previous studies suggested carcinogenicity associated with inhalation exposure, it was concluded that the studies should not be interpreted that vinylidene chloride is not a carcinogen. Despite a broad database of research from other published studies, adequate data do not exist regarding the carcinogenicity of vinylidene chloride. Although there have been many chronic inhalation and gavage studies reported in the literature, nearly all of these studies are insufficient to accurately evaluate the carcinogenicity of vinylidene chloride. The primary issue with the previously reported studies was that exposure durations were inadequate (12 months or less). However, other issues included changing or discontinuing dosing or exposure concentrations during the study, excessive mortality, inappropriate range of exposures, presence of potential contaminants (vinyl chloride), and lack of statistical description or analysis. The current United States Environmental Protection Agency (USEPA) carcinogen risk assessment is based on increased incidences of adrenal pheochromocytomas that were not statistically significant and thereby not considered treatment related in the previously conducted NTP gavage study.^71,131^

The effects of whole body inhalation exposure to vinylidene chloride for 2 weeks, 3 months, or 2 years were studied in male and female F344/N rats and B6C3F1/N mice. Overall, mice were more sensitive to vinylidene chloride-induced toxicity than rats. Species- and strain-specific differences in vinylidene chloride-induced mor-tality have been widely reported. For the current 2-week study of B6C3F1/N mice, exposure concentrations of 50 ppm or greater in males and 100 ppm or greater in females caused decreased survival; in F344/N rats, decreased survival was observed at 200 and 400 ppm. In both rats and mice, the liver and kidney were target organs in early-death animals. Early deaths in both sexes of rats and mice were associated with marked centrilobular necrosis in the liver and granular casts in the kidney. In male mice, necrosis was observed in the renal tubules. These hepatic and nephrotoxic effects associated with mortality occurred quickly after the start of exposure. Kanz et al.^132^ demonstrated that, within 12 hours of a single oral administration of 100 mg/kg in Sprague Dawley rats, vinylidene chloride induced the formation of pyknotic hepatocytes, prenecrotic or preapoptotic cells identifiable by the condensation of chromatin in the nucleus. These data suggest that the observed liver effects may be a contributing factor in vinylidene chloride-induced mortality. In the 2-week mouse studies, necrosis of the respiratory epithelium in the nose also occurred in all of the early-death males and females. In the 3-month study, decreased survival in female mice exposed to 100 ppm was also associated with increased incidences of necrosis in the liver, nose, lung, and larynx.

In the 2-week studies, the liver was a target organ for male and female rats and mice. In rats, liver lesions consisted of centrilobular hepatocellular cytoplasmic alteration in 25, 50, and 100 ppm males and females and centrilobular hepatocellular necrosis in the 200 and 400 ppm groups. The cytoplasmic alteration is suggestive of a degenerative lesion in the lower dose groups, which culminates in hepatocellular necrosis at higher doses. In mice, liver lesions consisted of hepatocellular necrosis in males and females exposed to 100, 200, or 400 ppm vinylidene chloride, and there was evidence of hepatocellular regeneration in the 100 ppm female group.

The kidney was also a target organ for male and female rats and male mice in the 2-week studies. In rats, increased kidney weights were observed in both sexes. Kidney lesions consisted of tubule cast formation in the renal papillae in the 200 and 400 ppm males and females. In male mice, lesions were more severe, characterized not only by granular cast formation, but also proximal renal tubule necrosis in all dosed males.

The nose was also a target organ for male and female mice in the 2-week study. Lesions in the nose included respiratory epithelial necrosis in all 100, 200, and 400 ppm males and 200 and 400 ppm females.

In the 3-month studies, no effects on survival or body weights were observed in rats exposed to concentrations of vinylidene chloride up to 100 ppm; in mice, decreased survival was observed in 50 ppm males and 100 ppm females. Final mean body weights in all vinylidene chloride-exposed groups of female mice were significantly less than that of the chamber controls (9% to 18%), and in male mice there were exposure concentration-dependent decreases (10% to 16%) at 12.5 ppm or greater.

In the 3-month studies, the liver was a target organ in both sexes of rats and in female mice. In male rats, liver lesions consistent with cytoplasmic alteration as observed in the 2-week study occurred at 12.5 ppm or greater, whereas in females, cytoplasmic vacuolization consistent with fatty change was observed at 50 and 100 ppm, suggesting a potential sex-related difference in liver pathology induced by vinylidene chloride. The biologic significance of this difference is unknown. In female mice, liver necrosis and centrilobular hypertrophy were observed at 100 ppm. Although mild liver necrosis occurred in two 50 ppm males, this was not statistically significant; however, given the response in females, this may be related to exposure to vinylidene chloride. Hepatotoxicity was also reflected in mild transient treatment-related increases in sorbitol dehydrogenase and alanine aminotransferase activities. These effects in the liver are consistent with previously reported and well-established vinylidene chloride-induced hepatotoxicity. Various inhalation studies in rodents have demonstrated hepatocellular degeneration, necrosis, and cytoplasmic vacuolization following exposure to vinylidene chloride at concentrations ranging from 15 to 200 ppm.^30,71,133,134^ In male and female Sprague Dawley rats exposed to 25 and 75 ppm vinylidene chloride by inhalation for 6 or 12 months, midzonal hepatocellular fatty changes were observed.^80^ Alteration in serum markers of hepatocellular injury, including sorbitol dehydrogenase, alanine aminotransferase, aspartate transaminase, and ornithine carbomyl transferase activities, have also been widely reported following acute inhalation of vinylidene chloride^55,67,135^ or oral administration.^56,63,66^

In the nose at 3 months, rats were more sensitive than mice to the treatment-related effects of vinylidene chloride. Increased incidences of atrophy, mineralization, and necrosis of olfactory epithelium were observed in both sexes of rats, whereas only respiratory epithelial necrosis was observed in female mice exposed to 100 ppm. In rats exposed to 6.25 ppm or greater, significant increases in the incidences of olfactory epithelium mineralization in both sexes and of atrophy in males were observed. In males, necrosis of the olfactory epithelium was increased at 12.5 ppm or greater. In females, olfactory epithelium atrophy at 12.5 ppm or greater and olfactory epithelium necrosis at 25 ppm or greater were increased. In general, the severity of these lesions increased with increasing exposure concentration.

In the 3-month studies, nasal turbinate atrophy occurred in all rats exposed to 12.5 ppm or greater, and the severities increased with increasing exposure concentration, whereas an increased incidence was observed only in 100 ppm female mice. Turbinate atrophy was not observed in any of the chamber controls, 6.25 ppm male or female rats, or at 50 ppm or less in female mice. In the lung of 100 ppm female mice, minimal to marked necrosis of the bronchial epithelium and minimal to mild histiocytic inflammation occurred. In contrast to rats, lesions were observed in the larynx of high dose male and female mice and in the lung of high dose female mice, which is consistent with involvement of both the upper and lower respiratory tract. Increased incidences of squamous metaplasia of the respiratory epithelium were observed at 50 ppm in both sexes of mice and at 100 ppm in females, and lesion incidences and severities were greater in females than males. Additional lesions of respiratory epithelial hyperplasia and necrosis in the larynx were observed in 100 ppm female mice. These species differences in pulmonary injury are consistent with those reported in male C57BL/6 mice,^136^ but not in male Sprague Dawley rats^22^ administered a single gavage dose of 200 mg/kg vinylidene chloride. In male C57BL/6 mice, Forkert et al.^136^ showed that exposure to vinylidene chloride increased lung weights, induced necrosis and exfoliation of Clara cells in the bronchiolar epithelium, and resulted in peribronchiolar and perivascular edema. This pulmonary injury in mice was transient, and a regenerative response was observed 3 days after exposure, with the integrity of the epithelium substantially restored by 7 days. While neither of these studies included females for evaluation, these data are consistent with species-specific sensitivity between rats and mice.

In the current 3-month studies, the kidney was a target organ in male mice, but not rats or female mice. Increased incidences of minimal to moderate nephropathy were observed in male mice at 12.5 ppm or greater with exposure concentration-dependent increases in the severities. In addition, two 50 ppm males had proximal renal tubule necrosis and cast formation, consistent with the kidney findings in the 2-week study. While the incidences of necrosis and cast formation were not statistically significant, they were considered to be related to exposure to vinylidene chloride. In rats, dose-dependent increases (8% to 16%) in kidney weights were observed in females exposed to 12.5 ppm or greater; however, no corresponding changes in histopathology were observed. In the previous NTP^71^ gavage studies, chronic renal inflammation was observed in both sexes of F344/N rats exposed to 5 mg/kg following 2 years of exposure.

Corresponding to the nephropathy, there were mild exposure concentration-dependent decreases in the erythrocyte counts, hemoglobin concentration, and hematocrit values of the 12.5 ppm and greater male mice in the 3-month study. These decreases may be related to the decreases in body weight as well as the nephropathy, as the kidneys are the primary source of erythropoietin production. Specifically, erythropoietin is produced by interstitial peritubular cells within interstitial foci mostly adjacent to the proximal convoluted tubules.^137^ Injury to these areas of the kidney, like that observed in this study, can lead to decreased production of erythropoietin with a subsequent decrease in erythropoiesis and total red blood cell mass. In addition, reductions in erythropoiesis with renal injury are also attributed to the effects of uremic toxins.^138^

The observed species differences in the current 2-week and 3-month studies are consistent with previous reports that mice are more susceptible than rats to vinylidene chloride-induced nephrotoxicity. In male CD-1 mice, kidney nephrosis was observed within 24 hours of inhalation exposure to 50 ppm.^93^ Moderate-to-severe nephrosis was also observed in four strains of mice exposed to 55, 100, or 200 ppm 6 hours/day, 5 days per week for 10 days.^134^ Nephrotoxicity has also been observed in rats, but at higher exposure concentrations. In male Sprague Dawley rats, exposure to greater than 300 ppm vinylidene chloride induced tubular necrosis with calcium deposits.^67^ At 250 ppm, vinylidene chloride induced moderate cellular swelling in the renal cortex. In fasted males, which are more sensitive to the toxicity of vinylidene chloride, marked degeneration of proximal tubular epithelium was observed at 200 ppm.^20^ In male and female Sprague Dawley rats fasted overnight, oral administration of a single gavage dose of 400 mg/kg vinylidene chloride increased serum markers of renal toxicity and induced dose-related histopathologic changes in the kidney, including vacuolization, pigmentation, tubular dilation, and necrosis.^66^

In the 2-year study in rats, increased incidences of neoplasms were observed in the nose and kidney of males and in the thyroid gland of females exposed to vinylidene chloride. Increased incidences of systemic neoplasms were also observed in both sexes, including malignant mesotheliomas in males and mononuclear cell leukemias in females. In males, vinylidene chloride induced marked increases in the incidences of malignant mesothelioma in all exposed groups with a concentration-dependent decrease in the time to first incidence. These neoplasms were associated with gross observations of fluid in the abdomen and multiple nodules throughout the peritoneum, particularly on the testicular tunics and epididymides, but also involved a variety of abdominal organs including the intestines, mesentery, pancreas, prostate gland, spleen, and liver. One 25 ppm male had mesothelioma within the pleura and pericardium in addition to the testicular and epididymal sites. In addition, mesotheliomas were observed in the thoracic cavity of one 25 ppm and the abdominal cavity of one 50 ppm female. Malignant mesothelioma is an uncommon background neoplasm in male F344/N rats, most often arising from the testicular tunics. This neoplasm is very rare in female rats. Therefore, the vinylidene chloride-induced increase in the incidences of malignant mesothelioma in male rats was considered clear evidence for carcinogenicity. The malignant mesotheliomas observed in two female rats may have been related to vinylidene chloride exposure.

Compared to spontaneous mesotheliomas in control animals, mesotheliomas arising in vinylidene chloride-exposed animals had overrepresentation of pathways associated with a proinflammatory response and immune dysregulation. These global gene changes allowed separation of background spontaneous mesotheliomas from those arising in vinylidene chloride-exposed animals based on genomic signatures, despite indistinguishable morphology between these neoplasm groups.

A molecular phenotype consistent with a proinflammatory response, immune dysregulation, or tissue damage has been shown to be associated with mechanisms of tumorigenesis, including development of mesothelioma. Inflammation is a well-known contributor to mesotheliomagenesis.^139-141^ Exposure to vinylidene chloride results in saturation of the glutathione pathway and the generation of reactive vinylidene chloride metabolites (1,1-diethylene oxide, chloroacetyl chloride), which have the potential to cause tissue damage.^142^ Although there was not a significant inflammatory response observed in either spontaneous or vinylidene chloride-treated mesotheliomas nor a significant difference in necrosis, apoptosis, or tissue damage between the tumor groups, molecular features suggest a proinflammatory microenvironment. Anti-inflammatory cytokines and chemokines were underrepresented in vinylidene chloride-exposed mesotheliomas compared to spontaneous tumors, while pattern recognition receptors and damage-associated molecular pattern molecules were upregulated, consistent with immune dysregulation and a proinflammatory response. Responses such as these have been associated with mesothelial cell proliferation.^143^ The overrepresentation of these complex pathways supports the observation of a proinflammatory environment associated with mesotheliomas in vinylidene chloride-exposed animals.

In female rats, the incidence of mononuclear cell leukemia in the 100 ppm group was significantly increased, and the time to first incidence was markedly shorter (by 236 days) than in the chamber controls. The time to first incidence was also decreased in the 25 and 50 ppm groups; however, the incidences in these groups were comparable to the chamber control incidence. Mononuclear cell leukemia is a relatively common background neoplasm in F344/N rats, but there was a significant increase in the 100 ppm females that exceeded the historical control ranges for studies by inhalation exposure and all routes combined. There was also an exposure-dependent decrease in the time to first incidence of the neoplasms. Therefore, the increased incidence of mononuclear cell leukemia in females exposed to 100 ppm was considered to be related to vinylidene chloride exposure. Cotti et al.^6^ also reported increased incidences of leukemia in male and female Sprague Dawley rats exposed to 100 ppm vinylidene chloride in utero starting on gestation day 12 for a duration of 104 weeks. These leukemias were described as a variety of hemolymphoreticular neoplastic diseases at different sites. In the NTP^71^ gavage study, there was a higher incidence of lymphoma or leukemia observed at 1 mg/kg but not at 5 mg/kg when compared to chamber controls, but these lesions were not considered related to vinylidene chloride exposure.

In the thyroid gland, C-cell adenomas were increased in the 100 ppm female rats and occurred with a positive exposure concentration-dependent trend. C-cell carcinomas were observed in all groups of exposed females with a significant increased incidence occurring at 25 ppm, but not at 50 or 100 ppm. C-cell carcinomas are rare neoplasms in the F344/N rat. The incidences at 50 and 100 ppm, while not statistically significant, exceeded the historical control range for the inhalation route of exposure in female rats. The combined incidences of adenoma or carcinoma were increased in all exposed female groups compared to controls, with significant increases observed at 25 and 100 ppm. However, there was no accompanying increase in the incidences of hyperplasia, and the increases were not exposure concentration-dependent. Exposure to vinylidene chloride did not induce C-cell neoplasms in males. The increases in C-cell neoplasms in female rats were considered to be related to vinylidene chloride exposure. These findings were considered some evidence of carcinogenic activity.

In the kidney, renal tubule carcinomas were observed in male rats exposed to vinylidene chloride for 2 years. While the incidences were not statistically significant, these neoplasms are exceedingly rare in male F344/N rats and have not been observed in 200 historical controls from inhalation studies. Furthermore, after single and step section evaluations were combined, a dose-related increase in the incidences of renal tubule hyperplasia were observed in exposed male rats; this lesion may be considered a precursor to neoplasm formation. In addition, there was a robust kidney neoplasm response in vinylidene chloride-exposed male mice in the corresponding mouse study, further supporting the kidney as a target of carcinogenesis in rats.

As observed in the 3-month study, the nose was a target organ for toxicity in the 2-year study in rats. In males, there was a positive trend in the incidences of adenoma of the respiratory epithelium. While the incidences of this neoplasm were low, no nasal adenomas were observed in any of the 697 historical controls from studies with all routes of exposure in F344/N rats. In addition, nonneoplastic lesions occurred in both sexes with increased incidences and severities with increasing exposure concentration. These lesions included turbinate atrophy and hyperostosis, respiratory metaplasia of olfactory epithelium, chronic active inflammation, respiratory epithelial hyperplasia, and thrombosis. These nonneoplastic lesions are consistent with chronic injury and repair, a process that has been linked with carcinogenesis; therefore, the nasal adenomas in males were considered to be related to exposure to vinylidene chloride. In the lower respiratory tract, there was an increased incidence of alveolar epithelium hyperplasia in all exposed male groups with an exposure concentration-dependent increase in severity. However, no neoplasms were observed in the lung, indicating that the nose was the primary target of vinylidene chloride exposure.

The liver was a target organ for toxicity in 2-year rats, but exposure to vinylidene chloride did not induce any treatment-related hepatic neoplasms. Vinylidene chloride induced chronic inflammation and diffuse fatty change in both sexes at all exposure concentrations. Necrosis and cystic degeneration were also observed at higher exposure concentrations.

Nonneoplastic lesions observed at increased incidences included ovarian bursal dilatation and mesenteric fat necrosis. The incidences of bursal dilatation of the ovary were significantly increased in an exposure concentration-related manner, and the severities were increased in the exposed groups. The etiology of bursal dilatation may involve obstruction of the oviduct or other lower reproductive tract structures due to chronic inflammation or other abnormality; however, no such predisposing factor was noted grossly or on histopathologic examination. As such, the cause of increase in the incidences of ovarian bursal dilatation remains uncertain, and its biologic significance in this study is unknown. Increased incidences of fat necrosis of the mesentery were observed in all groups of exposed female rats. Localized fat necrosis may occur secondary to peritonitis or inflammatory lesions in the liver and other organs; however, this needs to be further substantiated, as the definitive cause of this lesion could not be determined, and, thus, its biologic relevance is uncertain. There are also treatment- and exposure concentration-related increases in the companion mouse study, which suggest a similar effect across species. However, because histopathologic examination of this lesion was only performed when gross lesions in the mesenteric fat were observed, the true incidence and biologic relevance of this lesion remain unknown.

The current 2-year rat study demonstrates that vinylidene chloride induced malignant mesotheliomas, renal tubule carcinomas, and nasal respiratory epithelium adenomas in males, and mononuclear cell leukemia and thyroid gland C-cell adenomas and carcinomas in females. Previously reported carcinogenicity studies with vinylidene chloride in rats failed to demonstrate carcinogenicity in a variety of rat strains, including Wistar, Sprague Dawley, and CD rats. In those studies, no treatment-related tumors were reported following exposure to vinylidene chloride by inhalation^6,11,77,78,144,145^ or by oral administration.^11,51,144^ With the exception of two studies,^51,145^ rats in those studies were only exposed for 1 year, an exposure period that is too short to adequately determine carcinogenicity. In the studies conducted by Quast et al.,^145^ inhalation exposures up to 75 ppm vinylidene chloride were carried out for 18 months in Sprague Dawley rats followed by a 6-month recovery period. Ponomarkov and Tomatis^51^ exposed pregnant female BD IV rats to 150 mg/kg vinylidene chloride by gavage on gestation day 17 and exposed the offspring once weekly at 50 mg/kg for up to 120 weeks. No exposure-related tumors were observed in the studies conducted by Ponomarkov and Tomatis^51^ or Quast et al.^145^

In the current 2-year mouse study, decreases in body weight occurred in males at 12.5 and 25 ppm and females at 25 ppm. Decreased survival was observed at 25 ppm in males and in 6.25 and 25 ppm females. Increased survival was observed in 6.25 ppm males. Similar to the 3-month study, the kidney, liver, and nose were target organs. Following exposure to vinylidene chloride for 2 years, treatment-related neoplasms were observed in the kidney of males, in the liver of males and females, and in the lung and small intestine and systemically in females.

In all exposed groups of males, there were significant increases in the incidences of renal tubule hyperplasia, adenoma, and carcinoma. Additionally, bilateral and multiple adenomas and carcinomas were observed in some animals at 12.5 ppm. Grossly observed neoplastic lesions ranged from 1 mm pale cortical foci to large, occasionally bilateral masses that often replaced normal parenchyma. No renal tubule hyperplasia, adenomas, or carcinomas were observed in chamber control male mice or in 298 historical control mice from inhalation studies. In addition, one renal tubule adenoma occurred in a 25 ppm female mouse; this is an exceedingly rare neoplasm in female mice. Based on the marked treatment-related increase in the incidences of renal tubule adenoma and carcinoma and concurrent increases in the incidences of renal tubule hyperplasia, renal cell adenoma and carcinoma were considered to be related to vinylidene chloride exposure.

The mechanism by which vinylidene chloride induces adverse effects in the liver and kidney may be related to the deactivation in the liver and reactivation in the kidney. Vinylidene chloride is metabolized in the liver by CYP2E1 and undergoes subsequent conjugation by glutathione or cysteine and is then transported to the kidney for excretion. This metabolic pathway is similar to that of trichloroethylene, a structurally similar chemical that also yields glutathione- and cysteine-conjugated metabolites. For trichloroethylene, glutathione conjugation leads to the formation of S-(1,2-dichlorovinyl) glutathione (DCVG), which can be further metabolized to the cysteine conjugate, S-(1,2-dichlorovinyl)-L-cysteine (DCVC).^48,146^ Exposure to DCVC has been associated with nephrotoxicity and is believed to be associated with nephrocarcinogenicity.^48,147,148^ The mechanism for kidney effects has been associated with cysteine conjugate β-lyase activity in the kidney. β-lyase bioactivation of DCVC to S-(1,2-dichlorovinyl)thiol (DCVSH), a chemically unstable compound that undergoes rearrangement to reactive species that alkylate cellular nucleophiles, is considered to be the major metabolic pathway of DCVC.^47,48^ According to this proposed metabolic pathway, vinylidene chloride may undergo metabolism by hepatic cytochrome P450 and conjugation to deactivated products that are transported to the kidney. In the kidney, cysteine-conjugated products become ideal substrates for β-lyase bioactivation to reactive metabolites. Eyre et al.^149,150^ found that the activation of trichloroethylene by β-lyase was greater in mice than in rats, which is consistent with the more potent responses observed in the mice than the rats.

In the liver of female mice, there were positive trends in the incidences of hepatocellular adenoma, carcinoma, and adenoma or carcinoma (combined); the combined incidences were significantly increased at 12.5 and 25 ppm. The incidence of hepatocellular carcinoma was significantly increased in the 25 ppm females compared to chamber controls. The increased incidences of these neoplasms may have been related to exposure to vinylidene chloride; however, these neoplasms are common background neoplasms in B6C3F1 mice with a wide range in incidence. Furthermore, there is not a corresponding hepatocellular adenoma or carcinoma response in male mice. Hepatocholangiocarcinomas were observed in one 6.25 ppm, one 12.5 ppm, and one 25 ppm female, while none were observed in chamber controls or in any of the 948 historical controls by all route of exposure, which includes 300 from inhalation studies. Therefore, these neoplasms were considered to also be related to vinylidene chloride exposure.

In male mice, a single hepatocholangiocarcinoma was observed in chamber controls, two each in the 6.25 ppm and 12.5 ppm dose groups, and three in the 25 ppm group. These neoplasms are not as rare in males, with 10 observed in 949 historical controls by all routes of exposure, including 2 of 299 from inhalation studies. Additionally, the incidences did not exceed the historical controls for all routes of exposure. The hepatocholangiocarcinomas in males may have been related to vinylidene exposure. In males, there was an exposure concentration-dependent decreasing trend in the incidence of hepatocellular adenoma, and significant decreases in the incidences of adenoma at 25 ppm and carcinoma at 12.5 ppm. The incidence of basophilic focus was significantly increased in 25 ppm males. The biological significance of these lesions is unclear.

In 25 ppm female mice, there was an increase in the incidence of systemic hemangiosarcoma, predominantly driven by the statistically significant increase in the incidence of this neoplasm in the liver. Systemic hemangiomas were also observed in two females in each exposed group. None were observed in the control group, or in any of the 300 historical controls from inhalation studies. The incidences also exceeded the historical control range for all routes of exposure. Based on the increased incidence of hemangioma or hemangiosarcoma (combined) for all organs, which occurred with a positive trend among exposure groups and was significantly increased in the 25 ppm group, these neoplasms were considered related to vinylidene chloride exposure.

The incidence of alveolar/bronchiolar carcinoma in 12.5 ppm female mice was significantly increased compared to chamber controls, and the incidence in the 25 ppm females was at the upper end of the the historical control range for inhalation studies. Additionally, a positive trend in carcinoma incidence was observed. The time to first incidence for alveolar/ bronchiolar carcinoma was shorter in all exposed groups of females when compared to chamber controls. However, there was no supporting increase in the incidences of alveolar/bronchiolar adenoma, no neoplastic effect in males, and no accompanying increase in incidence or severity of hyperplastic lesions. Alveolar/ bronchiolar carcinomas are also fairly common background neoplasms. Given these data, and the fact that this was an inhalation route of exposure, it was considered that the incidence of alveolar/bronchiolar carcinoma in female mice may have been related to vinylidene chloride treatment. The induction of pulmonary adenomas by vinylidene chloride was previously reported in both male and female Swiss mice, with increased incidences in males at 10 ppm and both sexes at 25 ppm.^11,144^ Lee et al.^77^ also report increased incidences of alveolar/bronchiolar adenomas in male CD-1 mice. These increases were not statistically significant, however exposures in this study were only conducted for 1 year, not 2 years as in the current study.

A few uncommon carcinomas of the small intestine occurred in both male and female mice. The incidences in males fell within the historical control ranges, but the incidence in the 25 ppm group of females was outside the historical control ranges both for inhalation studies and all routes of exposure. Therefore, the incidence of small intestine neoplasms in female mice may have been related to vinylidene chloride exposure.

Similar to the effects observed in rats, nonneoplastic lesions were observed in the nose of male and female mice with generally increased incidence and severity with increasing exposure concentration. Signficantly increased incidences of atrophy of the turbinate, hyperstosis, and respiratory metaplasia in the olfactory epithelium were observed in all exposed groups. In females, the incidences of hyaline droplet accumulation in the olfactory epithelium and respiratory epithelium hyperplasia were increased at 25 ppm. In males, the incidences of hyaline droplet accumulation in the olfactory epithelium were increased at 12.5 and 25 ppm.

Treatment-related increases in other nonneoplastic lesions were observed in female mice. There were increased incidences of fat necrosis of the mesentery in exposed groups of female mice, similar to those observed in the companion rat study; however, because this lesion was only examined microscopically when a gross lesion in the mesentery was observed at necropsy, the true incidence of this lesion is uncertain. Localized fat necrosis may occur with inflammatory lesions in the liver or other closely associated abdominal organs; however, this needs to be further substantiated, and the true biologic significance of this lesion remains uncertain. Cystic endometrial hyperplasia of the uterus was significantly increased in incidence in exposed groups of female mice. However, the cause of this increase could not be determined based on histopathologic examination, and therefore the biologic relevance between this increased incidence and vinylidene chloride exposure remains unknown.

Results from a variety of published in vitro genetic toxicology studies with vinylidene chloride, including approaches such as bacterial mutagenicity assays, yeast test systems, and mammalian cell lines, demonstrate that under appropriate exposure conditions that control for the volatility of vinylidene chloride, the chemical has mutagenic, clastogenic, and aneugenic properties. In in vivo studies, the limited available genotoxicity test data are negative, with the exception of one study that detected low levels of DNA alkylation in liver and kidney, tissues associated with vinylidene chloride-induced tumorigenesis.^93^ Because alkylating agents in general possess mutagenic, clastogenic, and aneugenic properties, and many are known carcinogens, DNA alkylation may be one possible mode of action for vinylidene chloride associated tumorigenesis, consistent with the results obtained in well-conducted in vitro assays but not captured in the micronucleus studies that rely on exposure of proerythrocytes in the bone marrow.