# Results

## Rats

### Two-week Study

All male and nine of 10 female rats in the 200 and 400 ppm groups were found dead by day 2; one 400 ppm female was found dead on day 4 (Table 2). All other rats survived the entire study except one 25 ppm male removed from the study due to chylothorax (nonexposure-related condition). The mean body weight gain of 100 ppm females was significantly less than that of the chamber controls. Final mean body weights of male and female rats exposed to 100 ppm were 3% and 6% less, respectively, than those of the chamber control groups. All females and nine of 10 males exposed to 200 or 400 ppm became lethargic, while all females and four of five males exposed to 400 ppm developed ataxia.

Table 2 Survival and Body Weights of Rats in the Two-week Inhalation Study of Vinylidene Chloride^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 93 ± 2 | 158 ± 2 | 66 ± 3
25 | 4/5^c^ | 91 ± 1 | 150 ± 3 | 60 ± 4 | 95
50 | 5/5 | 92 ± 3 | 159 ± 5 | 67 ± 3 | 100
100 | 5/5 | 93 ± 1 | 154 ± 2 | 62 ± 2 | 97
200 | 0/5^d^ | 92 ± 2 | – | – | –
400 | 0/5^e^ | 91 ± 2 | – | – | –
Female
0 | 5/5 | 84 ± 1 | 124 ± 2 | 40 ± 1
25 | 5/5 | 84 ± 1 | 125 ± 3 | 40 ± 3 | 101
50 | 5/5 | 84 ± 2 | 122 ± 1 | 38 ± 2 | 98
100 | 5/5 | 83 ± 2 | 117 ± 3 | 34 ± 1* | 94
200 | 0/5^d^ | 83 ± 1 | – | – | –
400 | 0/5^f^ | 84 ± 1 | – | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 16 days/number initially in group.

^c^ Day of death: 10.

^d^ Day of deaths: 2.

^e^ Days of deaths: 1, 2, 2, 2, 2.

^f^ Days of deaths: 2, 2, 2, 2, 4.

Absolute and relative kidney weights of all surviving groups of exposed males and females were significantly greater than those of the chamber controls (Table G-1). In males, relative lung weights were increased at 100 ppm compared to controls, and an increasing trend was observed in absolute and relative lung weights.

In the liver, centrilobular necrosis was associated with early deaths in male and female rats exposed to 200 or 400 ppm vinylidene chloride and was characterized as partial or complete disintegration of hepatocytes within the central areas of hepatic lobules, sparing only the periportal areas (Table 3). Necrotic hepatocytes were replaced with hemorrhage and necrotic debris, and the remaining viable hepatocytes had pale or vacuolated cytoplasm and margination of nuclear chromatin. Mild centrilobular necrosis was also observed in one 25 ppm male rat, and it was characterized by shrunken, eosinophilic hepatocytes with complete or partial loss of nuclear and cell membranes and karyorrhexis. Centrilobular cytoplasmic alteration of hepatocytes occurred in all exposed male and female rats that survived to terminal kill. Hepatocytic centrilobular cytoplasmic alteration was characterized by decreased cytoplasmic staining, perinuclear halos, and flocculent cytoplasm. Mean severity of this alteration was slightly higher in males. Centrilobular cytoplasmic alteration likely represents a form of hepatocellular degeneration, because rats exposed to 200 and 400 ppm did not have cytoplasmic alteration, but rather centrilobular necrosis, consistent with a more severe stage of hepatocellular damage.

Table 3 Incidences of Selected Nonneoplastic Lesions in Rats in the Two-week Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Male
Liver^a^ | 5 | 5 | 5 | 5 | 5 | 5
Centrilobular, Necrosis^b^ | 0 | 1 (2.0)^c^ | 0 | 0 | 5** (4.0) | 5** (4.0)
Hepatocyte, Centrilobular, Cytoplasmic Alteration | 0 | 4* (2.8) | 5** (3.0) | 5** (3.0) | 0 | 0
Kidney | 5 | 0 | 0 | 5 | 5 | 5
Papilla, Renal Tubule, Casts | 0 | – | – | 0 | 5** (3.2) | 4* (2.5)
Female
Liver | 5 | 5 | 5 | 5 | 5 | 5
Centrilobular, Necrosis | 0 | 0 | 0 | 0 | 5** (4.0) | 5** (4.0)
Hepatocyte, Centrilobular, Cytoplasmic Alteration | 0 | 5** (2.4) | 5** (3.0) | 5** (2.6) | 0 | 0
Kidney | 5 | 0 | 0 | 5 | 5 | 5
Papilla, Renal Tubule, Casts | 0 | – | – | 0 | 5** (3.0) | 5** (3.2)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Renal tubule casts occurred in the renal papillae of 200 and 400 ppm rats, characterized by the presence of variable amounts of finely granular, brightly eosinophilic material in dilated tubule lumens of the renal papillae (Table 3).

Exposure Concentration Selection Rationale: Based on decreased survival of males and females exposed to 200 or 400 ppm in the 2-week study, vinylidene chloride exposure concentrations selected for the 3-month inhalation study in rats were 6.25, 12.5, 25, 50, and 100 ppm. Doses were also partially based on the lack of hepatocellular necrosis in the 25, 50, and 100 ppm groups. Cytoplasmic alteration was not considered to be dose limiting.

### Three-month Study

All rats survived until the end of the study (Table 4). Final mean body weights and body weight gains of exposed groups were similar to those of the chamber control groups (Table 4 and Figure 3). No exposure-related clinical findings or gross lesions were observed.

Table 4 Survival and Body Weights of Rats in the Three-month Inhalation Study of Vinylidene Chloride^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 111 ± 2 | 326 ± 7 | 216 ± 6
6.25 | 10/10 | 110 ± 2 | 332 ± 6 | 222 ± 6 | 102
12.5 | 10/10 | 111 ± 2 | 337 ± 5 | 226 ± 5 | 103
25 | 10/10 | 110 ± 2 | 319 ± 6 | 209 ± 6 | 98
50 | 10/10 | 111 ± 1 | 340 ± 6 | 230 ± 6 | 104
100 | 10/10 | 111 ± 2 | 322 ± 5 | 212 ± 6 | 99
Female
0 | 10/10 | 96 ± 2 | 203 ± 3 | 108 ± 2
6.25 | 10/10 | 96 ± 2 | 205 ± 6 | 109 ± 5 | 101
12.5 | 10/10 | 95 ± 2 | 206 ± 4 | 111 ± 3 | 101
25 | 10/10 | 95 ± 2 | 201 ± 4 | 106 ± 3 | 99
50 | 10/10 | 95 ± 2 | 205 ± 4 | 110 ± 3 | 101
100 | 10/10 | 96 ± 1 | 195 ± 2 | 100 ± 2 | 96

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 3

Growth Curves for Rats Exposed to Vinylidene Chloride by Inhalation for Three Months

The hematology and clinical chemistry data for rats are presented in Table F-1. Slight increases (≤6%) in hemoglobin concentrations and red blood cell (erythrocyte) counts were observed in 100 ppm male and female rats on day 3. In addition, on day 3 the hematocrit was also slightly increased in 100 ppm males. These changes ameliorated by day 23 and were consistent with a transient hemoconcentration associated with mild dehydration as the rats acclimated to exposure. No other hematological changes were considered toxicologically or biologically relevant.

Exposure concentration-related minimal to mild (≤10%) increases were observed in total protein and globulin concentrations on days 3 and 23 in both male and female rats in various exposed groups, but most consistently at 100 ppm. In addition, albumin was minimally increased (≤5%) in 100 ppm males and 25 ppm or greater female rats on day 23. Urea nitrogen concentrations were minimally increased in 50 and 100 ppm male and female rats on day 3, and 50 and 100 ppm males and 6.25 ppm or greater females on day 23. Similar to the observed changes in the erythron, the total protein, albumin, globulin, and urea nitrogen concentrations returned to chamber control levels by week 14 and were consistent with mild dehydration.

Increased alkaline phosphatase activities were observed in the 50 and 100 ppm groups on days 3 and 23 in male rats and on day 23 in female rats.While increased alkaline phosphatase activity is considered an indicator of cholestasis, the increases were of minimal severity and transient, and bile acid concentrations, another marker for cholestasis, were unchanged or decreased, suggesting that these changes represent a transient alteration in hepatic metabolism rather than cholestasis.

Sorbitol dehydrogenase (SDH) activities were increased in 100 ppm females on day 3 and in 100 ppm males and 50 and 100 ppm females on day 23. In addition, alanine aminotransferase (ALT) activities were increased on day 3 in 50 and 100 ppm male rats and day 23 in 100 ppm male rats. Both SDH and ALT are considered markers of hepatocellular injury. These increases were transient, not being observed at week 14, and minimal histopathologic changes were observed in the liver at study termination; therefore, these changes are consistent with mild transient hepatocellular injury.

Relative kidney weights of 6.25, 12.5, and 100 ppm males and absolute and relative kidney weights of 12.5 ppm or greater females were significantly greater than those of the chamber controls (Table G-2).

Male rats exposed to 100 ppm exhibited significantly lower sperm motility (approximately 5% less than chamber controls) (Table H-1). Rats in this exposed group also exhibited lower spermatid/g testis and total spermatid/testis values (15% and 16%, respectively, compared to chamber controls). At necropsy, rats did not display any histopathologic change in the contralateral organ; however, fixation quality of the rat testes was poor. There were no vinylidene chloride-related changes in estrous cyclicity in female rats (Table H-2). Therefore, vinylidene chloride exhibits the potential to be a reproductive toxicant in male rats but not in female rats.

Microscopic lesions of the nose were noted in both sexes of rats (Table 5). A combination of lesions in the nasal epithelium composed of olfactory epithelium atrophy, mineralization, and necrosis and turbinate atrophy was observed with generally increasing severity with increasing exposure to vinylidene chloride. A no-effect level was not observed, although turbinate atrophy was not seen in rats exposed to 6.25 ppm, and most of the lesions were minimal in rats exposed to 12.5 ppm or less. Atrophy of the olfactory epithelium was characterized by a decrease in the number of olfactory epithelial cells lining the turbinates, usually in the dorsal meatus of Level III, and by replacement with a single layer of respiratory-type epithelium (metaplasia). This lesion was often associated with a corresponding decrease in nerve fibers and glands in the underlying lamina propria. Mineralization of the olfactory epithelium was characterized by linear to irregular, oval to elongate laminated deposits of greyish-blue material in the basement membrane, often underlying an atrophic epithelium or disrupting the epithelium, and most often affecting the lateral walls and turbinates. Olfactory epithelial necrosis occurred at the dorsal meatus, dorsal septum, and all regions of ethmoturbinates in Level III of the nose. Necrosis of the olfactory epithelium was characterized by areas of nuclear pyknosis of the epithelium, fragmentation, and hypereosinophilia, and in some areas, full-thickness sloughing of the epithelium and cell debris into the nasal passages at Level III. Necrosis was not associated with inflammation. Turbinate atrophy was characterized by thinning and blunting of primarily the ethmoid turbinates of Level III, often with bony remodeling.

Table 5 Incidences of Selected Nonneoplastic Lesions in Rats in the Three-month Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
Nose^a^ | 10 | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Atrophy^b^ | 0 | 4* (1.0)^c^ | 10** (1.0) | 10** (1.7) | 10** (2.2) | 10** (2.7)
Olfactory Epithelium, Mineralization | 0 | 10** (1.3) | 10** (2.0) | 10** (2.9) | 10** (3.0) | 10** (2.6)
Olfactory Epithelium, Necrosis | 0 | 2 (1.0) | 6** (1.0) | 9** (1.0) | 7** (1.7) | 10** (1.6)
Turbinate, Atrophy | 0 | 0 | 10** (1.0) | 10** (2.0) | 10** (2.2) | 10** (3.0)
Liver | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Cytoplasmic Alteration | 1 (1.0) | 1 (1.0) | 6* (1.7) | 10** (1.8) | 10** (2.0) | 10** (1.9)
Female
Nose | 10 | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Atrophy | 0 | 2 (1.0) | 10** (1.0) | 10** (1.3) | 10** (1.7) | 10** (2.4)
Olfactory Epithelium, Mineralization | 0 | 5* (1.0) | 9** (1.3) | 10** (1.9) | 10** (2.1) | 10** (2.3)
Olfactory Epithelium, Necrosis | 0 | 1 (1.0) | 3 (1.3) | 6** (1.5) | 10** (2.2) | 10** (1.6)
Turbinate, Atrophy | 0 | 0 | 10** (1.0) | 10** (2.0) | 10** (2.2) | 10** (3.0)
Liver | 10 | 10 | 10 | 10 | 10 | 10
Vacuolization, Cytoplasmic | 0 | 0 | 0 | 0 | 10** (1.1) | 10** (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the liver of male rats, centrilobular cytoplasmic alteration was significantly increased at 12.5 ppm or greater. In females, cytoplasmic vacuolization was observed at 50 and 100 ppm (Table 5). Centrilobular cytoplasmic alteration was characterized by a decrease in cytoplasmic eosinophilia of hepatocytes located in centrilobular areas; this lesion was not observed in female rats. Cytoplasmic vacuolization was characterized by single to multiple clear, well-circumscribed, round, 1 to 15 μm diameter vacuoles in the cytoplasm of hepatocytes.

Decreased incidences of nephropathy were observed in male rats exposed to vinylidene chloride (6/10, 3/10, 4/10, 4/10, 3/10, 1/10). All incidences of nephropathy in the chamber controls were graded as minimal, and the lesion was characterized by single to few clusters of regenerative tubules with minimal thickening of the basement membrane. The higher exposure concentration groups had histologically normal kidneys. This lesion is a common background finding in the F344/N rat and was unrelated to vinylidene chloride exposure. The decreasing incidence of nephropathy in exposed animals is of uncertain biologic significance.

Exposure Concentration Selection Rationale: In the 3-month studies, minimal changes in clinical chemistry parameters were considered reflective of possible mild dehydration. While increased kidney weights were observed in males and females, there were no corresponding histopathologic changes in the kidney. The nose and the liver were target organs in both sexes. However, the observed lesions were not considered preclusive for chronic administration at these exposures. Exposure concentrations greater than 100 ppm were not considered due to increased mortality observed at greater than 100 ppm in the 2-week study. Based on the overall minimal chemical-related toxicity in the 3-month study, vinylidene chloride exposure concentrations selected for the 2-year inhalation study in rats were 25, 50, and 100 ppm.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 6 and in the Kaplan-Meier survival curves (Figure 4). Survival of exposed groups of males was similar to that of the chamber control group. Survival of 100 ppm females was significantly less than that of the chamber controls.

Table 6 Survival of Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 21 | 15 | 23 | 27
Natural deaths | 4 | 8 | 5 | 4
Animals surviving to study termination | 25 | 27 | 22 | 19
Percent probability of survival at end of study^a^ | 50 | 54 | 44 | 38
Mean survival (days)^b^ | 680 | 662 | 650 | 646
Survival analysis^c^ | P = 0.121 | P = 1.000 | P = 0.372 | P = 0.207
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 19 | 22 | 18 | 28
Natural deaths | 1 | 2 | 2 | 3
Animals surviving to study termination | 30 | 26 | 30^d^ | 19
Percent probability of survival at end of study | 60 | 52 | 58 | 38
Mean survival (days) | 705 | 681 | 678 | 675
Survival analysis | P = 0.046 | P = 0.337 | P = 0.709 | P = 0.029

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^100^ is in the chamber control column, and the results of the life table pairwise comparisons^99^ with the chamber controls are in the exposed group columns.

^d^ Includes one animal that died during the last week of the study.

Figure 4

Kaplan-Meier Survival Curves for Rats Exposed to Vinylidene Chloride by Inhalation for Two Years

#### Body Weights and Clinical Findings

Mean body weights of exposed groups of male and female rats were similar to those of the chamber control groups throughout the study (Figure 5, Table 7, and Table 8). No clinical findings related to vinylidene chloride exposure were observed in male rats; thinness was observed in approximately half of the 100 ppm females.

Figure 5

Growth Curves for Rats Exposed to Vinylidene Chloride by Inhalation for Two Years

Table 7 Mean Body Weights and Survival of Male Rats in the Two-year Inhalation Study of Vinylidene Chloride

Day | Chamber Control | | 25 ppm | | | 50 ppm | | | 100 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 100 | 50 | 100 | 101 | 50 | 100 | 100 | 50 | 99 | 99 | 50
10 | 136 | 50 | 137 | 101 | 50 | 136 | 100 | 50 | 131 | 96 | 49
17 | 162 | 50 | 167 | 103 | 50 | 164 | 101 | 50 | 159 | 98 | 49
24 | 186 | 50 | 192 | 103 | 50 | 190 | 102 | 50 | 186 | 100 | 49
31 | 208 | 50 | 214 | 103 | 50 | 213 | 103 | 50 | 210 | 101 | 49
38 | 226 | 50 | 230 | 102 | 50 | 228 | 101 | 50 | 227 | 101 | 49
45 | 242 | 50 | 246 | 102 | 50 | 245 | 101 | 50 | 244 | 101 | 49
52 | 258 | 50 | 259 | 100 | 50 | 258 | 100 | 50 | 254 | 99 | 49
59 | 272 | 50 | 273 | 100 | 50 | 272 | 100 | 50 | 272 | 100 | 49
66 | 286 | 50 | 286 | 100 | 50 | 285 | 100 | 50 | 285 | 100 | 49
73 | 298 | 50 | 298 | 100 | 50 | 296 | 100 | 50 | 297 | 100 | 49
80 | 308 | 50 | 309 | 100 | 50 | 306 | 99 | 50 | 305 | 99 | 49
87 | 318 | 50 | 319 | 100 | 50 | 315 | 99 | 50 | 318 | 100 | 49
115 | 354 | 50 | 357 | 101 | 50 | 351 | 99 | 50 | 350 | 99 | 49
143 | 380 | 50 | 383 | 101 | 50 | 376 | 99 | 50 | 377 | 99 | 49
171 | 402 | 50 | 405 | 101 | 50 | 399 | 99 | 50 | 400 | 100 | 49
199 | 421 | 50 | 426 | 101 | 50 | 419 | 99 | 50 | 420 | 100 | 49
227 | 436 | 50 | 441 | 101 | 50 | 432 | 99 | 50 | 435 | 100 | 49
255 | 448 | 50 | 453 | 101 | 50 | 443 | 99 | 50 | 446 | 100 | 49
283 | 461 | 50 | 465 | 101 | 50 | 453 | 98 | 50 | 457 | 99 | 49
311 | 472 | 50 | 476 | 101 | 49 | 463 | 98 | 49 | 467 | 99 | 49
339 | 482 | 50 | 484 | 101 | 49 | 472 | 98 | 49 | 475 | 99 | 49
367 | 488 | 49 | 491 | 101 | 48 | 476 | 98 | 49 | 481 | 99 | 49
395 | 497 | 49 | 504 | 101 | 48 | 488 | 98 | 49 | 496 | 100 | 49
423 | 503 | 49 | 505 | 100 | 48 | 489 | 97 | 47 | 498 | 99 | 49
451 | 507 | 49 | 510 | 101 | 48 | 490 | 97 | 47 | 502 | 99 | 47
479 | 512 | 49 | 516 | 101 | 47 | 493 | 96 | 47 | 501 | 98 | 47
507 | 515 | 48 | 515 | 100 | 46 | 498 | 97 | 45 | 503 | 98 | 46
535 | 522 | 47 | 517 | 99 | 45 | 498 | 95 | 44 | 509 | 98 | 43
563 | 525 | 45 | 521 | 99 | 41 | 502 | 96 | 41 | 513 | 98 | 41
591 | 529 | 43 | 525 | 99 | 41 | 507 | 96 | 37 | 516 | 97 | 39
619 | 528 | 42 | 531 | 101 | 36 | 514 | 97 | 33 | 517 | 98 | 33
647 | 532 | 39 | 532 | 100 | 34 | 513 | 96 | 30 | 520 | 98 | 31
661 | 529 | 37 | 536 | 101 | 31 | 513 | 97 | 28 | 518 | 98 | 29
675 | 519 | 34 | 532 | 103 | 30 | 506 | 98 | 26 | 506 | 98 | 28
689 | 516 | 30 | 532 | 103 | 30 | 509 | 99 | 24 | 497 | 96 | 27
703 | 512 | 29 | 531 | 104 | 29 | 509 | 99 | 23 | 506 | 99 | 21
717 | 515 | 26 | 525 | 102 | 28 | 500 | 97 | 22 | 497 | 97 | 21
Mean for Weeks
1–13 | 231 | – | 233 | 101 | – | 231 | 100 | – | 230 | 100 | –
14–52 | 428 | – | 432 | 101 | – | 423 | 99 | – | 425 | 99 | –
53–103 | 516 | – | 520 | 101 | – | 500 | 97 | – | 505 | 98 | –

Table 8 Mean Body Weights and Survival of Female Rats in the Two-year Inhalation Study of Vinylidene Chloride

Day | Chamber Control | | 25 ppm | | | 50 ppm | | | 100 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 88 | 50 | 87 | 99 | 50 | 87 | 99 | 50 | 87 | 99 | 50
10 | 111 | 50 | 108 | 98 | 50 | 107 | 97 | 50 | 104 | 94 | 50
17 | 125 | 50 | 123 | 99 | 50 | 122 | 98 | 50 | 119 | 95 | 50
24 | 139 | 50 | 137 | 99 | 50 | 135 | 98 | 50 | 132 | 95 | 50
31 | 150 | 50 | 150 | 100. | 50 | 150 | 100 | 50 | 146 | 97 | 50
38 | 158 | 50 | 159 | 101 | 50 | 157 | 99 | 50 | 154 | 97 | 50
45 | 167 | 50 | 167 | 100 | 50 | 165 | 99 | 50 | 162 | 97 | 50
52 | 173 | 50 | 173 | 100 | 50 | 170 | 98 | 50 | 168 | 97 | 50
59 | 178 | 50 | 178 | 100 | 50 | 175 | 98 | 50 | 173 | 97 | 50
66 | 183 | 50 | 181 | 99 | 50 | 180 | 99 | 50 | 177 | 97 | 50
73 | 188 | 50 | 186 | 99 | 50 | 185 | 99 | 50 | 182 | 97 | 50
80 | 191 | 50 | 192 | 101 | 50 | 191 | 100 | 50 | 187 | 98 | 50
87 | 196 | 50 | 197 | 100. | 50 | 194 | 99 | 50 | 191 | 98 | 50
115 | 211 | 50 | 213 | 101 | 50 | 210 | 99 | 50 | 207 | 98 | 50
143 | 222 | 50 | 225 | 101 | 50 | 221 | 99 | 50 | 218 | 98 | 49
171 | 235 | 50 | 237 | 101 | 50 | 234 | 100 | 50 | 232 | 99 | 49
199 | 245 | 50 | 249 | 102 | 50 | 245 | 100 | 50 | 243 | 99 | 49
227 | 254 | 50 | 258 | 102 | 50 | 254 | 100 | 50 | 252 | 99 | 49
255 | 264 | 50 | 267 | 101 | 50 | 264 | 100 | 50 | 260 | 99 | 49
283 | 273 | 50 | 276 | 101 | 50 | 272 | 100 | 50 | 268 | 98 | 49
311 | 284 | 50 | 286 | 101 | 50 | 283 | 100 | 50 | 279 | 98 | 49
339 | 298 | 50 | 301 | 101 | 50 | 297 | 100 | 50 | 292 | 98 | 49
367 | 308 | 50 | 312 | 101 | 50 | 307 | 100 | 50 | 300 | 98 | 49
395 | 321 | 50 | 328 | 102 | 50 | 325 | 101 | 50 | 318 | 99 | 48
423 | 330 | 50 | 337 | 102 | 50 | 331 | 100 | 48 | 323 | 98 | 48
451 | 338 | 50 | 344 | 102 | 49 | 335 | 99 | 48 | 331 | 98 | 48
479 | 343 | 50 | 352 | 103 | 48 | 342 | 100 | 48 | 333 | 97 | 48
507 | 350 | 50 | 357 | 102 | 48 | 346 | 99 | 48 | 339 | 97 | 48
535 | 352 | 50 | 359 | 102 | 47 | 350 | 99 | 45 | 343 | 98 | 48
563 | 358 | 48 | 365 | 102 | 45 | 355 | 99 | 43 | 346 | 97 | 48
591 | 362 | 47 | 371 | 102 | 44 | 360 | 99 | 41 | 354 | 98 | 45
619 | 370 | 46 | 374 | 101 | 41 | 367 | 99 | 39 | 357 | 97 | 44
647 | 376 | 45 | 379 | 101 | 37 | 367 | 98 | 37 | 357 | 95 | 40
661 | 375 | 43 | 382 | 102 | 34 | 370 | 99 | 36 | 362 | 97 | 35
675 | 374 | 41 | 379 | 102 | 33 | 380 | 102 | 33 | 364 | 97 | 33
689 | 372 | 39 | 376 | 101 | 32 | 380 | 102 | 33 | 358 | 96 | 30
703 | 372 | 34 | 378 | 102 | 30 | 379 | 102 | 32 | 356 | 96 | 25
717 | 370 | 34 | 389 | 105 | 27 | 382 | 103 | 31 | 366 | 99 | 21
Mean for Weeks
1–13 | 157 | – | 157 | 100 | – | 155 | 99 | – | 152 | 97 | –
14–52 | 254 | – | 257 | 101 | – | 253 | 100 | – | 250 | 98 | –
53–103 | 354 | – | 361 | 102 | – | 355 | 100 | – | 344 | 97 | –

#### Gross Findings

Fluid in the abdomen and multiple nodules on the peritoneum, particularly on the testicular tunics and epididymides, were grossly observed. These findings were associated with exposure to vinylidene chloride and resulted from the occurrence of mesothelioma.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of malignant mesothelioma and mononuclear cell leukemia, and neoplasms and/or nonneoplastic lesions of the thyroid gland, kidney, urinary bladder, nose, lung, liver, ovary, clitoral gland, and mesentery. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

Malignant Mesothelioma: The incidences of malignant mesothelioma occurred with a positive trend and were significantly increased in all exposed groups of males (Table 9, Table A-1, and Table A-2). The peritoneal mesothelium covering the testis and epididymis was most often affected, similar to spontaneous mesothelioma. One male exposed to 25 ppm also had mesotheliomas on the pleura and pericardium in addition to the testicular and epididymal sites. Malignant mesothelioma occurred in one 25 ppm female (pleura, pericardium) and one exposed to 50 ppm (peritoneum); these incidences were greater than those in the chamber control group, and no malignant mesotheliomas have occurred in 700 females in the historical control database (Table 9 and Table B-1). Malignant mesothelioma was characterized by sessile to arboriform and papillary proliferations of large, plump mesothelial cells with large nuclei, prominent nucleoli, and scant to moderate cytoplasm, supported by a fibrovascular stroma (Figure 9). In males, these neoplasms originated in the epididymis and testes, and disseminated throughout the peritoneum to multiple organs including the intestines, mesentery, pancreas, prostate gland, spleen, and liver.

Table 9 Incidences of Malignant Mesothelioma in Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Male
All Organs: Malignant Mesothelioma^a^
Overall rate^b^ | 1/50 (2%) | 12/50 (24%) | 28/50 (56%) | 23/50 (46%)
Adjusted rate^c^ | 2.4% | 27.9% | 63.4% | 52.7%
Terminal rate^d^ | 0/25 (0%) | 5/27 (19%) | 10/22 (46%) | 7/19 (37%)
First incidence (days) | 562 | 535 | 500 | 449
Poly-3 test^e^ | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Female
All Organs: Malignant Mesothelioma^f^
Overall rate | 0/50 (0%) | 1/50 (2%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 0.0% | 2.4% | 2.4% | 0.0%
Terminal rate | 0/30 (0%) | 1/26 (4%) | 0/29 (0%) | 0/19 (0%)
First incidence (days) | –^g^ | 731 (T) | 634 | –
Poly-3 test | –^h^ | – | – | –

T = terminal kill.

^a^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 1/200 (0.5% ± 1.0%), range 0%–2%; all routes: 26/699 (3.7% ± 3.1%), range 0%–8%.

^b^ Number of animals with malignant mesothelioma per number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^f^ Historical incidence for inhalation studies 0/200; all routes: 0/700.

^g^ Not applicable; no neoplasms in animal group.

^h^ Value of statistic not computed because all exposure groups have fewer than two neoplasms.

Global gene expression profiling of mesotheliomas arising in male F344/N rats exposed to vinylidene chloride, spontaneous mesotheliomas in F344/N rats, and cultured rat mesothelial cells (Fred-PE cells) showed that mesotheliomas from vinylidene chloride-exposed animals and control animals could be differentiated based on their genomic profiles, despite indistinguishable morphology (Appendix L). Moreover, while spontaneous mesotheliomas and mesotheliomas from vinylidene chloride-exposed animals harbored many similarities in pathway and gene dysregulation, including those associated with oncogenesis, growth factor pathways, embryonic development, matrix remodeling, and mesothelial markers, mesotheliomas from vinylidene chloride-exposed animals were distinguished from spontaneous mesotheliomas based on overrepresentation of genes associated with a proinflammatory response and immune dysregulation, including alterations in pathways associated with proinflammatory cytokines and chemokines, Jak/Stat mediators, complement factors, pattern recognition receptors and damage-associated molecular pattern molecules, interferon pathway mediators, activated macrophage products, cell surface receptors, and a variety of inflammatory mediators.

Thyroid Gland (C-Cell): The incidence of C-cell adenoma was significantly increased in 100 ppm females, exceeded the historical control range for inhalation studies, and was at the upper end of the historical control range for all routes of administration (Table 10, Table B-1, Table B-2, and Table B-3). Incidences of carcinoma were increased in all exposed groups of females, and the incidence in the 25 ppm group was significantly greater than that in the chamber controls The incidences of carcinoma in all exposed groups of females exceeded the historical control range for inhalation studies, and the incidence in the 25 ppm group exceeded the historical control range for all routes of administration. The incidences of adenoma or carcinoma (combined) were significantly increased in 25 and 100 ppm females.

Table 10 Incidences of Neoplasms of the Thyroid Gland (C-Cell) in Female Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Adenoma^a^
Overall rate^b^ | 3/50 (6%) | 4/50 (8%) | 6/48 (13%) | 11/50 (22%)
Adjusted rate^c^ | 6.6% | 9.5% | 14.6% | 26.2%
Terminal rate^d^ | 3/30 (10%) | 2/26 (8%) | 4/28 (14%) | 6/19 (32%)
First incidence (days) | 731 (T) | 625 | 579 | 669
Poly-3 test^e^ | P = 0.004 | P = 0.461 | P = 0.195 | P = 0.012
Carcinoma^f^
Overall rate | 0/50 (0%) | 6/50 (12%) | 2/48 (4%) | 2/50 (4%)
Adjusted rate | 0.0% | 14.4% | 4.9% | 4.8%
Terminal rate | 0/30 (0%) | 6/26 (23%) | 1/28 (4%) | 1/19 (5%)
First incidence (days) | –^g^ | 731 (T) | 670 | 670
Poly-3 test | P = 0.474 | P = 0.011 | P = 0.213 | P = 0.218
Adenoma or Carcinoma^h^
Overall rate | 3/50 (6%) | 10/50 (20%) | 8/48 (17%) | 13/50 (26%)
Adjusted rate | 6.6% | 23.7% | 19.3% | 30.8%
Terminal rate | 3/30 (10%) | 8/26 (31%) | 5/28 (18%) | 7/19 (37%)
First incidence (days) | 731 (T) | 625 | 579 | 669
Poly-3 test | P = 0.006 | P = 0.023 | P = 0.071 | P = 0.003

T = terminal kill.

^a^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 13/200 (6.5% ± 1.0%), range 6%–8%; all routes: 81/690 (11.7% ± 5.5%), range 6%–22%.

^b^ Number of animals with neoplasm per number of animals with thyroid gland examined microscopically.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^f^ Historical incidence for inhalation studies: 1/200 (0.5% ± 1.0%), range 0%-2%; all routes: 6/690 (0.9% ± 2.0%), range 0%-7%.

^g^ Not applicable; no neoplasms in animal group.

^h^ Historical incidence for inhalation studies: 14/200 (7.0% ± 1.2%), range 6%-8%; all routes: 87/690 (12.7% ± 5.8%), range 6%-22%.

Thyroid gland C-cell adenomas were characterized by a discrete, small, well-demarcated focal proliferation of well-differentiated C-cells that comprised greater than the diameter of five contiguous follicles and caused variable compression of the adjacent thyroid gland parenchyma (Figure 10). Carcinomas were more infiltrative, less well-differentiated, and typically showed evidence of cellular atypia and mitotic activity (Figure 11).

Mononuclear Cell Leukemia: The incidence of mononuclear cell leukemia was significantly increased in 100 ppm females and exceeded the historical control ranges for inhalation studies and all routes of administration (Table 11, Table B-1, Table B-2, and Table B-4).

Table 11 Incidences of Mononuclear Cell Leukemia in Female Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
All Organs: Mononuclear Cell Leukemia^a^
Overall rate^b^ | 10/50 (20%) | 11/50 (22%) | 13/50 (26%) | 25/50 (50%)
Adjusted rate^c^ | 21.4% | 24.6% | 28.3% | 54.6%
Terminal rate^d^ | 3/30 (10%) | 4/26 (15%) | 3/29 (10%) | 8/19 (42%)
First incidence (days) | 631 | 451 | 421 | 395
Poly-3 test^e^ | P < 0.001 | P = 0.457 | P = 0.300 | P < 0.001

^a^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 58/200 (29.0% ± 6.2%), range 20%–34%; all routes: 165/700 (23.6% ± 8.2%), range 10%–36%.

^b^ Number of animals with mononuclear cell leukemia per number necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

Kidney: In the standard evaluation of the kidney, two 25 ppm males, one 50 ppm male, and one 100 ppm male had renal tubule carcinomas (Table 12 and Table A-1). Carcinomas were characterized by large, infiltrative proliferations of lobules and tubules of poorly differentiated renal tubule epithelial cells (Figure 12). Although not statistically significant, the incidence in the 25 ppm group exceeded the historical control ranges for inhalation studies and all routes of administration (Table 12 and Table A-4). There was a single incidence of renal tubule adenoma in 50 ppm females; no renal tubule adenomas have occurred in 692 females in the historical control database (Table 12 and Table B-1). Renal tubule adenoma was composed of a small, expansile proliferation of fairly well-differentiated renal tubule epithelial cells causing compression of adjacent renal parenchyma (Figure 13).

Table 12 Incidences of Neoplasms and Nonneoplastic Lesions of the Kidney in Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Male
Single Sections (Standard Evaluation)
Number Examined Microscopically | 50 | 50 | 49 | 50
Renal Tubule, Hyperplasia^a^ | 0 | 1 (2.0)^b^ | 1 (1.0) | 1 (4.0)
Transitional Epithelium, Hyperplasia | 0 | 0 | 1 (3.0) | 2 (1.5)
Renal Tubule, Carcinoma^c^ | 0 | 2 | 1 | 1
Step Sections (Extended Evaluation)
Number Examined Microscopically | 50 | 50 | 49 | 50
Renal Tubule Hyperplasia | 3 (1.0) | 5 (1.2) | 5 (2.2) | 7 (2.0)
Renal Tubule Adenoma | 3 | 3 | 5 | 1
Single and Step Sections (Combined)
Number Examined Microscopically | 50 | 50 | 49 | 50
Renal Tubule Hyperplasia | 3 | 5 | 6 | 8
Renal Tubule Adenoma | 3 | 3 | 5 | 1
Renal Tubule Carcinoma | 0 | 2 | 1 | 1
Renal Tubule Adenoma or Carcinoma
Overall rate^d^ | 3/50 (6%) | 4/50 (8%) | 6/49 (12%) | 2/50 (4%)
Adjusted rate^e^ | 7.2% | 9.8% | 15.7% | 5.3%
Terminal rate^f^ | 3/25 (12%) | 1/27 (4%) | 4/22 (18%) | 1/19 (5%)
First incidence (days) | 729 (T) | 631 | 502 | 718
Poly-3 test^g^ | P = 0.485N | P = 0.484 | P = 0.194 | P = 0.546N
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Renal Tubule, Hyperplasia | 1 (2.0) | 2 (2.5) | 0 | 2 (3.0)
Renal Tubule, Adenoma^h^ | 0 | 0 | 1 | 0

T = terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 0/200; all routes: 1/697 (0.1% ± 0.5%), range 0%–2%.

^d^ Number of animals with neoplasm per number of animals with kidney examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Historical incidence for inhalation studies: 0/199; all routes: 0/692.

Single incidences of renal tubule hyperplasia occurred in each exposed group of males, and slight increases in the incidences of this lesion occurred in 25 and 100 ppm females (Table 12, Table A-5, and Table B-6). This lesion did not occur in the concurrent chamber control males and was increased in severity in 100 ppm males. Renal tubule hyperplasia was characterized by few multifocal foci of enlarged tubule epithelial cells piling and filling the tubule lumen, often expanding to involve multiple tubule profiles (Figure 14). Hyperplasia of the transitional epithelium of the kidney occurred in one 50 ppm and two 100 ppm males and was characterized by similar crowding and piling of well-differentiated transitional epithelial cells.

Since there was evidence of a treatment-related effect in male rats, kidney step sections were performed to evaluate for additional proliferative lesions. The findings of the kidney step section evaluation in male rats (Table 12) indicated increased incidences of renal tubule hyperplasia in all exposed groups. Several newly diagnosed incidences of renal tubule adenoma were observed as a result of kidney step section review in male rats, although there was not a significant difference between exposed animals and chamber controls. No additional carcinomas were observed as the result of step section review. The final combined incidences of renal tubule adenoma or carcinoma resulting from the kidney step section review indicated slightly increased incidences in 25 and 50 ppm male rats compared with concurrent chamber controls, but not in the 100 ppm group; one 25 ppm male had both an adenoma and a carcinoma.

Urinary Bladder: Carcinoma of the transitional epithelium occurred in two 25 ppm males (Table A-1); this incidence exceeded the historical control ranges for inhalation studies (0%; 0/199) and all routes of administration (0% to 2%; 1/698). Hyperplasia of the transitional epithelium of the urinary bladder, characterized by increased layers of well-differentiated transitional epithelial cells lining the mucosa, occurred in one 50 ppm and two 100 ppm males (Table A-5). The biologic significance of this neoplasm is uncertain; the incidence of this neoplasm was not believed to be related to vinylidene chloride exposure.

Nose: The only exposure-related primary nasal neoplasm observed was adenoma of the respiratory epithelium that was diagnosed in one 50 ppm and four 100 ppm male rats and one 100 ppm female rat (Table 13, Table A-1, Table A-2, and Table B-1). No respiratory epithelium adenomas have been seen in male historical controls, and the incidence in 100 ppm females exceeded the historical control range for inhalation studies (Table 13 and Table B-5). Adenomas were typically small, polypoid masses arranged in glandular or papillary patterns and arose from the transitional epithelium lining the nasotubinates or the lateral wall of Level I (Figure 15). Neoplastic cells were relatively well differentiated, moderately sized, and polygonal with moderate amounts of lightly granular eosinophilic cytoplasm. Nuclei were also moderately sized and round to oval, with lightly stippled chromatin and one to two prominent basophilic to amphophilic nucleoli.

Table 13 Incidences of Neoplasms and Nonneoplastic Lesions of the Nose and Lung in Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Male
Nose^a^ | 49 | 50 | 50 | 50
Turbinate, Atrophy^b^ | 0 | 50** (2.2)^c^ | 50** (3.2) | 50** (3.8)
Turbinate, Hyperostosis | 0 | 49** (2.1) | 50** (2.6) | 50** (2.9)
Olfactory Epithelium, Metaplasia, Respiratory | 3 (1.0) | 49** (2.5) | 49** (3.2) | 48** (3.5)
Olfactory Epithelium, Metaplasia, Squamous | 0 | 0 | 1 (2.0) | 5* (1.2)
Respiratory Epithelium, Hyperplasia | 5 (1.6) | 8 (1.5) | 22** (2.5) | 31** (2.3)
Inflammation, Chronic Active | 9 (1.2) | 36** (2.0) | 45** (2.7) | 48** (3.2)
Thrombosis | 4 (2.3) | 4 (3.0) | 11* (3.3) | 7 (2.7)
Respiratory Epithelium, Adenoma^d^
Overall rate^e^ | 0/49 (0%) | 0/50 (0%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate^f^ | 0.0% | 0.0% | 2.7% | 10.5%
Terminal rate^g^ | 0/25 (0%) | 0/27 (0%) | 1/22 (5%) | 3/19 (16%)
First incidence (days) | –^i^ | – | 729 (T) | 635
Poly-3 test^h^ | P = 0.004 | –^j^ | P = 0.483 | P = 0.051
Lung | 50 | 50 | 50 | 50
Alveolar Epithelium Hyperplasia | 7 (1.1) | 18** (1.5) | 14* (1.6) | 14* (2.3)
Female
Nose | 50 | 50 | 50 | 50
Turbinate, Atrophy | 0 | 50** (2.8) | 50** (3.3) | 50** (4.0)
Turbinate, Hyperostosis | 0 | 50** (1.9) | 50** (2.6) | 50** (2.8)
Olfactory Epithelium, Metaplasia, Respiratory | 1 (1.0) | 50** (2.8) | 50** (3.1) | 50** (3.6)
Respiratory Epithelium, Hyperplasia | 4 (1.3) | 12* (1.6) | 14** (1.7) | 27** (2.1)
Inflammation, Chronic Active | 7 (1.4) | 45** (1.8) | 46** (2.0) | 46** (2.9)
Thrombosis | 0 | 3 (2.3) | 2 (2.0) | 7** (2.3)
Polyp, Inflammatory | 0 | 0 | 0 | 3 (3.0)
Respiratory Epithelium, Adenoma^k^ | 0 | 0 | 0 | 1

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

T = terminal kill.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 0/198; all routes: 0/697.

^e^ Number of animals with neoplasm per number of animals with tissue examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^i^ Not applicable; no neoplasms in animal group.

jValue of statistic cannot be computed.

^k^ Historical incidence for inhalation studies: 0/200; all routes: 1/697 (0.1% ± 0.5%), range 0%–2%.

A variety of nonneoplastic lesions were observed in the nose of male and female rats exposed to vinylidene chloride. Exposure-related nonneoplastic nasal lesions primarily affected Level III, but often extended into Levels II and/or I in 100 ppm rats, depending on the lesion. Turbinate atrophy was a striking lesion that occurred in every exposed male and female rat (Table 13, Table A-5, and Table B-6). This lesion was accompanied in most cases with turbinate hyperostosis, and the severity of both lesions increased with increasing exposure concentration. These lesions were not observed in chamber control rats. Turbinate atrophy was characterized by blunting, shortening, and sometimes loss of turbinates, particularly in Level III. Turbinate hyperostosis was characterized by bony remodeling resulting in thickened, nodular, misshapen turbinate bones. The turbinate changes were observed with and without extensive changes to the overlying epithelium, including respiratory metaplasia.

Olfactory epithelium respiratory metaplasia occurred in most exposed rats with exposure concentration-related increases in severity (Table 13, Table A-5, and Table B-6). This lesion was characterized by atrophy and replacement of the multilayered olfactory epithelium by a single layer of ciliated columnar epithelium. The metaplastic epithelium was often hyperplastic, with numerous folds in the mucosa, extending into the underlying lamina propria (pseudogland formation). Olfactory epithelium squamous metaplasia was less commonly observed, and the incidence in the 100 ppm males was significantly increased. This lesion was characterized by loss of olfactory epithelium and replacement by single to multiple layers of flattened squamous epithelial cells.

Exposure concentration-related increased incidences of respiratory epithelium hyperplasia occurred in male and female rats, and the incidences in 50 and 100 ppm males and in all exposed groups of females were significantly greater than those in the chamber controls (Table 13, Table A-5, and Table B-6). This lesion was characterized by thickening of the respiratory epithelium by increased numbers of cuboidal to ciliated columnar epithelial cells crowded in multiple layers, sometimes forming undulations with invaginations into the underlying lamina propria.

Incidences of chronic active inflammation were significantly increased in all exposed groups of male and female rats compared to the concurrent chamber controls, and the severities of the lesion increased with increasing exposure concentration (Table 13, Table A-5, and Table B-6). Chronic active inflammation was most prominent in Level III, but also affected Levels II and/or I when it was most severe. Inflammation was characterized by collections of neutrophils and mononuclear inflammatory cells in the airways or in the nasal mucosae. Incidences of thrombosis were sporadically observed in nasal vessels of male and female rats, particularly in the dorsal aspects of Level I; incidences of this lesion were significantly increased in 50 ppm males and 100 ppm females. Inflammatory polyp occurred in three 100 ppm females; this lesion was characterized by exophytic and pedunculated masses within the nasal cavity, composed of loose connective tissue covered by a single layer of respiratory epithelium.

Lung: The incidences of alveolar epithelium hyperplasia were significantly increased in all exposed groups of males (Table 13 and Table A-5). In addition, an exposure concentration-related increase in severities of this lesion occurred. The alveolar epithelium hyperplasia was characterized by focal, discrete proliferations of flat to cuboidal, low columnar or hypertrophied epithelial cells (Type II pneumocytes) lining the alveolar septae that were thickened by increased amounts of interstitial collagen.

Liver: Significantly increased incidences of chronic inflammation occurred in all exposed groups of rats (Table 14, Table A-5, and Table B-6). While chamber control rats of both sexes had infiltrates composed of histiocytes and lymphocytes, chronic inflammation in exposed animals was characterized by lipid-laden macrophages as a predominant component of the inflammatory reaction. Severities of inflammation increased with increasing exposure concentration. In some rat livers, a granulomatous reaction characterized by histiocytes and variably sized multinucleated giant cells with abundant cytoplasm was observed. Increased incidences of diffuse fatty change occurred in all exposed groups of rats and severities of the lesion were increased in exposed groups of females. This lesion consisted of individual cells with micro and macrovesicular accumulation of intracellular lipid scattered throughout the parenchyma. Areas of diffuse fatty change often coalesced and bridged into bands throughout the tissue. Significantly increased incidences of necrosis occurred in the 50 ppm male and 50 and 100 ppm female rats.

Table 14 Incidences of Nonneoplastic Lesions of the Liver in Rats in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Inflammation Chronic^a^ | 28 (1.0)^b^ | 46** (1.2) | 46** (1.3) | 44** (1.9)
Fatty Change, Diffuse | 4 (2.0) | 19** (1.7) | 18** (1.7) | 26** (2.0)
Necrosis | 2 (2.5) | 6 (2.8) | 8* (2.6) | 6 (2.3)
Degeneration, Cystic | 2 (2.0) | 5 (2.8) | 7 (1.9) | 12** (2.1)
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Inflammation, Chronic | 42 (1.0) | 48* (1.4) | 49** (1.4) | 48** (2.1)
Fatty Change, Diffuse | 19 (1.2) | 30* (1.7) | 26 (1.7) | 30** (2.0)
Necrosis | 0 | 3 (1.7) | 5* (2.2) | 11** (1.8)
Degeneration, Cystic | 0 | 2 (3.0) | 4* (2.3) | 7** (2.7)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Necrosis was characterized by focal hypereosinophilia, nuclear pyknosis and karyolysis, and loss of normal hepatic cord architecture. Incidences of cystic degeneration were significantly increased in the 100 ppm male and 50 and 100 ppm female rats compared to concurrent chamber controls. This lesion was characterized by hepatocellular dropout resulting in the formation of multifocal cyst-like structures sometimes containing finely granular or flocculent eosinophilic material or erythrocytes.

Ovary: Incidences of bursa dilatation increased in an exposure concentration-related manner (chamber control, 5/50; 25 ppm, 11/50; 50 ppm, 17/50; 100 ppm, 24/50; Table B-6). Severities of bursa dilatation were increased in all exposed female groups (1.8, 3.1, 3.1, 3.2). This lesion was characterized by a diffuse distension of the space between the ovary and its bursal covering, with thinning of the bursal wall. The biologic relevance of this lesion in exposed rats is uncertain.

Other Organs: The incidence of clitoral gland adenoma in 25 ppm females was greater than that in the chamber controls (4/47, 8/48, 3/45, 4/48; Table B-1 and Table B-2) and exceeded the historical control range for inhalation studies [8/196 (4.2% ± 3.9%, range 0%–9%], but was within the historical control range for all routes of administration [56/696 (8.1% ± 6.1%, range 0% to 24%). In addition, the incidence of this neoplasm in the concurrent chamber controls is the highest incidence in inhalation studies in the historical database. The incidence of clitoral gland carcinoma was increased in 100 ppm females (1/47, 0/48, 0/45, 5/48). The biologic significance of this neoplasm is uncertain; the incidence of this neoplasm was not believed to be related to vinylidene chloride exposure.

Incidences of fat necrosis of the mesentery were prevalent in all exposed groups of female rats (13/13, 19/20, 22/23, 23/24; Table B-6), and severities of the lesion were unaffected by exposure concentration (2.0, 2.0, 2.0, 2.0). Histologic evaluation of this lesion was only performed when gross lesions in the mesenteric fat were observed. Fat necrosis of the mesentery was characterized by saponification and loss of normal adipocyte architecture admixed with karyorrhectic and mineralized debris. The pathogenesis of this lesion and its biologic significance are uncertain. There is also a treatment- and exposure concentration-related increase in fat necrosis in the companion mouse study. Localized fat necrosis may be related to the inflammatory lesions in the liver; however, this needs to be further substantiated.

## Mice

### Two-week Study

All male mice exposed to 100 ppm or greater died within the first 4 days of exposure (Table 15). All females exposed to 200 or 400 ppm were found dead following exposure on day 1. One 50 ppm male and one 100 ppm female were removed dead before exposure on day 5. The mean body weight gains of 25 and 50 ppm males were significantly less than that of the chamber controls; the final mean body weights of these groups were 8% and 7% less, respectively, than that of the chamber control group. Two of five 50 ppm males and all 100 ppm males were lethargic. Abnormal breathing occurred in one of five 50 ppm males and four of five 100 ppm males. All 100 ppm female mice became thin, while one female exposed at this level also became lethargic, developed tremors, and was breathing abnormally.

Table 15 Survival and Body Weights of Mice in the Two-week Inhalation Study of Vinylidene Chloride^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 23.1 ± 0.6 | 26.6 ± 0.9 | 3.6 ± 0.6
25 | 5/5 | 23.6 ± 0.3 | 24.4 ± 0.9 | 0.8 ± 0.6* | 92
50 | 4/5^c^ | 23.6 ± 0.4 | 24.9 ± 0.2 | 1.3 ± 0.6* | 93
100 | 0/5^d^ | 23.7 ± 0.2 | – | – | –
200 | 0/5^e^ | 23.3 ± 0.4 | – | – | –
400 | 0/5^e^ | 23.3 ± 0.6 | – | – | –
Female
0 | 5/5 | 19.7 ± 0.4 | 22.2 ± 0.4 | 2.5 ± 0.4
25 | 5/5 | 19.9 ± 0.2 | 21.8 ± 0.5 | 2.0 ± 0.5 | 98
50 | 5/5 | 19.4 ± 0.4 | 21.4 ± 0.3 | 2.0 ± 0.4 | 96
100 | 4/5^c^ | 19.6 ± 0.4 | 22.2 ± 0.7 | 2.5 ± 0.2 | 100
200 | 0/5^e^ | 19.7 ± 0.4 | – | – | –
400 | 0/5^e^ | 19.1 ± 0.2 | – | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 17 days/number initially in group.

^c^ Day of death: 5.

^d^ Days of deaths: 3, 4, 4, 4, 4.

^e^ Day of deaths: 1.

In all surviving groups of exposed females, absolute and relative lung weights were significantly greater than those of the chamber controls (Table G-3). Absolute and relative liver weights of 50 and 100 ppm females and relative liver weights of 25 ppm females and 25 and 50 ppm males were significantly greater than those of the chamber controls.

Gross lesions were observed at 100 ppm and included pale or mottled livers in one male and one female, and pale kidney in one male mouse that survived more than 1 day of exposure.

In the nose, minimal necrosis of the respiratory epithelium occurred in all early-death male and female mice (Table 16). Necrosis involved the respiratory epithelium of the turbinates and lateral wall in Level I of the nose. Necrotic cells had increased cytoplasmic eosinophilia and were often sloughed into the nasal passages.

Table 16 Incidences of Selected Nonneoplastic Lesions in Mice in the Two-week Inhalation Study of Vinylidene Chloride

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Male
Nose^a^ | 5 | 5 | 5 | 5 | 5 | 5
Respiratory Epithelium, Necrosis^b^ | 0 | 0 | 1 (1.0)^c^ | 5** (1.0) | 5** (1.0) | 5** (1.0)
Liver | 5 | 5 | 5 | 5 | 5 | 5
Necrosis | 0 | 0 | 1 (1.0) | 5** (3.0) | 5** (4.0) | 5** (4.0)
Kidney | 5 | 5 | 5 | 5 | 5 | 5
Renal Tubule, Necrosis | 0 | 5** (1.2) | 5** (1.6) | 5** (4.0) | 5** (4.0) | 5** (4.0)
Cast Granular | 0 | 5** (1.8) | 5** (2.2) | 5** (3.0) | 5** (4.0) | 5** (4.0)
Renal Tubule, Regeneration | 0 | 5** (2.8) | 4* (3.0) | 0 | 0 | 0
Female
Nose | 5 | 0 | 5 | 5 | 5 | 5
Respiratory Epithelium, Necrosis | 0 | – | 0 | 1 (1.0) | 5** (1.0) | 5** (1.0)
Liver | 5 | 0 | 5 | 5 | 5 | 5
Necrosis | 0 | – | 0 | 5** (1.6) | 5** (4.0) | 5** (4.0)
Regeneration | 0 | – | 0 | 4* (2.0) | 0 | 0

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the liver, necrosis occurred in all males and females exposed to 100 ppm or greater, and in one male exposed to 50 ppm; in addition, regeneration occurred in the four 100 ppm females that survived to the end of study (Table 16). Hepatic necrosis was moderate to marked in all early-death mice exposed to 100 ppm or greater and minimal in the one 50 ppm male. In the early-death animals, hepatic necrosis was characterized by hypereosinophilic coagulum in centrilobular or midzonal areas that often extended to periportal regions. It was minimal in the four 100 ppm female mice that survived to terminal kill and was characterized by individual hypereosinophilic hepatocytes that demonstrated nuclear karyolysis in centrilobular areas. Hepatic regeneration in these animals was most prominent in the midzonal region and was characterized by an increased density of hepatocytes that had increased cytoplasmic basophilia, rare binucleate forms, and mild to moderate anisokaryosis (variation in nuclear size).

In the kidney, renal tubule necrosis and granular casts occurred in every exposed male (Table 16). The occurrence of granular casts and renal tubule necrosis and regeneration in all 25 ppm males precluded the determination of a no-effect level. Incidences of marked renal tubule necrosis coincided with early deaths in all male mice exposed to 100 ppm or greater. Incidences of minimal to moderate renal tubule necrosis and granular casts occurred in the 25 and 50 ppm male groups. Mild to moderate renal tubule regeneration occurred in 25 and 50 ppm males that survived until terminal sacrifice. Microscopically, renal tubule necrosis was characterized by attenuation, hypereosinophilia, nuclear pyknosis, and loss of tubular epithelium with sloughing into tubular lumens. Granular casts were composed of homogenous eosinophilic material, which often contained granular basophilic debris. Renal tubule regeneration was characterized by tubules with densely packed cuboidal tubule epithelium that often obscured the lumen, with deeply basophilic cytoplasm and prominent vesicular nuclei. Mitotic figures were occasionally seen. Additionally, these animals often had a mild interstitial to subscapular mononuclear inflammatory infiltrate.

Exposure Concentration Selection Rationale: Based on decreased survival of males in the 2-week study, vinylidene chloride exposure concentrations selected for the 3-month inhalation study in male mice were 6.25, 12.5, 25, and 50 ppm. Due to decreased survival of female mice in the 2-week study, vinylidene chloride exposure concentrations selected for the 3-month inhalation study in female mice were 6.25, 12.5, 25, 50, and 100 ppm.

### Three-month Study

Two 50 ppm males and four 100 ppm females died during the first week of the study; all other mice survived until terminal kill (Table 17). The final mean body weights and body weight gains of all exposed groups of females and of males exposed to 12.5 ppm or greater were significantly less than the those of the chamber control groups (Table 17 and Figure 6). There were no exposure-related clinical findings.

Table 17 Survival and Body Weights of Mice in the Three-month Inhalation Study of Vinylidene Chloride^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 23.2 ± 0.4 | 39.4 ± 1.2 | 16.2 ± 1.1
6.25 | 10/10 | 23.4 ± 0.3 | 37.8 ± 0.5 | 14.3 ± 0.3 | 96
12.5 | 10/10 | 23.2 ± 0.2 | 35.5 ± 0.6** | 12.3 ± 0.6** | 90
25 | 10/10 | 23.4 ± 0.2 | 33.5 ± 0.8** | 10.1 ± 0.8** | 85
50 | 8/10^c^ | 22.9 ± 0.2 | 33.0 ± 0.5** | 10.0 ± 0.4** | 84
Female
0 | 10/10 | 19.6 ± 0.2 | 35.2 ± 1.2 | 15.6 ± 1.2
6.25 | 10/10 | 19.5 ± 0.4 | 30.8 ± 0.6** | 11.4 ± 0.7** | 88
12.5 | 10/10 | 20.1 ± 0.3 | 31.9 ± 0.9** | 11.8 ± 0.7** | 91
25 | 10/10 | 19.8 ± 0.3 | 30.9 ± 0.8** | 11.1 ± 0.6** | 88
50 | 10/10 | 19.6 ± 0.4 | 28.7 ± 0.6** | 9.2 ± 0.6** | 82
100 | 6/10^c^ | 19.5 ± 0.4 | 29.9 ± 0.8** | 10.0 ± 0.4** | 85

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of deaths: 1.

Figure 6

Growth Curves for Mice Exposed to Vinylidene Chloride by Inhalation for Three Months

Gross lesions potentially related to exposure were observed in the lung (5/10) and liver (1/10) of 100 ppm female mice and the liver (1/10) and kidney (2/10) of 50 ppm male mice. Lung lesions included pale to white, 1 to 7 mm diameter foci; affected livers were mottled and/or red, and affected kidneys were diffusely pale and/or granular.

Hematology data for mice are presented in Table 18 and Table F-2. Exposure concentration-related decreases (≤8%) in erythrocyte counts, hemoglobin concentrations, and hematocrit values occurred at the end of the study in 12.5, 25, and 50 ppm male mice. Female mice had decreased erythrocyte counts in the 50 and 100 ppm groups, but the decreases (≤4%) were less than those in males. In addition, hemoglobin concentration and the hematocrit value were decreased in 50 ppm female mice, but not in the 100 ppm group. The erythron decreases in the 12.5 ppm and greater males and in the 50 ppm females may be related to the observed decreases in body weight.

Table 18 Selected Hematology Data for Mice in the Three-month Inhalation Study of Vinylidene Chloride^a^

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
n | 10 | 10 | 10 | 10 | 8 | –
Erythrocytes (10^6^/µL) | 10.18 ± 0.09 | 9.96 ± 0.09 | 9.74 ± 0.07** | 9.54 ± 0.07** | 9.40 ± 0.08** | –
Hemoglobin (g/dL) | 15.5 ± 0.1 | 15.1 ± 0.1 | 14.9 ± 0.1** | 14.5 ± 0.1** | 14.2 ± 0.1** | –
Hematocrit (manual) (%) | 49.9 ± 0.5 | 48.6 ± 0.3 | 47.8 ± 0.4** | 46.5 ± 0.4** | 45.9 ± 0.4** | –
Female
n | 10 | 9 | 10 | 10 | 10 | 6
Erythrocytes (10^6^/µL) | 10.19 ± 0.09 | 10.08 ± 0.06 | 10.02 ± 0.07 | 9.97 ± 0.11 | 9.73 ± 0.09** | 9.80 ± 0.08**
Hemoglobin (g/dL) | 15.9 ± 0.1 | 15.7 ± 0.1 | 15.7 ± 0.1 | 15.6 ± 0.2 | 15.3 ± 0.1* | 15.7 ± 0.1
Hematocrit (manual) (%) | 50.2 ± 0.4 | 49.8 ± 0.4 | 49.8 ± 0.3 | 49.3 ± 0.4 | 48.3 ± 0.5** | 50.3 ± 0.4

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are given as mean ± standard error. Statistical tests were performed on unrounded data.

Absolute kidney weights of all exposed groups of males were significantly less than that of the chamber control group (Table G-4). Absolute and relative liver weights of 12.5 ppm or greater females were significantly greater than those of the chamber controls. Relative liver weights were also increased in 6.25 ppm females. Absolute and relative kidney and lung weights of 100 ppm females were significantly greater than those of the chamber controls. Other organ weight differences were related to reduced body weight.

Relative to the chamber controls, male mice exposed to 25 or 50 ppm exhibited nonsignificant decreases in cauda epididymis weights (18% and 10%, respectively) (Table H-3). Males exposed to 12.5, 25, or 50 ppm had significant decreases in total sperm/cauda epididymis. No histopathologic changes in the contralateral organ were observed at necropsy. There were no changes in estrous cyclicity in females attributed to vinylidene chloride (Table H-4). These data suggest that vinylidene chloride has the potential to be a reproductive toxicant in male mice.

Kidney lesions, limited to males, consisted of renal tubule necrosis and protein cast formation in mice that experienced early death and nephropathy in those that survived to terminal kill (Table 19). Marked necrosis of the renal tubules and protein cast formation occurred in two 50 ppm males. Minimal to moderate nephropathy occurred in the 12.5, 25, and 50 ppm male groups. Decreases in the erythrocyte counts, hemoglobin concentration and hematocrit values also occurred in the same exposed groups. Renal tubule necrosis was seen as attenuation and/or loss of tubule epithelial cells with sloughing of pyknotic epithelial cells into tubule lumens. Renal tubule protein casts were present multifocally in tubule lumens as homogeneous, eosinophilic deposits that often contained granular basophilic cellular debris. Nephropathy was composed of minimal to mild tubule necrosis and cast formation; renal tubule regeneration; mild inflammatory infiltrates of lymphocytes, macrophages, and neutrophils within the interstitium and subcapsular areas; and occasional tubule mineralization.

Table 19 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm
Male
Kidney^a^ | 10 | 10 | 10 | 10 | 10 | –
Renal Tubule Necrosis^b^ | 0 | 0 | 0 | 0 | 2 (4.0)^c^ | –
Renal Tubule, Casts Protein | 0 | 0 | 0 | 0 | 2 (4.0) | –
Nephropathy | 0 | 0 | 5* (1.2) | 10** (1.9) | 8** (2.5) | –
Larynx | 10 | 10 | 10 | 10 | 10 | –
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 1 (1.0) | 4* (1.0) | –
Liver | 10 | 10 | 10 | 10 | 10 | –
Necrosis | 0 | 0 | 0 | 0 | 2 (2.0) | –
Female
Larynx | 10 | 10 | 10 | 10 | 9 | 10
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 0 | 8** (1.4)
Respiratory Epithelium, Metaplasia, Squamous | 1 (1.0) | 0 | 1 (2.0) | 3 (1.3) | 9** (1.8) | 7** (2.4)
Necrosis | 0 | 0 | 0 | 0 | 0 | 4* (1.0)
Liver | 10 | 10 | 10 | 10 | 10 | 10
Necrosis | 0 | 0 | 1 (1.0) | 0 | 0 | 4* (4.0)
Hepatocyte, Centrilobular, Hypertrophy | 0 | 0 | 0 | 0 | 0 | 6** (2.8)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Bronchus, Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 6** (2.7)
Inflammation, Histiocytic | 0 | 0 | 0 | 0 | 0 | 6** (1.7)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 0 | 4* (2.5)
Turbinate, Atrophy | 0 | 0 | 0 | 0 | 0 | 4* (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Laryngeal lesions consisted of necrosis and respiratory epithelium hyperplasia and squamous metaplasia (Table 19). Necrosis was minimal and was only seen in early death 100 ppm females. Respiratory epithelium hyperplasia occurred in most 100 ppm females and respiratory epithelium squamous metaplasia occurred in a few males and many females exposed to 25 ppm or greater, with slight increases in severities and incidences in the female mice. Necrosis was characterized by marked cytoplasmic vacuolation of respiratory epithelium with flocculent to wispy cytoplasm containing eosinophilic droplets, and individual pyknotic, hypereosinophilic cells that sloughed into the laryngeal lumen. Necrosis was most prominent dorsolateral to the ventral pouch. Respiratory epithelium hyperplasia consisted of increased size and number of respiratory epithelial cells, and was most prominent in the epithelium overlying the submucosal glands at the base of the epiglottis. Respiratory epithelium squamous metaplasia was characterized by replacement of the normal ciliated columnar epithelium overlying the submucosal glands at the base of the epiglottis with approximately two to four layers of nonkeratinized, polygonal to flattened squamous epithelial cells.

Nonneoplastic lesions of the liver included necrosis in male and female mice and centrilobular hepatocyte hypertrophy in female mice (Table 19). Necrosis was marked in early death 100 ppm females and mild in early death 50 ppm males. Hepatic necrosis was not evident in the 50 ppm mice that survived to terminal kill. Mild to moderate centrilobular hepatocyte hypertrophy was observed in six 100 ppm female mice. Necrosis in mice that died early ranged from piecemeal necrosis (individual hypereosinophilic hepatocytes with nuclear pyknosis and karyolysis) to more extensive necrosis, characterized by a hypereosinophilic coagulum within the centrilobular to midzonal regions that often extended into periportal areas. Centrilobular hepatocyte hypertrophy was characterized by increased numbers of enlarged hepatocytes within centrilobular areas containing more deeply basophilic cytoplasm and enlarged, occasionally binucleate nuclei, moderate variation in nuclear size (anisokaryosis), and mitotic figures.

Exposure-related lung lesions were limited to 100 ppm female mice and consisted of bronchial epithelium necrosis and histiocytic inflammation (Table 19). Bronchial epithelium necrosis occurred in four early-death females and two females that survived to terminal kill, and histiocytic inflammation occurred in all of the females that survived to terminal kill. Microscopically, bronchial epithelium necrosis was characterized by fragmentation and hypereosinophilia of bronchial epithelial cells, with sloughing into bronchial lumens. Histiocytic inflammation was characterized by focal alveolar infiltrates of foamy macrophages, often containing eosinophilic globular material, and associated with extracellular basophilic fibrillar or eosinophilic globular material. Small numbers of neutrophils were present within alveoli, the interstitium, and bordering vessels.

Several females exposed to 100 ppm vinylidene chloride had minimal to moderate necrosis of the nasal respiratory epithelium and minimal turbinate atrophy (Table 19). Male mice did not develop exposure-related nasal lesions. Respiratory epithelium necrosis occurred on the nasoturbinates and lateral wall of Level I of the nose in all early-death female mice and was characterized by hypereosinophilia and sloughing of cells and debris into the nasal passages. Turbinate atrophy occurred in four 100 ppm females and consisted of blunting and attenuation of scrolls with bone loss and remodeling in Level III of the nose.

Exposure Concentration Selection Rationale: In the 3-month study, there was increased mortality in 50 ppm males and 100 ppm females. Terminal body weights were reduced in all groups of males and females exposed to 12.5 ppm or greater compared to the chamber control groups. In male mice, the incidences of nephropathy were significantly increased in the 12.5 ppm or greater groups, and two 50 ppm males had renal tubule necrosis and protein casts. The severity of nephropathy also increased with exposure. The incidence of respiratory epithelium squamous metaplasia of the larynx was also significantly increased in the 50 ppm males. In female mice, exposure-related lesions occurred in the larynx, nose, and lung primarily in the 100 ppm group. Based on these findings in the 3-month study, vinylidene chloride exposure concentrations selected for the 2-year inhalation study in mice were 6.25, 12.5, and 25 ppm.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 20 and in the Kaplan-Meier survival curves (Figure 7). Survival of 6.25 ppm males was significantly greater than that of the chamber controls. Survival of 25 ppm males and 6.25 and 25 ppm females was significantly less than that of the chamber control groups.

Table 20 Incidences of Selected Nonneoplastic Lesions in Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 12 | 5 | 14 | 19
Natural deaths | 9 | 5 | 4 | 12
Animals surviving to study termination | 29 | 40^d^ | 32 | 19^d^
Percent probability of survival at end of study^a^ | 58 | 80 | 64 | 38
Mean survival (days)^b^ | 680 | 713 | 674 | 645
Survival analysis^c^ | P = 0.001 | P = 0.022N | P = 0.791N | P = 0.038
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 11 | 20 | 14 | 17
Natural deaths | 3 | 5 | 6 | 9
Animals surviving to study termination | 36 | 25 | 30 | 24^d^
Percent probability of survival at end of study | 72 | 50 | 60 | 48
Mean survival (days) | 687 | 667 | 688 | 653
Survival analysis | P = 0.064 | P = 0.046 | P = 0.399 | P = 0.027

^a^ Kaplan-Meier determinations

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^100^ is in the chamber control column, and the results of the life table pairwise comparisons^99^ with the chamber controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

^d^ Includes one animal that died during the last week of the study.

Figure 7

Kaplan-Meier Survival Curves for Mice Exposed to Vinylidene Chloride by Inhalation for Two Years

#### Body Weights and Clinical Findings

Mean body weights of 12.5 and 25 ppm males were at least 10% less than those of the chamber control group after weeks 17 and 13, respectively (Table 21 and Table 22, Figure 8). Mean body weights of 25 ppm females were at least 10% less after week 21, and 20% less for weeks 48 to 93 of the study. Exposure-related clinical findings were observed in 25 ppm males and included thinness and abnormal breathing. Exposure-related clinical findings observed in all exposed groups of females included abnormal breathing, thinness, and torso ventral mass.

Table 21 Mean Body Weights and Survival of Male Mice in the Two-year Inhalation Study of Vinylidene Chloride

Day | Chamber Control | | 6.25 ppm | | | 12.5 ppm | | | 25 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 22.8 | 50 | 22.7 | 99 | 50 | 22.0 | 96 | 50 | 22.2 | 97 | 50
11 | 24.6 | 50 | 24.8 | 101 | 50 | 23.9 | 97 | 50 | 23.3 | 95 | 50
18 | 26.0 | 50 | 26.2 | 101 | 50 | 25.3 | 97 | 50 | 24.7 | 95 | 50
25 | 27.3 | 50 | 27.5 | 101 | 50 | 26.8 | 98 | 50 | 26.4 | 97 | 50
32 | 28.3 | 50 | 28.5 | 101 | 50 | 27.6 | 97 | 50 | 27.5 | 97 | 50
39 | 29.5 | 50 | 29.8 | 101 | 50 | 28.8 | 98 | 50 | 28.5 | 97 | 50
46 | 30.4 | 50 | 30.5 | 100 | 50 | 29.6 | 97 | 50 | 29.3 | 96 | 50
53 | 31.6 | 50 | 31.2 | 99 | 50 | 30.0 | 95 | 50 | 29.9 | 95 | 50
60 | 32.4 | 50 | 32.2 | 99 | 50 | 31.0 | 96 | 50 | 30.8 | 95 | 50
67 | 33.5 | 50 | 33.1 | 99 | 50 | 31.6 | 95 | 50 | 31.4 | 94 | 50
74 | 34.1 | 50 | 33.7 | 99 | 50 | 32.3 | 95 | 50 | 32.1 | 94 | 50
81 | 35.5 | 50 | 34.7 | 98 | 50 | 33.0 | 93 | 50 | 32.9 | 93 | 50
88 | 36.4 | 50 | 35.4 | 98 | 50 | 34.1 | 94 | 50 | 33.6 | 93 | 50
116 | 39.8 | 50 | 38.3 | 96 | 50 | 36.6 | 92 | 50 | 36.0 | 90 | 50
144 | 43.3 | 50 | 40.9 | 94 | 50 | 39.2 | 90 | 50 | 37.6 | 87 | 50
172 | 46.1 | 50 | 43.5 | 94 | 50 | 41.3 | 90 | 50 | 38.4 | 83 | 50
200 | 48.0 | 50 | 45.2 | 94 | 50 | 41.9 | 87 | 50 | 39.7 | 83 | 50
228 | 49.5 | 50 | 47.3 | 96 | 50 | 43.6 | 88 | 50 | 40.7 | 82 | 50
256 | 50.7 | 50 | 48.4 | 96 | 50 | 44.3 | 88 | 50 | 41.3 | 82 | 50
284 | 51.2 | 50 | 49.3 | 96 | 50 | 44.9 | 88 | 50 | 41.7 | 82 | 50
312 | 51.7 | 50 | 50.1 | 97 | 50 | 45.5 | 88 | 50 | 42.3 | 82 | 50
341 | 52.0 | 50 | 50.5 | 97 | 50 | 45.9 | 88 | 50 | 42.3 | 81 | 50
368 | 52.5 | 50 | 51.2 | 98 | 50 | 46.4 | 88 | 50 | 43.1 | 82 | 50
396 | 52.1 | 50 | 51.6 | 99 | 50 | 46.7 | 90 | 50 | 43.3 | 83 | 50
424 | 52.8 | 50 | 51.7 | 98 | 50 | 46.8 | 89 | 49 | 43.1 | 82 | 50
452 | 52.9 | 49 | 52.1 | 99 | 50 | 46.9 | 89 | 47 | 43.3 | 82 | 49
480 | 53.0 | 49 | 52.2 | 99 | 50 | 46.9 | 89 | 47 | 43.5 | 82 | 47
508 | 52.4 | 47 | 51.7 | 99 | 50 | 47.0 | 90 | 46 | 43.1 | 82 | 47
536 | 52.7 | 45 | 51.8 | 98 | 49 | 47.2 | 89 | 44 | 43.0 | 82 | 44
564 | 52.4 | 44 | 51.6 | 99 | 49 | 46.8 | 89 | 44 | 43.3 | 83 | 39
592 | 52.3 | 43 | 51.0 | 98 | 49 | 46.1 | 88 | 43 | 43.4 | 83 | 34
620 | 52.0 | 41 | 50.4 | 97 | 48 | 46.2 | 89 | 39 | 42.7 | 82 | 30
648 | 52.2 | 37 | 50.8 | 97 | 46 | 46.5 | 89 | 34 | 43.0 | 82 | 26
662 | 52.9 | 35 | 50.9 | 96 | 44 | 46.0 | 87 | 33 | 42.5 | 81 | 25
676 | 53.1 | 34 | 50.6 | 95 | 43 | 45.5 | 86 | 33 | 42.2 | 80 | 23
690 | 52.5 | 34 | 50.3 | 96 | 42 | 45.0 | 86 | 33 | 41.5 | 79 | 23
704 | 52.2 | 32 | 49.6 | 95 | 41 | 43.9 | 84 | 33 | 41.0 | 79 | 20
718 | 52.5 | 30 | 49.4 | 94 | 40 | 43.6 | 83 | 33 | 40.1 | 76 | 19
Mean for Weeks
1–13 | 30.2 | – | 30.0 | 99 | – | 28.9 | 96 | – | 28.7 | 95 | –
14–52 | 48.0 | – | 45.9 | 96 | – | 42.6 | 89 | – | 40.0 | 83 | –
53–103 | 52.5 | – | 51.1 | 97 | – | 46.1 | 88 | – | 42.6 | 81 | –

Table 22 Mean Body Weights and Survival Female Mice in the Two-year Inhalation Study of Vinylidene Chloride

Day | Chamber Control | | 6.25 ppm | | | 12.5 ppm | | | 25 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 19.1 | 50 | 19.1 | 100 | 50 | 18.7 | 98 | 50 | 18.8 | 99 | 50
11 | 21.0 | 50 | 21.1 | 101 | 50 | 20.9 | 100 | 50 | 20.5 | 98 | 50
18 | 21.7 | 50 | 21.9 | 101 | 50 | 21.6 | 100 | 50 | 21.5 | 99 | 50
25 | 22.5 | 50 | 23.0 | 102 | 50 | 22.9 | 102 | 50 | 23.0 | 102 | 50
32 | 23.8 | 50 | 24.2 | 102 | 50 | 23.9 | 100 | 50 | 23.9 | 100 | 50
39 | 25.0 | 50 | 25.1 | 100 | 50 | 25.2 | 101 | 50 | 24.9 | 99 | 50
46 | 25.9 | 50 | 26.0 | 101 | 50 | 26.1 | 101 | 50 | 25.6 | 99 | 50
53 | 26.1 | 50 | 27.1 | 104 | 50 | 26.8 | 103 | 50 | 26.5 | 102 | 50
60 | 26.7 | 50 | 27.6 | 103 | 50 | 27.4 | 103 | 50 | 26.8 | 100 | 50
67 | 27.8 | 50 | 28.6 | 103 | 50 | 28.2 | 101 | 50 | 27.4 | 99 | 50
74 | 28.7 | 50 | 29.2 | 102 | 50 | 28.9 | 101 | 50 | 27.7 | 97 | 50
81 | 29.0 | 50 | 30.4 | 105 | 50 | 29.9 | 103 | 50 | 28.8 | 99 | 50
88 | 29.6 | 50 | 30.6 | 104 | 50 | 30.9 | 105 | 50 | 29.5 | 100 | 50
116 | 32.5 | 50 | 34.9 | 107 | 50 | 34.9 | 107 | 50 | 31.9 | 98 | 50
144 | 36.9 | 50 | 38.7 | 105 | 50 | 38.6 | 104 | 50 | 34.3 | 93 | 50
172 | 40.4 | 50 | 41.5 | 103 | 50 | 41.3 | 102 | 50 | 35.6 | 88 | 50
200 | 43.3 | 50 | 45.0 | 104 | 50 | 43.3 | 100 | 50 | 38.0 | 88 | 50
228 | 46.4 | 50 | 47.8 | 103 | 50 | 46.4 | 100 | 50 | 39.8 | 86 | 50
256 | 49.1 | 50 | 50.9 | 104 | 50 | 49.5 | 101 | 50 | 41.4 | 84 | 50
284 | 51.5 | 50 | 53.6 | 104 | 50 | 52.1 | 101 | 50 | 43.3 | 84 | 50
312 | 54.7 | 50 | 56.6 | 103 | 50 | 54.3 | 99 | 50 | 44.6 | 82 | 50
341 | 57.4 | 49 | 58.1 | 101 | 50 | 55.6 | 97 | 50 | 44.9 | 78 | 50
368 | 60.0 | 49 | 60.3 | 101 | 50 | 57.6 | 96 | 50 | 47.3 | 79 | 50
396 | 62.3 | 49 | 61.7 | 99 | 50 | 59.0 | 95 | 49 | 48.0 | 77 | 50
424 | 63.3 | 49 | 62.5 | 99 | 50 | 60.2 | 95 | 49 | 48.8 | 77 | 47
452 | 64.2 | 48 | 63.8 | 100 | 50 | 61.2 | 95 | 49 | 49.5 | 77 | 45
480 | 64.8 | 48 | 64.5 | 100 | 47 | 61.5 | 95 | 49 | 50.2 | 77 | 45
508 | 64.6 | 47 | 64.0 | 99 | 47 | 61.9 | 96 | 49 | 51.2 | 79 | 43
536 | 65.1 | 46 | 64.2 | 99 | 46 | 62.7 | 96 | 47 | 51.3 | 79 | 41
564 | 65.1 | 46 | 63.8 | 98 | 43 | 62.2 | 96 | 47 | 52.2 | 80 | 38
592 | 65.2 | 44 | 63.4 | 97 | 39 | 61.7 | 95 | 46 | 52.3 | 80 | 37
620 | 65.2 | 41 | 63.7 | 98 | 34 | 61.3 | 94 | 42 | 51.6 | 79 | 35
648 | 66.0 | 38 | 61.1 | 93 | 31 | 60.9 | 92 | 38 | 51.6 | 78 | 33
662 | 64.5 | 37 | 59.9 | 93 | 30 | 61.1 | 95 | 36 | 52.0 | 81 | 30
676 | 63.8 | 37 | 60.1 | 94 | 29 | 60.9 | 96 | 33 | 52.3 | 82 | 28
690 | 62.9 | 37 | 58.9 | 94 | 27 | 60.0 | 96 | 32 | 51.9 | 83 | 28
704 | 61.4 | 37 | 58.1 | 95 | 27 | 59.8 | 97 | 30 | 51.1 | 83 | 27
718 | 60.3 | 37 | 57.4 | 95 | 26 | 58.8 | 97 | 30 | 50.2 | 83 | 26
Mean for Weeks
1–13 | 25.1 | – | 25.7 | 102 | – | 25.5 | 101 | – | 25.0 | 99 | –
14–52 | 45.8 | – | 47.5 | 104 | – | 46.2 | 101 | – | 39.3 | 86 | –
53–103 | 63.7 | – | 61.7 | 97 | – | 60.7 | 95 | – | 50.7 | 80 | –

Figure 8

Growth Curves for Mice Exposed to Vinylidene Chloride by Inhalation for Two Years

#### Gross Findings

Gross lesions potentially related to vinylidene chloride exposure were observed in the kidney of male mice and ranged from pale, 1 mm cortical foci to large, occasionally bilateral masses that often replaced normal renal parenchyma.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of hemangioma and hemangiosarcoma and neoplasms and/or nonneoplastic lesions of the kidney, liver, lung, small intestine, nose, mesentery, and uterus. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Kidney: Microscopic chemical-related lesions in the kidney of males consisted of renal tubule hyperplasia, renal tubule adenoma, and renal tubule carcinoma. The incidences of adenoma, carcinoma, and adenoma or carcinoma (combined) were significantly increased in all exposed groups of males compared to those in the concurrent chamber control group (Table 23, Table C-1, and Table C-2). The incidences of adenoma, carcinoma, and adenoma or carcinoma (combined) in exposed groups of males exceeded the historical control ranges for inhalation studies, where none have occurred, and for all routes of administration (Table 23 and Table C-3). A renal tubule adenoma occurred in one 25 ppm female mouse (Table D-1), no such adenoma had been observed in 947 historical control male mice by all routes of exposure. No renal tubule neoplasms were observed in any other treated female mice, and no adenomas or carcinomas were observed in male or female chamber control mice. Adenomas were most often solitary and unilateral; one incidence of bilateral renal tubule adenoma and three incidences of multiple renal tubule adenoma occurred in 12.5 ppm males. Similar to adenomas, most carcinomas occurred as solitary masses, but the incidences of bilateral carcinoma increased with increasing exposure concentration. In addition, three 12.5 ppm males had multiple carcinomas in one kidney, and four 12.5 ppm males had multiple carcinomas bilaterally.

Table 23 Incidences of Neoplasms and Nonneoplastic Lesions of the Kidney in Male Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Number Examined Microscopically | 50 | 50 | 50 | 50
Renal Tubule, Hyperplasia^a^ | 0 | 8** (1.8)^b^ | 22** (1.7) | 16** (1.7)
Cyst | 1 (2.0) | 1 (2.0) | 5 (2.0) | 7* (2.6)
Nephropathy | 44 (1.9) | 46 (1.6) | 37* (2.2) | 44 (2.2)
Renal Tubule, Adenoma, Single | 0 | 5 | 15** | 10**
Renal Tubule, Adenoma, Bilateral | 0 | 0 | 1 | 0
Renal Tubule, Adenoma, Multiple | 0 | 0 | 3 | 0
Renal Tubule, Adenoma (includes single, bilateral, and multiple)^c^
Overall rate^d^ | 0/50 (0%) | 5/50 (10%) | 19/50 (38%) | 10/50 (20%)
Adjusted rate^e^ | 0.0% | 10.6% | 44.2% | 26.7%
Terminal rate^f^ | 0/29 (0%) | 5/40 (13%) | 15/32 (47%) | 8/19 (42%)
First incidence (days) | –^h^ | 729 (T) | 600 | 525
Poly-3 test^g^ | P < 0.001 | P = 0.041 | P < 0.001 | P < 0.001
Renal Tubule, Carcinoma, Single | 0 | 6 | 17** | 12**
Renal Tubule, Carcinoma, Bilateral | 0 | 1 | 7* | 6*
Renal Tubule, Carcinoma, Multiple | 0 | 0 | 3 | 0
Renal Tubule, Carcinoma, Multiple Bilateral | 0 | 0 | 4 | 0
Renal Tubule, Carcinoma (includes single, bilateral, multiple, and multiple bilateral)^i^
Overall rate | 0/50 (0%) | 7/50 (14%) | 31/50 (62%) | 18/50 (36%)
Adjusted rate | 0.0% | 14.7% | 70.5% | 45.8%
Terminal rate | 0/29 (0%) | 5/40 (13%) | 24/32 (75%) | 10/19 (53%)
First incidence (days) | – | 619 | 429 | 537
Poly-3 test | P < 0.001 | P = 0.012 | P < 0.001 | P < 0.001
Renal Tubule, Adenoma or Carcinoma^j^
Overall rate | 0/50 (0%) | 11/50 (22%) | 37/50 (74%) | 27/50 (54%)
Adjusted rate | 0.0% | 23.1% | 81.9% | 67.0%
Terminal rate | 0/29 (0%) | 9/40 (23%) | 27/32 (84%) | 17/19 (90%)
First incidence (days) | – | 619 | 429 | 525
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

T = terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 0/298; all routes: 8/944 (0.9% ± 1.4%), range 0%–4%.

^d^ Number of animals with neoplasm per number of animals with kidney examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Not applicable; no neoplasms in animal group.

^i^ Historical incidence for inhalation studies: 0/298; all routes: 3/944 (0.3% ± 1.0%), range 0%–4%.

^j^ Historical incidence for inhalation studies: 0/298; all routes: 11/944 (1.2% ± 1.8%), range 0%–6%.

Renal tubule adenomas were variably sized, well-circumscribed, solitary and discrete, expansile masses composed of fairly well-differentiated neoplastic tubule epithelial cells greater than five tubules in diameter, which compressed the adjacent renal parenchyma. The masses were solid, papillary to cystic, and arranged in tubules, rows, papillae, or sheets composed of tightly packed cuboidal to ovoid, occasionally markedly vacuolated cells overlying a fine fibrovascular stroma (Figure 16). Mitoses were rare or absent. Renal tubule carcinomas shared many of the morphologic features present within adenomas, but were generally larger, more compressive to locally invasive, had solid, papillary, cystic, or anaplastic growth patterns, prominent vascular ingrowth, and occasionally large areas of necrosis, hemorrhage, or proteinaceous fluid accumulation, and displayed nuclear and cellular pleomorphism, atypia, and numerous mitoses (Figure 17).

The incidences of renal tubule hyperplasia were significantly increased in all exposed groups of males compared to that in the chamber controls (Table 23 and Table C-4). Hyperplasia was characterized by enlarged tubules (approximately two to five tubules in diameter) containing increased numbers of epithelial cells with eosinophilic, basophilic, or clear cytoplasm, which exhibited piling and crowding, variable nuclear and cellular pleomorphism, and multilayered or solid growth that partially or completely filled the tubule lumen (Figure 18). The incidence of kidney cyst was significantly increased in 25 ppm males; this lesion also occurred in two females and one female in the 6.25 and 12.5 ppm groups, respectively (Table D-4). Kidney cysts were characterized by variably sized dilations lined by flattened cuboidal epithelial cells which often compressed adjacent renal parenchyma. The incidence of kidney nephropathy was significantly decreased in 12.5 ppm males.

Liver: The incidence of hepatocellular adenoma (including multiple) was significantly increased in 12.5 ppm female mice compared to that in concurrent chamber controls and the incidence of hepatocellular carcinoma (including multiple) was significantly increased in 25 ppm females (Table 24, Table D-1, and Table D-2). When combined, the incidences of hepatocellular adenoma or carcinoma were significantly increased in 12.5 and 25 ppm females. The incidences of hepatocellular adenoma in 12.5 and 25 ppm females and hepatocellular carcinoma and hepatocellular adenoma or carcinoma (combined) in all exposed female groups exceeded the historical control ranges for inhalation studies, but were within the historical control ranges for all routes of administration (Table 24 and Table D-3). Hepatocellular adenomas were generally discrete, expansile proliferations of solid sheets of fairly well-differentiated hepatocytes that caused compression of the adjacent hepatic parenchyma. Hepatocellular carcinomas were characterized by large, infiltrative proliferations of solid lobules or trabeculae generally greater than three hepatocytes thick, composed of poorly differentiated hepatocytes effacing the normal lobular architecture of the liver.

Table 24 Incidences of Neoplasms and Nonneoplastic Lesions of the Liver in Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Basophilic Focus^a^ | 2 | 4 | 2 | 7*
Hepatocellular Adenoma, Multiple | 20 | 19 | 17 | 13
Hepatocellular Adenoma (includes multiple)
Overall rate^b^ | 37/50 (74%) | 35/50 (70%) | 33/50 (66%) | 25/50 (50%)
Adjusted rate^c^ | 77.6% | 72.5% | 73.8% | 60.0%
Terminal rate^d^ | 21/29 (72%) | 31/40 (78%) | 25/32 (78%) | 12/19 (63%)
First incidence (days) | 443 | 619 | 429 | 471
Poly-3 test^e^ | P = 0.040N | P = 0.361N | P = 0.422N | P = 0.046N
Hepatocellular Carcinoma, Multiple | 8 | 1 | 4 | 8
Hepatocellular Carcinoma (includes multiple)
Overall rate | 26/50 (52%) | 19/50 (38%) | 15/50 (30%) | 29/50 (58%)
Adjusted rate | 55.0% | 38.1% | 33.2% | 64.4%
Terminal rate | 11/29 (38%) | 11/40 (28%) | 7/32 (22%) | 10/19 (53%)
First incidence (days) | 443 | 521 | 508 | 425
Poly-3 test | P = 0.118 | P = 0.070N | P = 0.026N | P = 0.234
Hepatocholangiocarcinoma^f^ | 1 | 2 | 2 | 3
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Hepatocellular Adenoma, Multiple | 12 | 9 | 26* | 17
Hepatocellular Adenoma (includes multiple)^g^
Overall rate | 25/50 (50%) | 21/50 (42%) | 36/50 (72%) | 29/50 (58%)
Adjusted rate | 55.3% | 49.0% | 77.6% | 69.0%
Terminal rate | 20/36 (56%) | 13/25 (52%) | 25/30 (83%) | 19/24 (79%)
First incidence (days) | 509 | 471 | 524 | 443
Poly-3 test | P = 0.026 | P = 0.347N | P = 0.015 | P = 0.126
Hepatocellular Carcinoma, Multiple | 1 | 2 | 2 | 3
Hepatocellular Carcinoma (includes multiple)^h^
Overall rate | 8/50 (16%) | 14/50 (28%) | 12/50 (24%) | 17/50 (34%)
Adjusted rate | 18.2% | 32.4% | 27.2% | 41.3%
Terminal rate | 6/36 (17%) | 4/25 (16%) | 8/30 (27%) | 9/24 (38%)
First incidence (days) | 611 | 478 | 611 | 415
Poly-3 test | P = 0.022 | P = 0.097 | P = 0.223 | P = 0.015
Hepatocellular Adenoma or Carcinoma^i^
Overall rate | 28/50 (56%) | 30/50 (60%) | 37/50 (74%) | 38/50 (76%)
Adjusted rate | 61.5% | 65.4% | 79.3% | 84.4%
Terminal rate | 22/36 (61%) | 14/25 (56%) | 25/30 (83%) | 21/24 (88%)
First incidence (days) | 509 | 471 | 524 | 415
Poly-3 test | P = 0.003 | P = 0.434 | P = 0.041 | P = 0.009
Hepatocholangiocarcinoma^j^ | 0 | 1 | 1 | 2

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

^a^ Number of animals with lesion.

^b^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 2/299 (0.7% ± 1.0%), range 0%–2%; all routes: 10/949 (1.1% ± 2.2%), range 0%–8%.

^g^ Historical incidence for inhalation studies: 105/300 (35.0% ± 8.8%), range 28%–50%; all routes: 378/948 (39.9% ± 18.7%), range 14%–78%.

^h^ Historical incidence for inhalation studies: 44/300 (14.7% ± 5.0%), range 8%–20%; all routes: 152/948 (16.0% ± 10.6%), range 4%–46%.

^i^ Historical incidence for inhalation studies: 133/300 (44.3% ± 8.6%), range 32%–56%; all routes: 448/948 (47.3% ± 19.3%), range 20%–82%.

^j^ Historical incidence for inhalation studies: 0/300; all routes: 0/948.

The incidences of hepatocholangiocarcinoma in exposed groups of males were higher than in the concurrent chamber control groups, and exceeded the historical control range for inhalation studies but not that for all routes of administration (Table 24, Table C-1, and Table C-2). In females, hepatocholangiocarcinoma occurred in all exposed groups; this neoplasm has not been seen in 300 inhalation controls or 948 controls from all routes of study. Hepatocholangiocarcinomas were characterized by infiltrative proliferations of trabeculae and solid sheets of poorly differentiated hepatocytes admixed with neoplastic biliary structures that effaced the normal lobular architecture of the liver.

The incidences of hepatocellular adenoma (including multiple) were decreased in males in an exposure concentration-dependent fashion, and the incidences of hepatocellular carcinoma (including multiple) were decreased in 6.25 and 12.5 ppm males (Table 24, Table C-1, and Table C-2). The incidence of basophilic focus of the liver was significantly increased in 25 ppm males (Table 24 and Table C-4).

Hemangioma and Hemangiosarcoma: The incidences of hemangioma in all exposed groups of females were increased compared to that in the concurrent chamber controls, and these incidences exceeded the historical control ranges for inhalation studies and all routes of administration (Table 25 and Table D-1). This neoplasm occurred in the liver, ovary, and uterus of exposed females and in the liver, bone marrow, and testes of exposed males (Table C-1 and Table D-1). Hemangiomas were composed of expansile proliferations of dilated to cavernous vascular spaces lined with well-differentiated endothelial cells. When all organs were combined, the incidence of hemangiosarcoma in 25 ppm females was greater than that in the concurrent chamber controls and exceeded the historical control ranges for inhalation studies and all routes of administration (Table 25, Table D-1, and Table D-2). Incidences of hemangiosarcoma in female mice were primarily driven by the incidences of this neoplasm in the liver, in which the incidence of hemangiosarcoma in the 25 ppm group was significantly greater than that in the concurrent chamber controls. Hemangiosarcomas occurred in the liver, spleen, mediastinal lymph node, and skeletal muscle of males and females, in the bone marrow, lung, kidney, and thymus of males, and mesentery, ovary, uterus, urinary bladder, and in subcutaneous skin tissues of females. When all organs were combined, the incidence of hemangioma or hemangiosarcoma (combined) in 25 ppm females was significantly greater than that in the concurrent chamber controls. Hemangiosarcomas were composed of infiltrative or invasive proliferations of poorly differentiated endothelial cells forming haphazard vascular channels within multiple organs.

Table 25 Incidences of Hemangioma and Hemangiosarcoma in Female Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Liver^a^ | 50 | 50 | 50 | 50
Hemangioma^b^ | 0 | 1 | 0 | 2
Hemangiosarcoma
Overall rate^c^ | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 6/50 (12%)
Adjusted rate^d^ | 2.3% | 2.5% | 2.3% | 15.2%
Terminal rate^e^ | 1/36 (3%) | 1/25 (4%) | 1/30 (3%) | 3/24 (13%)
First incidence (days) | 731 (T) | 731 (T) | 731 (T) | 508
Poly-3 test^f^ | P = 0.007 | P = 0.740 | P = 0.758 | P = 0.041
All Organs | 50 | 50 | 50 | 50
Hemangioma^g^ | 0 | 2 | 2 | 2
Hemangiosarcoma^h^ | 4 | 4 | 4 | 9
Hemangioma or Hemangiosarcoma^i^
Overall rate^j^ | 4/50 (8%) | 6/50 (12%) | 6/50 (12%) | 11/50 (22%)
Adjusted rate | 9.2% | 14.9% | 13.9% | 27.5%
Terminal rate | 4/36 (11%) | 4/25 (16%) | 4/30 (13%) | 7/24 (29%)
First incidence (days) | 731 (T) | 471 | 620 | 508
Poly-3 test | P = 0.018 | P = 0.324 | P = 0.368 | P = 0.027

T = terminal kill.

^a^ Number of animals with liver examined microscopically or number necropsied (all organs).

^b^ Number of animals with neoplasm.

^c^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal kill.

^f^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^g^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 0/300; all routes: 5/950 (0.5% ± 0.9%), range 0%–2%.

^h^ Historical incidence for inhalation studies: 21/300 (7.0% ± 2.1%), range 4%–10%; all routes: 50/950 (5.3% ± 3.9%), range 0%–12%.

^i^ Historical incidence for inhalation studies: 21/300 (7.0% ± 2.1%), range 4%–10%; all routes: 55/950 (5.8% ± 3.7%), range 2%–14%.

^j^ Number of animals with neoplasm per number of animals necropsied.

Lung: The incidence of alveolar/bronchiolar carcinoma (including multiple) in 12.5 ppm females was significantly increased and exceeded the historical control range for inhalation studies (Table 26, Table D-1, and Table D-2). Alveolar/bronchiolar carcinomas were characterized by discrete expansile to locally infiltrative irregularly shaped masses composed of solid lobules, papillary projections, and tubular structures composed of fairly well- to poorly differentiated epithelial cells, which effaced the normal alveolar parenchyma.There were slight increases in the incidences of alveolar epithelium hyperplasia in the lung of exposed groups of males (Table 26 and Table C-4). However, there were no increased incidences of lung neoplasms in any exposed groups of males (Table C-1), despite the significantly increased incidence of alveolar/bronchiolar carcinoma in 12.5 ppm females.

Table 26 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Alveolar Epithelium Hyperplasia^a^ | 3 (1.3)^b^ | 7 (1.3) | 4 (1.8) | 6 (2.3)
Female
Number Examined Microscopically | 50 | 50 | 50 | 49
Alveolar/bronchiolar Adenoma, Multiple | 1 | 0 | 0 | 0
Alveolar/bronchiolar Adenoma (includes multiple) | 3 | 4 | 2 | 2
Alveolar/bronchiolar Carcinoma, Multiple | 0 | 0 | 1 | 0
Alveolar/bronchiolar Carcinoma (includes multiple)^c^
Overall rate^d^ | 1/50 (2%) | 2/50 (4%) | 7/50 (14%) | 5/49 (10%)
Adjusted rate^e^ | 2.3% | 4.9% | 16.1% | 12.7%
Terminal rate^f^ | 1/36 (3%) | 0/25 (0%) | 6/30 (20%) | 1/24 (4%)
First incidence (days) | 731 (T) | 558 | 392 | 502
Poly-3 test^g^ | P = 0.038 | P = 0.477 | P = 0.030 | P = 0.080
Alveolar/bronchiolar Adenoma or Carcinoma | 4 | 5 | 9 | 7

T = terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 13/299 (4.4% ± 4.3%), range 0%–10%; all routes: 38/949 (4.0% ± 3.6%), range 0%–14%.

^d^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

Small Intestine: Carcinoma of the duodenum occurred in two 25 ppm males (Table 27 and Table C-1). One carcinoma occurred in the ileum of a 6.25 ppm male. Carcinomas of the duodenum or ileum have not been reported in the six inhalation studies included in the 2013 historical control database. Carcinoma also occurred in the jejunum of two 6.25 ppm males. Adenoma occurred in the ileum of a chamber control male and in the duodenum of one 12.5 ppm male. The overall combined incidences of small intestine (duodenum, jejunum, or ileum) carcinoma in males were within the historical control ranges for inhalation studies and all routes of administration (Table 27, Table C-1, and Table C-2).

Table 27 Incidences of Neoplasms of the Small Intestine in Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Male
Duodenum^a^ | 50 | 50 | 50 | 50
Adenoma^b^ | 0 | 0 | 1 | 0
Carcinoma^c^ | 0 | 0 | 0 | 2
Jejunum | 50 | 50 | 50 | 50
Carcinoma^d^ | 0 | 2 | 0 | 0
Ileum | 50 | 50 | 50 | 50
Adenoma | 1 | 0 | 0 | 0
Carcinoma^e^ | 0 | 1 | 0 | 0
Small Intestine (Duodenum, Jejunum, or Ileum) | 50 | 50 | 50 | 50
Adenoma | 1 | 0 | 1 | 0
Carcinoma^f^ | 0 | 3 | 0 | 2
Small Intestine (Duodenum, Jejunum, or Ileum): Adenoma or Carcinoma^g^
Overall rate^h^ | 1/50 (2%) | 3/50 (6%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate^i^ | 2.4% | 6.4% | 2.4% | 5.4%
Terminal rate^j^ | 1/29 (3%) | 3/40 (8%) | 1/32 (3%) | 1/19 (5%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 563
Poly-3 test^k^ | P = 0.463 | P = 0.348 | P = 0.758 | P = 0.455
Female
Duodenum | 50 | 50 | 50 | 50
Adenoma | 0 | 0 | 1 | 0
Ileum | 50 | 50 | 50 | 50
Adenoma | 1 | 0 | 0 | 1
Carcinoma^l^ | 1 | 1 | 1 | 3
Small Intestine (Duodenum or Ileum): Adenoma or Carcinoma^m^
Overall rate | 2/50 (4%) | 1/50 (2%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 4.6% | 2.5% | 4.6% | 10.4%
Terminal rate | 1/36 (3%) | 0/25 (0%) | 1/30 (3%) | 3/24 (13%)
First incidence (days) | 599 | 584 | 536 | 640
Poly-3 test | P = 0.141 | P = 0.531N | P = 0.691 | P = 0.279

T = terminal kill.

^a^ Number of animals necropsied.

^b^ Number of animals with neoplasm.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 0/300; all routes: 1/950 (0.1% ± 0.5%), range 0%–2%.

^d^ Historical incidence for inhalation studies: 6/300 (2.0% ± 3.4%), range 0%–8%; all routes: 18/950 (1.9% ± 2.2%), range 0%–8%.

^e^ Historical incidence for inhalation studies: 0/300; all routes: 0/950.

^f^ Historical incidence for inhalation studies: 6/300 (2.0% ± 3.4%), range 0%–8%; all routes: 19/950 (2.0% ± 2.2%), range 0%–8%.

^g^ Historical incidence for inhalation studies: 10/300 (3.3% ± 2.7%), range 0%–8%; all routes: 31/950 (3.3% ± 2.3%), range 0%–8%.

hNumber of animals with neoplasm per number of animals necropsied.

^i^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^j^ Observed incidence at terminal kill.

^k^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^l^ Historical incidence for inhalation studies: 2/300 (0.7% ± 1.0%), range 0%–2%; all routes: 2/950 (0.2% ± 0.6%), range 0%–2%.

^m^ Historical incidence for inhalation studies (includes jejunum): 4/300 (1.3% ± 1.6%), range 0%–4%; all routes: 10/950 (1.1% ± 1.4%), range 0%–4%.

One adenoma occurred in the duodenum of a 12.5 ppm female, one adenoma and three carcinomas occurred in the ileum of 25 ppm females, and one ileum carcinoma occurred in a 6.25 ppm and a 12.5 ppm female (Table 27, Table D-1, and Table D-2). In 25 ppm females, the incidence of carcinomas of the ileum exceeded the historical control ranges for inhalation studies and all routes of administration as did the incidence of adenoma or carcinoma in all small intestine sites. Small intestine adenomas were typically discrete, exophytic masses composed of well-differentiated glandular epithelial cells that did not invade the underlying lamina propria. Carcinomas of the small intestine were characterized by polypoid to sessile proliferations of tubules and acini composed of generally fairly well differentiated epithelium showing local infiltration into the underlying lamina propria or deeper muscle layers. Carcinomas often exhibited regional or local atypia and pleomorphism, including alterations in architectural pattern and increased mitotic figures.

Nose: Exposure-related nonneoplastic lesions occurring in the nose included turbinate atrophy, hyperostosis, olfactory epithelium respiratory metaplasia, and olfactory epithelium hyaline droplet accumulation (Table 28, Table C-4, and Table D-4). These lesions primarily affected Level III, but often, depending on the lesion, extended into Levels II and/or I in mice exposed to 25 ppm. Turbinate atrophy occurred in the vast majority of male and female mice exposed to vinylidene chloride and the severity of the lesion increased with increasing exposure concentration. Turbinate atrophy was characterized by blunting, attenuation, or loss of turbinates. Incidences of hyperostosis increased in an exposure concentration-related fashion, and occurred in most male and female mice in the 12.5 and 25 ppm groups. Hyperostosis occurred in one chamber control male. This lesion was characterized by extensive bony remodeling of turbinate bones, resulting in misshapen and often thickened, nodular turbinates. Additionally, hyperostosis was often present in the ventral portion of the nasal septum of Level III. Accompanying the septal and turbinate changes were significantly increased incidences of respiratory metaplasia in the olfactory epithelium in all exposed groups of males and females, with exposure concentration-related increases in severities. This lesion was characterized by replacement of the multilayered olfactory epithelium by a single layer of nonciliated or ciliated cuboidal to columnar epithelium. Attenuation of the olfactory epithelium and loss of nerves in the underlying lamina propria often accompanied respiratory metaplasia. The incidences of olfactory epithelium hyaline droplet accumulation were increased in all exposed groups of males and in 25 ppm females; the increases were significant in 12.5 ppm males and 25 ppm males and females. This lesion was characterized by the accumulation of globular, homogeneous, eosinophilic material within the cytoplasm of olfactory epithelial cells. The incidence of respiratory epithelium hyperplasia was significantly increased in 25 ppm females (Table 28 and Table D-4). This lesion occurred in Levels I and II of the nose, and was characterized by increased numbers and crowding of respiratory epithelial cells, with folding of the mucosa and extension of infolding into the underlying submucosa (pseudogland formation).

Table 28 Incidences of Nonneoplastic Lesions of the Nose in Mice in the Two-year Inhalation Study of Vinylidene Chloride

| Chamber Control | 6.25 ppm | 12.5 ppm | 25 ppm
Male
Number Examined Microscopically | 50 | 50 | 49 | 49
Turbinate, Atrophy^a^ | 0 | 46** (1.1)^b^ | 46** (2.1) | 47** (2.8)
Hyperostosis | 1 (2.0) | 27** (1.3) | 45** (2.1) | 48** (2.2)
Olfactory Epithelium, Metaplasia, Respiratory | 17 (1.2) | 39** (1.2) | 47** (1.6) | 48** (1.8)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 2 (1.0) | 5 (1.0) | 13** (1.3) | 11** (1.3)
Female
Number Examined Microscopically | 50 | 50 | 50 | 50
Turbinate, Atrophy | 0 | 46** (1.0) | 50** (2.3) | 49** (2.8)
Hyperostosis | 0 | 13** (1.2) | 45** (2.0) | 48** (2.2)
Olfactory Epithelium, Metaplasia, Respiratory | 3 (1.0) | 29** (1.1) | 49** (1.6) | 50** (1.9)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 18 (1.6) | 18 (1.5) | 13 (1.4) | 32** (1.8)
Respiratory Epithelium, Hyperplasia | 33 (1.1) | 41 (1.2) | 39 (1.5) | 43** (1.8)

** Significantly different (P ≤ 0.01) from the chamber control group by the Poly-3 test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Other Organs: Increased incidences of fat necrosis of the mesentery occurred in exposed groups of females (8/10, 14/16, 15/19, 33/37; Table D-4). Because this lesion was microscopically examined only in cases in which a gross lesion was observed in the mesenteric fat at the time of necropsy, the true incidence of this lesion is uncertain. There were also treatment- and exposure concentration-related increases in the incidences of fat necrosis in the companion rat study.

Significantly increased incidences of uterus endometrium cystic hyperplasia occurred in all exposed groups of females (36/50, 41/49, 46/50, 46/50; Table D-4). Cystic endometrial hyperplasia was characterized by increased numbers of glandular profiles and variably sized cystic structures lined by flattened to cuboidal endometrial epithelium causing dilatation of the uterine lumen and variable compression of the endometrial stroma. This is a common background lesion in aged mice, and its biologic relevance in this study is uncertain. The incidences of this lesion were not considered to be related to vinylidene chloride exposure.

## Genetic Toxicology

Vinylidene chloride in liquid form tested over a concentration range of 33.3 to 6,666 µg/plate was not mutagenic in Salmonella typhimurium strains TA98, TA100, TA1535, or TA1537 when testing occurred with or without exogenous metabolic activation (10% induced hamster or rat liver S9 mix) using a preincubation protocol (Table E-1; Mortelmans et al.^85^). However, when tested in a closed system as a vapor, vinylidene chloride (0.16% to 2.5% in air) demonstrated clear mutagenic activity in mouse lymphoma L5178Y tk^+/−^ cells in trials conducted with 10% induced male rat liver S9 mix (Table E-2; McGregor et al.^90^); in the absence of S9, a positive response was seen at a concentration of 30% vinylidene chloride in one of three trials. In vivo, no increase in sex-linked recessive lethal mutations was seen in germ cells of adult male Drosophila melanogaster exposed via feeding (20,000 or 25,000 ppm) or injection (5,000 ppm) to vinylidene chloride^130^ (Table E-2). No increase in the frequency of micronucleated normochromatic erythrocytes was observed in peripheral blood of male or female B6C3F1/N mice exposed to vinylidene chloride by inhalation for a period of 3 months, and no change in the percentage of immature polychromatic erythrocytes (reticulocytes) was seen in these mice following exposure to vinylidene chloride, suggesting the absence of chemical-induced bone marrow toxicity (Table E-3).

Figure 9

Malignant Mesothelioma in a Male F344/N Rat Exposed to 100 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

Malignant mesotheliomas were characterized by arboriform proliferations of plump, poorly differentiated mesothelial cells supported by a fibrovascular stroma.

Figure 10

Thyroid Gland C-Cell Adenoma in a Female F344/N Rat Exposed to 100 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

C-cell adenomas were discrete, expansile proliferations of clusters and lobules of fairly well differentiated C-cells, causing mild compression of adjacent thyroid gland follicular parenchyma.

Figure 11

Thyroid Gland C-Cell Carcinoma in a Female F344/N Rat Exposed to 50 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

C-cell carcinomas were large, effaced normal thyroid gland parenchyma, and often invaded adjacent tissues beyond the thyroid capsule.

Figure 12

Renal Tubule Carcinoma in a Male F344/N Rat Exposed to 100 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

Renal tubule carcinomas were invariably large, invasive neoplasms composed of infiltrative clusters and lobules of poorly differentiated renal tubule epithelial cells that effaced and infiltrated normal renal parenchyma, sometimes sparing glomeruli.

Figure 13

Renal Tubule Adenoma in a Male F344/N Rat Exposed to 100 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

Renal tubule adenomas were variably sized, expansile masses composed of clusters and lobules of large epithelial cells with variable atypia, causing compression of the adjacent renal parenchyma.

Figure 14

Renal Tubule Hyperplasia in a Male F344/N Rat Exposed to 25 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

Renal tubule hyperplasias characterized by piling and filling of one or more tubule lumens with enlarged, well-differentiated epithelial cells.

Figure 15

Nasal Adenoma in a Male F344/N Rat Exposed to 100 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

The nasal adenoma was expansile, causing partial obstruction of the nasal passage, and was composed of clusters and tubules of fairly well differentiated nasal epithelial cells supported by a fine fibrovascular stroma.

Figure 16

Renal Tubule Adenoma in a Male B6C3F1/N Mouse Exposed to 12.5 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

Renal tubule adenomas were discrete, expansile lesions that compressed adjacent parenchyma.

Figure 17

Renal Tubule Carcinoma in a Male B6C3F1/N Mouse Exposed to 12.5 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

Renal tubule carcinomas were infiltrative proliferations of tubules, lobules, and papillary projections of poorly differentiated renal tubule epithelial cells that infiltrated and effaced normal renal architecture, and were often associated with hemorrhage and necrosis.

Figure 18

Renal Tubule Hyperplasia in a Male B6C3F1 Mouse Exposed to 6.25 ppm Vinylidene Chloride by Whole Body Inhalation for Two Years (H&E)

Renal tubule hyperplasias were discrete lesions characterized by partial to complete filling of one or more tubular lumens by variably pleomorphic epithelial cells exhibiting mild to moderate atypia.