# Materials and Methods

## Procurement and Characterization

### Vinylidene Chloride

Vinylidene chloride, manufactured by Dow Chemical Company (Freeport, TX), was obtained in one lot from Sigma-Aldrich and was used in the 2-week, 3-month, and 2-year studies. The material was identified as lot SB20019301. Identity and purity analyses were conducted by the analytical chemistry laboratory at Chemir Pharma Services (Maryland Heights, MO) and the study laboratory at Battelle Toxicology Northwest (Richland, WA) (Appendix I). Reports on analyses performed in support of the vinylidene chloride studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a colorless, low viscosity liquid with a sweet odor, was identified as vinylidene chloride by infrared and proton nuclear magnetic resonance spectroscopy. Purity of lot SB20019301 was determined by elemental analyses, Karl Fisher titration, anion exchange chromatography, a potassium iodide (KI) titration, a turbidity assay, and gas chromatography with flame ionization detection (GC/FID). Elemental analyses for carbon and hydrogen were consistent with theoretical values for vinylidene chloride. Karl Fischer titration indicated a water content of 74 ppm. KI titration indicated that peroxide was less than 1 ppm by weight as active oxygen compared to vinylidene chloride. Anion exchange chromatography indicated that residual chloride content was less than 2 ppm. The turbidity assay showed that the concentration of polymer was less than 9 ppm. GC/FID indicated that the test article was stabilized with approximately 300 ppm monomethyl ether hydroquinone (MEHQ). Purity analysis by GC/FID indicated the overall purity of lot SB20019301 was greater than 99.9%.

To ensure stability, the bulk chemical was stored under a nitrogen headspace in the original shipping containers (400-L steel mini-Bulk^™^ containers) at a temperature of approximately 63°F. Periodic reanalyses of the bulk chemical were performed during the 2-week, 3-month, and 2-year studies by the study laboratory using the same turbidity and GC/FID assays used in the initial bulk chemical purity assays, and no degradation of the bulk chemical was detected.

## Vapor Generation and Exposure System

Vinylidene chloride was pumped from a disposable 4 liter amber glass generator reservoir into a heated glass flask. Nitrogen entered the flask and assisted in vaporizing the chemical while conveying it from the generator into a short vapor distribution manifold. Concentration in the manifold was determined by the chemical pump and nitrogen flow rates. Pressure in the distribution manifold was kept fixed to ensure constant flows through the manifold and into all chambers as the flow of vapor to each chamber was adjusted.

Individual Teflon^®^ delivery lines carried the vapor from the manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor delivery to the exposure chamber exhaust until the generation system stabilized and exposure could proceed. The flow rate to each chamber was controlled by a metering valve at the manifold. To initiate exposure, the chamber exposure valves were rotated to allow the vinylidene chloride vapor to flow to each exposure chamber inlet duct where it was diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector was used with and without animals in the exposure chambers to ensure that vinylidene chloride vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## Vapor Concentration Monitoring

Chamber and room concentrations of vinylidene chloride were monitored by an on-line gas chromatograph. Samples were drawn from each exposure chamber approximately three times (2-week and 3-month studies) or twice (2-year studies) per hour during each 6-hour exposure period using Hastelloy^®^-C stream-select and gas-sampling valves in a separate, heated oven. The sample lines composing each sample loop were made from Teflon^®^ tubing and were connected to the exposure chamber relative humidity sampling lines at a location close to the gas chromatograph. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout each exposure day for instrument drift against an on-line standard vapor of methylene chloride in nitrogen supplied by a standard generator. The on-line gas chromatograph was recalibrated as required to meet acceptance criteria. Calibration was performed by a comparison of chamber concentration data to data from grab samples collected with activated coconut charcoal gas-sampling tubes, extracted with toluene containing an internal standard of methylene chloride and analyzed using an off-line gas chromatograph equipped with an electron capture detector. Known volumes of chamber atmosphere were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standard solutions of the test chemical containing methylene chloride as an internal standard in toluene.

## Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with (all studies) and without (3-month and 2-year studies) animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.4 minutes. Based on experimental data, a T_90_ value of 12 minutes was selected for the 2-week studies and a T_90_ value of 10 minutes was selected for the 3-month and 2-year studies.

The uniformity of vinylidene chloride vapor concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month and 2-year studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 2-week studies, once during the 3-month studies, and approximately quarterly during the 2-year studies. The vapor concentration was measured using the on-line gas chromatograph. Chamber concentration uniformity was maintained throughout the studies.

The persistence of vinylidene chloride in the chambers after vapor delivery ended was determined by monitor-ing the vapor concentration in the 400 ppm chambers in the 2-week studies, the 100 ppm chambers in the 3-month studies, and the 100 ppm rat and 25 ppm mouse chambers in the 2-year studies with (all studies) and without (3-month and 2-year studies) animals present in the chambers. In the 2-week studies, the concentration decreased to 1% of the target concentration within 21 minutes with animals present. In the 3-month studies, the concentration decreased to 1% of the target concentration within 21 minutes without animals present and within 23 minutes with animals present. For the 2-year rat studies, the concentration decreased to 1% of the target concentration within 22 minutes with and without animals present; for mice, the concentration decreased to 1% of the target concentration within 18 minutes without animals present and within 21 minutes with animals present.

Samples of the test atmosphere from the distribution lines and the low and high exposure concentration chambers for each species were collected prior to the study without animals present (3-month and 2-year studies) and at the beginning and end of one generation day with animals present during the 2-week, 3-month, and 2-year studies. Additional samples were collected from the generator reservoir, and all of the samples were analyzed using GC/FID to measure the stability and purity of vinylidene chloride in the generation and delivery system. To assess whether impurities or degradation products co-eluted with vinylidene chloride or the solvent, a second GC/FID analysis of the samples was performed using a polar column capable of resolving compounds with similar boiling points and polarities. Separate atmosphere samples were collected in these studies using toluene bubblers; MEHQ inhibitor was assayed in these distribution line samples using GC/FID, and peroxide was assayed in these distribution line and low (except 2-week studies) and high exposure concentration chamber samples by KI titration. Hydrochloric acid, formaldehyde, and phosgene concentrations were measured in atmosphere samples collected during the last 2 hours of a 6-hour generation day. Fourier transform IR spectroscopy was used to measure the presence of HCL in samples collected prior to the 3-month studies and during the 2-week, 3-month, and 2-year studies. Formaldehyde and phosgene were measured in atmosphere samples collected on silica adsorbent sampling tubes coated with 2,4-dinitrophenyl-hydrazine prior to the 3-month and 2-year studies and during the 2-week, 3-month, and 2-year studies. These samples were analyzed using a liquid chromatography procedure. Samples were collected from the generator reservoir 3 to 14 days after the reservoir was placed in use in studies conducted without animals present prior to the 3-month and 2-year studies and at the same timepoints during the 2-week, 3-month, and 2-year studies. These samples were analyzed for area percent purity, polymer formation, peroxide content, and MEHQ concentration using the same methodologies employed for the initial bulk chemical characterization assays.

No evidence of degradation of vinylidene chloride was noted in any part of the exposure system in any of the samples collected prior to the 3-month and 2-year studies or during the 2-week, 3-month, and 2-year studies. No impurity peaks with areas greater than 0.1% of the total peak area were detected in atmosphere or generator reservoir samples, and no additional impurities were found in any of the atmosphere or reservoir samples using the polar column. HCL concentrations in the atmosphere samples were consistently less than the detection limit. Formaldehyde and phosgene concentrations were less than 0.1% by weight compared to vinylidene chloride in all distribution line and chamber atmosphere samples. Acceptable, low concentrations of peroxide as active oxygen relative to vinylidene chloride were found in all atmosphere samples. All distribution line samples contained concentrations within the acceptable range for the inhibitor MEHQ relative to vinylidene chloride. No evidence of degradation, peroxide formation, or polymer formation was noted in any samples taken from the generator reservoir after multiple days of use.

## Animal Source

Male and female F344/N rats were obtained from the commercial colony at Taconic Farms, Inc. (Germantown, NY), and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc., for the 2-week, 3-month, and 2-year studies.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-week Studies

On receipt, the rats and mice were 4 to 5 weeks old. Animals were quarantined for 11 days and were 5 to 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. At the end of the studies, serologic analyses were performed on five male and five female chamber control rats and mice using the protocols of the NTP Sentinel Animal Program (Appendix K).

Groups of five male and five female rats and mice were exposed by whole body inhalation to vinylidene chloride vapor at concentrations of 0, 25, 50, 100, 200, or 400 ppm, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 16 (rats) or 17 (mice) days. These wide-ranging exposure concentrations were selected based on reports in the literature that indicated significant differences in species- and strain-related sensitivity to the toxicity of vinylidene chloride. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded daily before and after exposure and at the end of the studies. The animals were weighed initially, on days 6 and 13, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Inhalation Studies of Vinylidene Chloride

Two-week Studies | Three-month Studies | Two-year Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
F344/N rats B6C3F1/N mice | F344/N rats B6C3F1/N mice | F344/N rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
11 days | Rats: 12 (males) or 13 (females) days Mice: 12 days | 12 days
Age When Studies Began
5 to 6 weeks | Rats: 5 to 7 weeks Mice: 5 to 6 weeks | Rats: 5 to 6 weeks Mice: 5 to 6 weeks
Date of First Exposure
June 14, 2004 | Rats: October 11 (males) or 12 (females), 2004 Mice: October 11, 2004 | Rats: June 6, 2005 Mice: June 20, 2005
Duration of Exposure
6 hours plus T_90_ (12 minutes) per day, 5 days per week for 16 (rats) or 17 (mice) days | 6 hours plus T_90_ (10 minutes) per day, 5 days per week, for 14 weeks | 6 hours plus T_90_ (10 minutes) per day, 5 days per week, for 105 weeks
Date of Last Exposure
Rats: June 29, 2004 Mice: June 30, 2004 | Rats: January 10 (males) or 11 (females), 2005 Mice: January 12 (males) or 13 (females), 2005 | Rats: June 7, 2007 Mice: June 21, 2007
Necropsy Dates
Rats: June 30, 2004 Mice: July 1, 2004 | Rats: January 11 (males) or 12 (females), 2005 Mice: January 13 (males) or 14 (females), 2005 | Rats: June 4-8, 2007 Mice: June 18-22, 2007
Age at Necropsy
8 to 9 weeks | Rats: 18 to 20 weeks Mice: 19 to 20 weeks | 109 to 111 weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females | 50 males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies | Same as 2-week studies
Animals per Cage
1 | 1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 open formula wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum except during exposure periods, changed weekly | Same as 2-week studies | Same as 2-week studies
Water
Tap water (Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, MI), available ad libitum | Same as 2-week studies | Same as 2-week studies
Cages
Stainless steel wire-bottom (Lab Products, Inc., Seaford. DE), changed weekly with chambers, rotated daily in chambers | Same as 2-week studies, except rotated weekly in chambers | Same as 3-month studies
Cageboard
Untreated paper cage pan liner (Techboard, Shepherd Specialty Papers, Kalamazoo, MI), changed daily | Same as 2-week studies | Same as 3-month studies
Chamber Air Supply Filters
Single HEPA (open stock), charcoal (RSE, Inc., New Baltimore, MI), Purafil (Environmental Systems, Lynnwood, WA), all new at study start | Same as 2-week studies | Same as 2-week studies, except HEPA filter changed annually
Chambers
Stainless steel chambers, excreta pan at each occupied level (Lab Products, Inc., Seaford, DE) chambers changed weekly, excreta pans changed daily | Same as 2-week studies | Same as 2-week studies
Chamber Environment
Temperature: 75° ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Same as 2-week studies | Same as 2-week studies
Exposure Concentrations
0, 25, 50, 100, 200, or 400 ppm in air | 0, 6.25, 12.5, 25, 50, or 100 (except male mice) ppm in air | Rats: 0, 25, 50, or 100 ppm in air Mice: 0, 6.25, 12.5, or 25 ppm in air
Type and Frequency of Observation
Observed twice daily; animals were weighed on days 1, 6, 13, and at the end of studies; clinical findings were recorded daily before and after exposure and at the end of the studies. | Observed twice daily; core study animals were weighed initially, day 9 (female rats) or 10, weekly thereafter, and at the end of the studies. Clinical findings were recorded on day 9 (female rats) or day 10, weekly thereafter, and at the end of the studies. | Observed twice daily. Animals were weighed initially, weekly for the first 13 weeks, every 4 weeks through week 93, every 2 weeks thereafter, and at the end of the studies. Clinical findings were recorded every 4 weeks through week 93, then every 2 weeks, and at the end of the studies.
Method of Kill
Carbon dioxide asphyxiation | Same as 2-week studies | Same as 2-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all animals.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of clinical pathology rats on days 3 and 23 and from core study animals at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; erythrocyte and platelet morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, globulin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, bile acids, | None
Histopathology
Histopathology was performed on 0, 100, 200, and 400 ppm rats and 0, 50, 100, 200, and 400 ppm mice. In addition to gross lesions and tissue masses, the eyes, kidney (except 50 ppm female mice), liver, lung, and nose were examined to a no-effect level. | Complete histopathology was performed on 0 and 100 ppm core study rats, 0 and 50 ppm male mice and 0 and 100 ppm female mice. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung, lymph nodes (mandibular, mesenteric, bronchial, and mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on all rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung, lymph nodes (mandibular, mesenteric, bronchial, and mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, spermatid and sperm samples were collected from male animals in the 0, 12.5 (mice), 25, 50, and 100 (rats) ppm groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from females exposed to 0, 12.5 (mice), 25, 50 or 100 (rats) ppm. | None

At the end of the 2-week studies, necropsies were performed on all rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Histopathologic examinations were performed on 0, 100, 200, and 400 ppm rats and 0, 50, 100, 200, and 400 ppm mice; the eyes, kidney (except 50 ppm female mice), liver, lung, and nose were examined. Table 1 lists the tissues and organs examined.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to vinylidene chloride and to determine the appropriate exposure concentrations to be used in the 2-year studies.

On receipt, the rats were 4 weeks old, and the mice were 4 or 5 weeks old. Animals were quarantined for 12 or 13 days and were 5 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. During week 2 and at the end of the studies, serologic analyses were performed on five male and five female sentinel rats and mice using the protocols of the NTP Sentinel Animal Program (Appendix K).

Groups of 10 male and 10 female rats and mice were exposed by whole body inhalation to vinylidene chloride vapor at concentrations of 0, 6.25, 12.5, 25, 50, or 100 (rats and female mice) ppm, 6 hours plus T_90_ (10 minutes) per day, 5 days per week for 14 weeks. Groups of 10 male and 10 female clinical pathology rats were exposed to the same concentrations for 23 days. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded on day 9 (female rats) or day 10, weekly thereafter, and at the end of the studies. The animals were weighed initially, day 9 (female rats) or day 10, weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Blood was collected from the retroorbital sinus of clinical pathology rats on days 3 and 23 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats only) analyses. For the hematology samples, blood was collected in a tube (Vacutainer, Becton Dickinson; Franklin Lakes, NJ) containing potassium-EDTA; for the clinical chemistry samples, the blood was collected in a tube devoid of anticoagulant but containing a separator gel for serum. An Abbott Cell-Dyn 3700 (Abbott Diagnostics Systems, Abbott Park, IL) was used to determine packed cell volume; hemoglobin concentration; erythrocyte, platelet, and leukocyte counts; mean cell volume; mean cell hemoglobin; and mean cell hemoglobin concentration. Manual hematocrit values were determined using a microcentrifuge (Heraeus haemofuge, Germany) and a Damon/IEC capillary reader (International Equipment Company, Needham Heights, MA) for comparison to Cell-Dyn values for packed cell volume. Leukocyte, erythrocyte, and platelet morphology were assessed on blood smears stained with Romanowsky-type aqueous stain in a Wescor 7100 slide stainer (Wescor, Inc., Logan UT), and when observed, nucleated erythrocytes were counted per 100 leukocytes from the same stained blood smear. Reticulocytes were stained supravitally with new methylene blue and enumerated as reticulocytes per 1,000 erythrocytes using the Miller disc method.^94^ Howell-Jolly bodies were counted per 1,000 erythrocytes. For clinical chemistry analyses, serum samples were analyzed using a Roche Hitachi 912 System (Roche Diagnostic Corporation, Indianapolis, IN). The hematology and clinical chemistry parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats exposed to 0, 25, 50, or 100 ppm and mice exposed to 0, 12.5, 25, or 50 ppm. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained.Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lungs, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on 0 and 100 ppm core study rats and 0, 50 (male), and 100 (female) ppm mice. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^95^ and Boorman et al.^96^

## Two-year Studies

### Study Design

Groups of 50 male and 50 female rats and mice were exposed by whole body inhalation to vinylidene chloride vapor at concentrations of 0, 25, 50, or 100 (rats) or 0, 6.25, 12.5, or 25 (mice) ppm, 6 hours plus T_90_ (10 minutes) per day, 5 days per week for 105 weeks.

Rats and mice were quarantined for 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats and mice were 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K).

Rats and mice were housed individually. Feed was available ad libitum except during exposure periods; water was available ad libitum. Chambers and racks were rotated weekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix J.

### Clinical Examinations and Pathology

All animals were observed twice daily. Body weights were recorded on day 1, weekly for the first 13 weeks, every 4 weeks through week 93, every 2 weeks thereafter, and at terminal kill. Clinical findings were recorded every 4 weeks through week 93, then every 2 weeks, and at terminal kill.

Complete necropsies and microscopic examinations were performed on all core study rats and mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s Solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. For extended evaluation of renal proliferative lesions, kidneys were step sectioned at 1 mm intervals from the residual cross sectional half of the right kidney and the longitudinal half of the left kidney of male rats, and four additional sections were obtained from each kidney. Tissues examined microscopically are listed in Table 1. Samples of tumor tissues collected at necropsy for molecular analysis (mesotheliomas) were flash frozen in liquid nitrogen and stored at −80°C (Appendix L).

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included the nose of rats and mice, the kidney of male rats and male and female mice, and the liver of rats.

The quality assessment report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^95^ and Boorman et al.^96^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^97^

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^98^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^99^ method for testing two groups for equality and Tarone’s^100^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-5, Table B-1, Table B-6, Table C-1, Table C-4, Table D-1, and Table D-4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^101-103^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^101^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^101^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1/N mice.^104^ Bailer and Portier^101^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^105^

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1−P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^106^ and Williams.^107,108^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^109^ (as modified by Williams^110^) and Dunn.^111^ Jonckheere’s test^112^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a mono-tonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^113^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the Fisher exact test.^114^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^115^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period.^116,117^ In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the present study.

## Quality Assurance Methods

The 2-week, 3-month, and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^118^ In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of vinylidene chloride was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium, mutations in L5178Y mouse lymphoma cells, sex-linked recessive lethal mutations in Drosophila melanogaster, and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^119,120^ The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mecha-nisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^121^ and the somatic mutation theory of cancer.^122,123^ However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^124^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^125,126^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test.^127,128^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^129^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.