# Introduction

Figure 1

Vinylidene Chloride (CASRN: 75-35-4; Chemical Formula: C2H2Cl2; Molecular Weight: 96.94)

Synonyms: 1, 1-dichloroethene; 1, 1-dichloroethylene.

## Chemical and Physical Properties

Vinylidene chloride is a clear, volatile liquid that has a sweet odor and a melting point of −122.1°C, a boiling point of 31.7°C, and a vapor pressure of 400 mm at 14.8°C.^1-5^ Vinylidene chloride is insoluble in water, but miscible with most organic solvents.^5^ In the absence of an added inhibitor, monomethyl ether of hydroquinone, vinylidene chloride readily polymerizes. In the presence of air or oxygen, shock-sensitive and explosive peroxides are formed.

## Production, Use, and Human Exposure

Vinylidene chloride is a man-made chemical that is not known to occur naturally. It is produced commercially via the dehydrochlorination of 1,1,2-trichloroethane with an aqueous alkali, like sodium hydroxide or lime.^1^ Vinylidene chloride can be purified through distillation and extraction. Commercial grade vinylidene chloride contains up to 200 ppm MEHQ that is added to prevent polymerization and the formation of explosive peroxides. In order to manufacture vinylidene chloride polymers, polymerization initiators are added.

The annual production of vinylidene chloride in the United States has varied between 68,000 and 90,000 tons^1-3,6,7^ with the most recent estimate of 79,000 tons.^7^ In 1990, the world-wide production was estimated at 290,000 tons.^7,8^

Vinylidene chloride is used as an intermediate in organic synthesis reactions and is widely used in the production of a variety of polymers. For increased polymer stability, it is usually copolymerized with other chemicals, such as vinyl chloride, acrylonitrile, meth-acrylonitrile, and methacrylate.^1^ Most of the vinylidene chloride in the plastics industry is used in the production of copolymers with polyvinylidene polymers that have a broad spectrum of application in film form and as solvent-soluble resins, water dispersions, and latexes.^1-3,9,10^ These polymers are used extensively in films for household and industrial food packaging based on their oxygen-barrier properties. Solvent-soluble resins are used as coatings on other polymer films; paper cups and plates; pipes; ship, railroad, and fuel storage tanks; and binders in coatings for various tapes.^11^ Latexes and extruded fibers made from vinylidene chloride copolymers are used in coating plastics, in flame-resistant fiber and carpet backing, as binders in paints, and to fabricate filaments, pipes, pipe liners, and gaskets.^11^

The highest potential for human exposure to vinylidene chloride is at its point of production and formulation. Occupational exposure may occur via inhalation or dermal contact.^3,7,9^ The U.S. Environmental Protection Agency reported that 6,500 workers in monomer and polymer plants were exposed to air levels of 25 to 100 µg/m^3^.^2^ The primary source of vinylidene chloride in the environment is through volatile air emissions in the atmosphere and in effluent waters from plants synthesizing vinylidene chloride and its copolymers, or manufacturing products containing vinylidene chloride. The general population is exposed via inhalation and ingestion of contaminated drinking water. Based on personal air sampling in the general population, Wallace^12^ estimated mean vinylidene chloride exposure to be 6.5 μg/m^3^. Consumers may also be exposed via migration of vinylidene chloride from the films and coatings of packaging materials into foods contained in the packaging. The recommended threshold limit value for occupational exposure to vinylidene chloride is currently 5 ppm for 8 hours based on effects involving the liver and kidney.^7,13^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Following inhalation exposure in rats, the absorption of vinylidene chloride was rapid and concentration-dependent. The uptake was linear for concentrations up to 150 ppm, above which the uptake decreased with the increasing concentration.^14,15^ The compound was found in blood of rats within 2 minutes following exposure. Following exposure to concentrations up to 2,000 ppm [^14^C]vinylidene chloride, the highest level of total radioactivity was found in the liver and kidney, with only very small amounts present in other tissues.^14,16,17^ Covalently bound radioactivity was also highest in the liver and the kidney with fasted rats having higher levels than nonfasted.^14,17^ Following exposure to 10 ppm for 6 hours, a higher body burden was observed in mice than in rats exposed under similar conditions. The bound radioactivity was higher in mouse liver and kidney than in corresponding tissues in rats.^17^ Elimination of vinylidene chloride following inhalation exposure in rats was rapid with the majority of the dose eliminated in the urine. Steady state levels in expired air were achieved following exposure to 25 to 150 ppm vinylidene chloride, indicating that the elimination is first order at these levels; about 1% of the dose was excreted unchanged in the expired air at these exposure concentrations. At concentrations greater than 150 ppm, levels in expired air increased indicating saturation of metabolism.^15^ The pulmonary elimination was biphasic in rats following inhalation exposure; the half-lives for the first and second phases, respectively, based on the unchanged compound were 20 and 217 minutes following exposure to 10 ppm and 21 and 133 minutes following exposure to 200 ppm [^14^C]vinylidene chloride. Urinary elimination followed a similar pattern; the half-lives for the first and second phases, respectively, based on the total [^14^C] excretion in urine were 3.1 and 19.3 hours following exposure to 10 ppm and 3.8 and 23.9 hours following exposure to 200 ppm [^14^C]vinylidene chloride. The major portion of the dose was eliminated in both the breath and the urine during the rapid first phase. Fasting did not affect the elimination kinetics of vinylidene chloride in rats.^14,17^ Limited data in mice following inhalation exposure to 10 ppm vinylidene chloride indicated that the elimination of unchanged compound in the expired air is smaller and elimination via urine is larger compared to rats, indicating that mice metabolize vinylidene chloride at a greater rate than rats.^17^

An investigation of the plasma toxicokinetics of vinylidene chloride in Sprague Dawley rats showed that the C_max_ and AUC_0–∞_, respectively, following inhalation exposure to 300 ppm were 2.8 mg/L and 279 μg·min/mL; the elimination half-life and bioavailability, respectively, were 50 minutes and 55.7%.^18^

Following oral administration of doses ranging from 0.5 to 100 mg/kg, vinylidene chloride was rapidly and almost completely absorbed in rats and mice and distributed to all tissues examined.^4,19-23^ Peak blood levels were observed in rats within 2 to 8 minutes.^23^ Vinylidene chloride was distributed to all tissues following administration with the highest amount found in the liver and kidney.^20,24^ The pattern of elimination was similar to that following inhalation exposure. Following a single administration of 1 mg/kg in rats, about 1% to 3% of the dose was excreted in expired air as unchanged chemical, with 21% recovered as carbon dioxide.^20^ The majority of the dose was eliminated in urine (63%) and some in feces (16%) within 72 hours, with the majority excreted within the first 24 hours. Following administration of 50 mg/kg, 16% to 30% of the dose was excreted in expired air as the parent with concomitant reductions in the expired carbon dioxide (3% to 6%) and urinary excretion (35% to 47%) suggesting that metabolism saturates at rather low doses.^20,21,24^ Fasting slightly modified the elimination of vinylidene chloride in rats after oral administration; 29% of a 50 mg/kg dose was excreted unchanged in expired air compared to 19% in fed rats.^20^ Mice eliminated less in expired air as unchanged chemical and more in urine than rats following oral administration of 50 mg/kg.^19^ The elimination of vinylidene chloride following oral administration in rats was biphasic.^20,21^ Half-lives for the two phases, respectively, for pulmonary elimination were 25 and 117 minutes for a 1 mg/kg dose and 21 and 66 minutes for 50 mg/kg.^20^ For urinary elimination of total radioactivity, the estimated half-lives for the first and second phases were 6 and 17 hours for both doses. Plasma toxicokinetics of vinylidene chloride in Sprague Dawley rats following gavage exposure showed a similar behavior to inhalation exposure.^18^ The C_max_ and AUC_0–∞_ following gavage exposure to 30 mg/kg were 8.9 mg/L and 233 μg·min/mL, respectively; the elimination half-life and bioavailability were 88 minutes and 46.5%, respectively.

In a study where mice were administered a single intraperitoneal injection of 125 mg/kg [14C] vinylidene chloride, radioactivity was distributed to all examined tissues with the highest levels of radioactivity found in the kidney, liver, and lung 6 hours after administration.^25^

The metabolism of vinylidene chloride is saturable, and unmetabolized vinylidene chloride is primarily eliminated via exhalation from the lung regardless of the method of administration.^15,17,26^ The proposed pathway for the metabolism of vinylidene chloride in rodents is shown in Figure 2. Vinylidene chloride is metabolized in rodents via pathways involving CYP2E1 to yield three reactive metabolites: vinylidene chloride epoxide, 2-chloroacetyl chloride, and 2,2-dichloroacetaldehyde. These electrophilic metabolites undergo oxidation, hydrolysis, and reactions with glutathione and cellular macromolecules. The oxidative metabolism of vinylidene chloride has been reported to saturate in rats at around 200 ppm following inhalation and between 10 to 50 mg/kg following oral exposure.^15,17,26,27^ The involvement of glutathione in the detoxification of vinylidene chloride was consistent with the observation that exposure to vinylidene chloride depletes liver glutathione levels.^28-30^ Urinary metabolites identified were N-acetyl-S-(2-hydroxyethyl)cysteine, S-(cysteinyl acetyl) glutathione, N-acetyl-S-(2-carboxymethyl) cysteine, thiodiglycolic acid, dithioglycolic acid, dithiodiglycolic acid, chloroacetic acid, and biliary metabolites identified were S-(2-carboxymethyl) glutathione, S-(cysteinyl acetyl)glutathione, and a product of the intramolecular rearrangement of the metabolite, S-(2-chloroacetyl)glutathione.^4,19,24,25,31-39^ In addition, several carboxymethylated proteins were identified in bile from vinylidene chloride-treated rats.^38^ Mice metabolized a greater portion of the orally administered vinylidene chloride than rats.^24,35^ Although the types of metabolites observed in rats and mice were similar, N-acetyl-S-(2-carboxymethyl)cysteine arising likely from the 2-chloroacetyl chloride pathway was detected in mice but not in rats. In addition, quantitatively, mice produced more S-(2-hydroxyethyl)-N-acetyl cysteine [previously identified by Jones and Hathway^24^ as N-acetyl-S-cysteinyl acetyl derivative], a product of the reaction between vinylidene chloride epoxide with glutathione, than rats suggesting that the formation of vinylidene chloride epoxide is higher in mice than in rats.

Figure 2

The Proposed Metabolic Pathway of Vinylidene Chloride in Rodents

In addition, several investigations in rat liver microsome incubations and mouse liver and lung microsomal incubations have shown that vinylidene chloride epoxide is the major and likely the most important cytotoxic metabolite; minor metabolites identified were 2,2,-dichloroacetaldehyde and 2-chloroacetylchloride.^31,32,35,39-42^ As seen in vivo, these metabolites undergo secondary reactions including oxidation, glutathione conjugation and hydrolysis. The levels of the acetal observed in lung microsomes were higher than those in the liver microsomal incubations.^41^ It was also demonstrated that the mean rate of formation of the epoxide was twofold higher in mouse lung microsomal incubations compared to human lung microsomal incubations.^41^ Simmonds et al.^39^ showed that both CYP2E1 and CYP2F2 catalyze the bioactivation of vinylidene chloride to its epoxide in the mouse lung microsomes. Using incubations of mouse lung microsomes, and recombinant CYP2E1 (rat and human), CYP2F2 (mouse), CYP2F3 (goat), and CYP2F4 (rat), they further demonstrated that vinylidene chloride metabolism occurred with different affinities and catalytic efficiencies in different species, suggesting species differences in the severities of toxicities by vinylidene chloride. Recombinant rat CYP2E1 showed greater affinity and efficiency for vinylidene chloride than human CYP2E1, mouse CYP2F2, goat CYP2F3, or rat CYP2F4.

There are several critical factors that contribute to the metabolism of vinylidene chloride. Glutathione levels and glutathione S-transferase activity,^25,43^ nutritional status (fasting and nonfasting), and changes in CYP2E1 are important factors. Inducers and inhibitors of CYP2E1 alter metabolic activation of vinylidene chloride to reactive intermediates.^41,44-46^ In rodents, vinylidene chloride epoxide and 2-chloroacetylchloride are proposed as the reactive intermediates which are subsequently detoxified via the reaction with glutathione and produced in the liver following exposure. These electrophilic intermediates are also capable of reacting with cellular macromolecules to form adducts in the liver, which may partially explain the observed liver toxicity in rodents. The glutathione conjugates are secreted from the hepatocytes and delivered to the kidney where they undergo glomerular filtration.^47^ In the kidney, glutathione conjugates may be metabolized to the corresponding cysteine conjugate, which is acetylated and excreted in urine. Alternately, glutathione conjugates can be metabolized by β-lyase, an enzyme located in the renal proximal tubule, to release an electrophilic product that can subsequently interact with cellular macromolecules in the kidney. This mechanism has been shown to be associated with the observed nephrotoxicity of other halogenated ethylenes and ethanes.^48^ It has been shown that fasting significantly reduces detoxification and enhances covalent binding of toxic metabolites in the liver and kidney.^14,16,17,28^

### Humans

No studies are available for the disposition of vinylidene chloride in humans. In human liver and lung microsomal incubations, epoxide-derived glutathione conjugates were the major metabolites detected along with low levels of 2,2,-dichloroacetaldehyde.^49^ Liver microsomes from three out of five human samples metabolized vinylidene chloride to the epoxide-derived glutathione conjugates. Studies using human recombinant enzymes have demonstrated the involvement of CYP2E1 in vinylidene chloride metabolism in humans.^39^

## Toxicity

### Experimental Animals

Vinylidene chloride toxicity, including lethality, varies considerably with species, sex, strain, and nutritional status. Mice are more sensitive than rats to vinylidene chloride toxicity. The oral LD_50_ ranges from 1,500 to 1,800 mg/kg in rats^50,51^ compared to 194 to 217 mg/kg in mice.^24^ The reported values for inhalation LC_50_ are 6,350 ppm in rats^52^ and 98 to 105 ppm in mice.^53^

A major contributing factor to the variability of vinylidene chloride toxicity involves food intake (fasted/ nonfasted). Lethal inhalation concentrations for fed rats are higher than those in fasted rats.^28,52,54^ Vinylidene chloride toxicity is enhanced in fasted animals^28,55-57^ and in glutathione-depleted rats and mice.^28,58-61^ Toxicity is decreased when the capacity of P450 metabolic activation is decreased.^62,63^

In short-term studies in laboratory animals, the liver and kidney are the main target organs of vinylidene chloride-induced toxicity. Vinylidene chloride suppresses liver glutathione levels^29,30,64,65^ and induces hepatotoxicity. Exposure to vinylidene chloride increases serum markers for liver damage and hepatic histopathologic lesions, including hepatocellular degeneration, necrosis, and bile duct hyperplasia.^30,53,66^ Exposure to vinylidene chloride increases kidney weights and serum markers for nephrotoxicity and induces histopathologic lesions, including tubular dilation and necrosis in rats^66,67^ and mice.^53^ Vinylidene chloride-mediated renal toxicity correlates to metabolic activation by CYP2E1 in the proximal tubules, decreased glutathione concentrations, and increased covalent binding in the kidney. In the kidneys, glutathione conjugates and/or their derivatives may undergo secondary modification by β-lyase to reactive metabolites.^68,69^ In mice, exposure to vinylidene chloride has also been shown to induce morphologic changes in Clara cells, including dilation of cisternae, endoplasmic reticulum degeneration, and cytoplasmic vacuolization.^70^

The National Toxicology Program (NTP) previously conducted 14-day and 13-week subchronic toxicology and 2-year chronic toxicology and carcinogenesis studies for vinylidene chloride administered via gavage to F344 rats and B6C3F1 mice.^71^ In the 14-day studies, decreased survival was observed at 500 and 1,000 mg/kg in rats and 500 mg/kg in mice. Hemorrhagic necrosis in the liver corresponded with increased mortality in both rats and mice. In rats, significantly decreased body weights were also observed at these doses. In the 13-week studies, decreased mean body weights and increased incidences of hepatocytomegaly and hepatic centrilobular necrosis were observed in rats exposed to 250 mg/kg. Hepatocytomegaly with less severity was also observed at 100 mg/kg. In mice, increased mortality in both sexes exposed to 250 mg/kg was associated with necrosis, hemorrhage, and congestion of the liver. At 100 mg/kg, survival was slightly decreased (8/10 males; 7/10 females) and increased incidences of cellular atypia of the liver were observed in males and females. A dose-dependent decrease in mean body weight gain was observed in male mice.

### Humans

In humans, vinylidene chloride is an irritant and a central nervous system depressant, and it induces toxicity in liver, lung, and kidney.^4,10^ The irritant properties have been attributed to the polymerization inhibitor MEHQ.^3,10^

## Reproductive and Developmental Toxicity

In studies assessing reproduction, exposure to vinylidene chloride via inhalation or drinking water had no effects on reproduction in male mice or in either sex of rats.^72-74^ No evidence of maternal toxicity or teratogenic effects was observed in rats exposed to 200 ppm vinylidene chloride on gestation days 6 to 15 in the drinking water.^75^ In inhalation studies, maternal toxicity was observed at 15 ppm or greater in CD-1 rats, 30 ppm or greater in CD-1 mice, 80 ppm or greater in Sprague Dawley rats, and 160 ppm or greater in New Zealand white rabbits.^44,75^ In these studies, inhalation exposure to vinylidene chloride during gestation clearly induced embryo- and fetotoxicity at concentrations that induced maternal toxicity. In CD-1 mice, fetal toxicity in the absence of significant maternal toxicity was observed at 15 ppm vinylidene chloride. In this study, there was an increase in fetuses with an unossified incus, incompletely ossified sternebrae, hydrocephalus, occluded nasal passages, microphthalmia, cleft palate, small liver, and hydronephrosis.

## Carcinogenicity

### Experimental Animals

The chronic toxicity and carcinogenicity of vinylidene chloride in rats and mice have been investigated in eight rat and three mouse inhalation studies and five rat and one mouse oral studies.^6,11,51,71,76-80^ Overall, none of the results from these studies demonstrate a significant increase in neoplasms following exposure to vinylidene chloride. Despite this broad database of research from other published studies, these studies are insufficient for determining the carcinogenic risk. Problems associated with the results from these studies include the lack of statistical analysis, inadequate control of dosing or exposure, changing or discontinuing dosing or exposure levels during the study, excessive mortality, inadequate study duration or overall study design, and a lack of dose response.

In the previous NTP^71^ studies, no significant effects were observed on survival, clinical signs, or body weights in rats or mice administered vinylidene chloride by gavage. When rats were administered 1 or 5 mg/kg, the incidence of chronic inflammation of the kidney was higher in 5 mg/kg males than in the vehicle controls. There was no increased incidence of neoplasms at any site in rats administered vinylidene chloride. When mice were administered 2 or 10 mg/kg, a significant increase in the incidence of lymphoma or leukemia at 2 mg/kg that was not observed at 10 mg/kg was not considered to be related to vinylidene chloride administration in females. There was no increased incidence of neoplasms at any other site in male or female mice administered vinylidene chloride.

### Humans

Major limitations in the two cohort studies conducted in vinylidene chloride-exposed workers restrict the value of the results. No specific association has been found between exposure to vinylidene chloride in a synthetic chemical plant and excess cancer.^3^

## Genetic Toxicity

The literature suggests that vinylidene chloride, which is a gas at temperatures above 31.7°C, demonstrates consistent mutagenic activity in vitro when tests are conducted with an exogenous metabolic activation system. No evidence of genotoxicity was seen in the few in vivo assays that were reported for vinylidene chloride.

Increases in mutant colonies were observed in Salmonella typhimurium strains TA100 and TA1530 following exposure to vinylidene chloride concentrations of 0.2%, 2%, and 20% in air (v/v) in the closed environment of a desiccator in the presence of noninduced rat or mouse liver microsomal mix (S9)^81^; mutagenicity was greater in the presence of mouse S9. Mouse kidney and lung S9 fractions were also effective at producing mutagenic metabolites of vinylidene chloride in strain TA100, although the responses were lower than those observed with liver S9 activation.^81^ Strongly positive results were also observed in S. typhimurium strains TA92, TA98, TA100, and TA1537 and Escherichia coli strain WP2 uvrA exposed to vinylidene chloride (375 to 22,500 ppm) in the presence of noninduced mouse liver S9 in a sealed desiccator.^82^ In this study, the effectiveness of vinylidene chloride-induced mouse liver S9 and rat liver S9 was examined, and no additional increase in mutagenicity was observed compared with use of the noninduced S9.

Other studies of the effect of S9 preparation from different species on the mutagenicity of vinylidene chloride (5% in air, sealed culture system) in S. typhimurium strain TA1535 demonstrated that pretreatment with Aroclor 1254 increased the effectiveness of mouse liver and kidney S9, and that induced mouse liver S9 was more effective than induced rat liver S9 at generating mutagenic metabolites of vinylidene chloride.^83^

Vinylidene chloride (3%) has also been used as a positive control for strains TA100 and TA1530 in experiments conducted in a closed environment, in the presence of metabolic activation, with gaseous test agents.^84^ The need to control for volatility is demonstrated by the failure of vinylidene chloride (tested up to 6,667 μg/mL) to induce revertants in S. typhimurium strains TA98, TA100, TA1535, or TA1537, with or without S9, when a preincubation protocol was employed.^85^

Consistent with the other studies in bacteria, vinylidene chloride (2.5 mM) induced a mutagenic response in E. coli K-12 in the presence, but not the absence, of mouse S9.^86,87^

In yeast test systems, vinylidene chloride was shown to be toxic but not mutagenic in the diploid Saccharomyces cerevisiae strain D7 in the absence of S9.^88^ However, in the presence of Aroclor 1254-induced mouse liver S9, dose-related increases in both point mutations and mitotic gene conversions were seen in strain D7 at doses above 20 mM.^88,89^ Significant increases in mitotic gene conversion were also seen in logarithmic phase S. cerevisiae D7 cells with a high level of cytochrome P450 that provided for metabolic activation of vinylidene chloride.^88^ Vinylidene chloride induced a highly significant, dose-related increase in aneuploidy in S. cerevisiae strain D61.M, with and without S9.^88^

Inconsistent mutagenic responses were seen in L5178Y mouse lymphoma tk^+/−^ cells with vinylidene chloride in the absence of metabolic activation; with activation, both cytotoxicity and mutagenicity were consistently positive at concentrations of 0.16% and above in repeat experiments.^90^ Concentrations of 2% or 10% vinylidene chloride by air (5-hour exposure) with or without S9 mix did not increase resistance to ovabain (membrane sodium-potassium ATPase locus) or γ-azocytidine (HGPRT locus) in Chinese hamster V9 cells.^91^

Dose-related increases in chromosomal aberrations were seen in cultured Chinese hamster lung cells exposed to vinylidene chloride over a concentration range of 0.125 to 1.5 mg/mL in the presence of 15% PCB-induced male F344 rat liver S9.^92^ In addition, sister chromatid exchanges were increased in these same cells when treatment was carried out in the presence of S9.

Limited evidence of genotoxicity was seen with vinylidene chloride in vivo. Bone marrow micronucleus tests in ddY male mice following single (25 to 200 mg/kg) or multiple (25 to 100 mg/kg) daily gavage treatments with vinylidene chloride were negative, and no increases in micronucleated cells of fetal liver or fetal blood were seen 24 hours after a single intraperitoneal injection (25 to 100 mg/kg) administered to pregnant ICR mice on gestational day 18.^92^ Negative results were also reported in dominant lethal tests (germ cell mutagenicity assays) in male CD-1 mice treated with 3,000 to 30,000 ppm vinylidene chloride 6 hours/day for 5 days followed by mating,^72^ and male CD rats exposed to 55 ppm vinylidene chloride for at least 11 weeks prior to mating.^73^ However, evidence of vinylidene chloride interaction with DNA was seen in one study in which alkylated DNA was recovered from the livers and kidneys of mice and rats exposed to radiolabeled vinylidene chloride (10 or 50 ppm for 6 hours), although the number of alkylated nucleotides recovered was very low compared to those recovered after intraperitoneal dosing with 10 mg/kg of the potent alkylating agent dimethylnitrosamine.^93^

## Study Rationale

The toxicology and carcinogenicity of inhaled vinylidene chloride were investigated based on insufficient critical information concerning its health effects and the need to fill critical data gaps. Previously conducted NTP^71^ studies were considered insufficient to evaluate carcinogenicity because selected doses failed to include a maximum tolerated dose. The conclusion of those studies was that the lack of carcinogenicity observed should not be taken as proof that vinylidene chloride was not a carcinogen.